# References

1 National Center for Biotechnology Information (NCBI). PubChem Compound Summary for CID 167693, Trimethylsilyldiazomethane. PubChem; 2020. https://pubchem.ncbi.nlm.nih.gov/compound/Trimethylsilyldiazomethane [Accessed: August, 2020]
2 Aoyama T, Shioiri T. New methods and reagents in organic synthesis. 17. Trimethylsilyldiazomethane (TMSCHN2) as a stable and safe substitute for hazardous diazomethane. Its application to the Arndt-Eistert synthesis. Chem Pharm Bull (Tokyo). 1981; 29(11):3249–3255. 10.1248/cpb.29.3249
3 Kuhnel E, Laffan DD, Lloyd-Jones GC, Martinez Del Campo T, Shepperson IR, Slaughter JL. Mechanism of methyl esterification of carboxylic acids by trimethylsilyldiazomethane. Angew Chem Int Ed. 2007; 46(37):7075–7078. 10.1002/anie.200702131 17691089
4 Leggio A, Liguori A, Perri F, Siciliano C, Viscomi MC. Methylation of alpha-amino acids and derivatives using trimethylsilyldiazomethane. Chem Biol Drug Des. 2009; 73(3):287–291. 10.1111/j.1747-0285.2009.00777.x 19207464
5 Migowska N, Stepnowski P, Paszkiewicz M, Golebiowski M, Kumirska J. Trimethylsilyldiazomethane (TMSD) as a new derivatization reagent for trace analysis of selected non-steroidal anti-inflammatory drugs (NSAIDs) by gas chromatography methods. Anal Bioanal Chem. 2010; 397(7):3029–3034. 10.1007/s00216-010-3853-y 20563796
6 van ’t Erve TJ, Rautiainen RH, Robertson LW, Luthe G. Trimethylsilyldiazomethane: A safe non-explosive, cost effective and less-toxic reagent for phenol derivatization in GC applications. Environ Int. 2010; 36(8):835–842. 10.1016/j.envint.2010.02.011 20385409
7 Seyferth D, Menzel H, Dow AW, Flood TC. Trimethylsilyl-substituted diazoalkanes: I. Trimethylsilyldiazomethane. J Org Chem. 1972; 44(2):279–290.10.1016/S0022-328X(00)82916-2
8 Sunderman F, Connor R, Fields H. Diazomethane poisoning. First clinical case report. Am J Med Sci. 1938; 195(4):469–472. [Reviewed in Potter et al. 2015]. 10.1097/00000441-193804000-00006
9 Potter G, Budge SM, Speers RA. Beyond diazomethane: Alternative approaches to analyzing non-esterified fatty acids. Eur J Lipid Sci Technol. 2015; 117(7):908–917. 10.1002/ejlt.201400404
10 Stain JP, Nouvet G, Morere P. [Poisoning by diazomethane inhalation]. Toxicol Eur Res. 1983; 5(5):217–219. 6675207
11 LeWinn E. Diazomethane poisoning; Report of a fatal case with autopsy. Am J Med Sci. 1949; 218(5):556–562. 10.1097/00000441-194911000-00011 15392072
12 Hazardous Substance Databank (HSDB). Diazomethane. Washington, DC: U.S. National Library of Medicine, National Center for Biotechnology Information; 2005. HSDB No. 1628. https://pubchem.ncbi.nlm.nih.gov/compound/9550
13 American Conference of Governmental Industrial Hygienists (ACGIH). Diazomethane. In: Documentation of the Threshold Limit Values for Substances in Workroom Air. 3rd ed. Cincinnati, OH: American Conference of Governmental Industrial Hygienists; 1971. p. 71-72.
14 Kuhn J. Acute dermal toxicity study in rabbits, report by Stillmeadow Incorporated submitted to Gelest, Inc. Morrisville, PA: Stillmeadow Incorporated; 2008.
15 Murphy NG, Varney SM, Tallon JM, Thompson JR, Blanc PD. Fatal occupational exposure to trimethylsilyldiazomethane. North American Congress of Clinical Toxicology Annual Meeting, September 21-26, 2009, San Antonio, TX, USA, Clin Toxicol. 2009; 47(7):712.
16 Bray PA, Sokas RK. Delayed respiratory fatality from trimethylsilyldiazomethane: What do workers need to know about potentially hazardous exposures? J Occup Environ Med. 2015; 57(2):e15–e16. 10.1097/JOM.0000000000000281 25654529
17 Occupational Safety and Health Administration (OSHA). Letter from David Micheals, PhD: Request for nomination to the National Toxicology Testing Program for trimethylsilyldiazomethane (TMSD). Washington, DC: US Department of Labor; 2011.
18 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
19 Boorman G, Montgomery C Jr, Eustis S, Wolfe M, McConnell E, Hardisty J. Quality assurance in pathology for rodent carcinogenicity studies. In: Milman H, Weisburger E, editors. Handbook of Carcinogen Testing. Park Ridge, NJ: Noyes Publications; 1985. p. 345–357.
20 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
21 Armitage P. Tests for linear trends in proportions and frequencies. Biometrics. 1955; 11(3):375–386.10.2307/3001775
22 Dixon W, Massey F. Introduction to statistical analysis. New York, NY: McGraw Hill Book Company Inc; 1957.10.2307/2332898
23 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121.10.1080/01621459.1955.10501294
24 Williams D. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
25 Williams D. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
26 Jonckheere A. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41:133–145.10.1093/biomet/41.1-2.133
27 Code of Federal Regulations (CFR). 21: Part 58.
28 National Toxicology Program (NTP). TOX-101: Pathology tables, survival and growth curves from NTP short-term studies. Research Triangle Park, NC: US Department of Health and Human Services, Public Health Service, National Institutes of Health; 2021. 10.22427/NTP-DATA-TOX-101
29 National Toxicology Program (NTP). NTP Report on the toxicity studies of n-Hexane in B6C3F1 mice (inhalation studies)(CAS No. 110-54-3). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1991. NTP Tox 2. NIH Publication No. 91-3121. https://ntp.niehs.nih.gov/ntp/htdocs/st_rpts/tox002.pdf?utm_source=direct&utm_medium=prod&utm_campaign=ntpgolinks&utm_term=tox002
30 Kunczik J, Barbosa Pereira C, Zieglowski L, Tolba R, Wassermann L, Häger C, Bleich A, Janssen H, Thum T, Czaplik M. Remote vitals monitoring in rodents using video recordings. Biomed Opt Express. 2019; 10(9):4422–4436. 10.1364/boe.10.004422 31565499