# Discussion

Acute inhalation toxicity testing of trimethylsilyldiazomethane (TMSD), a synthetic methylating reagent widely used in organic chemistry, was performed in male Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and B6C3F1/N mice by the National Toxicology Program (NTP) because of reports of the death of two chemists exposed to TMSD in the workplace. Other concerns included the known inhalation toxicity of the related compound diazomethane and the absence of inhalation toxicity data for TMSD. Lung injury, peribronchial inflammation, pulmonary edema, and death have been reported in humans exposed to diazomethane.^8,10,11^

The two human case reports appeared to involve single, acute exposures to unknown concentrations of TMSD vapors. In the NTP studies, these exposure scenarios were mimicked in vivo by single exposures to TMSD in rats and mice; however, no significant adverse effects were observed in rats after a single exposure so multiple exposures were also tested in both species. A potential scenario involving more chronic or persistent (multiple) exposures in an occupational setting cannot be ruled out but has not been reported.

In the NTP studies, inhaled TMSD caused acute and progressive lung injury in both rats and mice at low vapor concentrations (≤10 ppm). Also, pulmonary toxicity in rats and mice was due to exposure specifically to TMSD vapors and not exposure to diazomethane vapors as a reaction byproduct of TMSD. Under the experimental conditions and with the exposure concentrations tested in this study, TMSD was more toxic in mice than in rats in that it caused labored breathing in 8/16 and 19/32 mice exposed to 3 and 10 ppm, respectively (compared to 4/32 rats exposed to 10 ppm) and was lethal after one to three exposures at 10 ppm in mice. The potency of TMSD was most evident in the findings of extensive lung injury, labored breathing, and death induced in mice after just a single 30-minute exposure to 10 ppm TMSD.

Peripheral lung effects at the bronchiolar/alveolar level were observed in rats and mice after exposure to TMSD. Histopathological effects in the lungs of both species included chronic-active inflammation, acute hemorrhage often with accompanying vascular congestion, pulmonary edema, bronchiolar and alveolar epithelial hyperplasia, interstitial fibrosis, and necrosis (only in mice). Overall, these adverse effects were observed in the lung at lower exposure concentrations in mice than in rats. The no-observed-effect level (NOEL) for pulmonary edema, which is an adverse lung effect previously reported after lethal exposure in humans, was <10 ppm in rats and <1 ppm in mice after only five repeated 30-minute exposures on 5 consecutive days. The NOEL for lung necrosis in mice was <3 ppm. TMSD was also observed to be profibrotic, inducing interstitial fibrosis in the lungs of rats and mice. The NOEL for interstitial fibrosis was <10 ppm in rats and <1 ppm in mice. The NOEL for this study overall was <0.3 ppm, based on increased lung weights in rats and mice. A NOEL of <0.3 ppm is approximately equal to the 8-hour time-weighted average occupational exposure limit of 0.2 ppm for diazomethane. Exposure-related adverse effects also were observed in the mediastinal lymph nodes (rats) and larynx (mice).

The vehicle for TMSD was a solution of mixed hexanes in air; however, hexanes at an exposure concentration (25 ppm) equivalent to the level of hexanes in the highest tested exposure concentration of TMSD (10 ppm) caused no adverse effects in rats or mice, which is consistent with a previous NTP study that showed n-hexane is toxic after 13 weeks of exposure, but only at much higher concentrations.^29^ The cause of death in mice was likely attributable to extensive lung necrosis and pulmonary edema resulting from TMSD-induced lung injury. Why rats are less sensitive than mice to the toxic effects of inhaled TMSD is unclear, but might be related to higher breathing rates in mice compared to rats^30^ and/or tissue dosimetry in the distal lung at the alveolar level.

In summary, the histopathological findings in rats and mice suggest that the toxic effects to the lung following short-term inhalation exposure to TMSD are progressive over time and consistent with the adverse effects (in particular, pulmonary edema) observed in the two human case reports for which pulmonary intoxication was lethal. The progressive nature of the lung injury induced by TMSD was most apparent by the presence of interstitial fibrosis in the 1 and 3 ppm TMSD-exposed mice at study termination in the 5-day exposure – recovery group, but not in the 5-day exposure group, which suggests that ongoing adverse post-inhalation exposure changes did not show evidence of resolving during the recovery period. In addition, adverse lung effects were observed in the 10 ppm-exposed mice of the 1-day exposure – recovery group but not in the 1-day exposure group.

These in vivo acute inhalation exposure data, including NOELs for increased lung weights and specific deleterious lung effects (such as necrosis, pulmonary edema, and interstitial fibrosis), can be used by the Occupational Safety and Health Administration and other agencies (e.g., the National Institute for Occupational Safety and Health) to help mitigate TMSD exposure risks in the production and use of TMSD in chemical laboratories. These data also can be used to update the Material Safety Data Sheet for TMSD (and other chemical reviews) and to alert chemical suppliers to the dangers of TMSD, which is readily available commercially and is considered a safer, less toxic alternative to diazomethane.