# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TOX-101.^28^

## Rats: One-day and Five-day Studies

All trimethylsilyldiazomethane (TMSD)-exposed rats survived until scheduled euthanasia (Table 3). Final mean body weights in the 1-day exposure and 1-day exposure – recovery groups were unaffected by TMSD exposure; however, the final mean body weights for all rats in the 1-day exposure group were lower than the initial mean body weights (Table 4; Figure 4A, Figure 4B). Final mean body weights were significantly decreased in the 5-day exposure and 5-day exposure – recovery groups compared to the air control groups at the highest TMSD exposure concentration (10 ppm) (Table 4; Figure 4C, Figure 4D). Final mean body weight gains in the 5-day exposure and 5-day exposure – recovery groups at 10 ppm TMSD were also significantly decreased relative to the air control groups.

Table 3 Summary of the Disposition of Male Rats in the One-day and Five-day Nose-only Inhalation Studies of Trimethylsilyldiazomethane

Exposure Group | 0 ppm (air) | 0 ppm (hexanes)^a^ | 0.3 ppm | 1 ppm | 3 ppm | 10 ppm
One-day Exposure^b^
Animals Initially in Study | 8 | 8 | –^c^ | – | – | 8
Early Deaths | 0 | 0 | – | – | – | 0
Scheduled Sacrifice, Terminal | 8 | 8 | – | – | – | 8
Animals Examined Microscopically | 8 | 8 | – | – | – | 8
One-day Exposure – Recovery^d^
Animals Initially in Study | 8 | 8 | – | – | – | 8
Early Deaths | 0 | 0 | – | – | – | 0
Scheduled Sacrifice, Terminal | 8 | 8 | – | – | – | 8
Animals Examined Microscopically | 8 | 8 | – | – | – | 8
Five-day Exposure^e^
Animals Initially in Study | 8 | 8 | 8 | 8 | 8 | 8
Early Deaths | 0 | 0 | 0 | 0 | 0 | 0
Scheduled Sacrifice, Terminal | 8 | 8 | 8 | 8 | 8 | 8
Animals Examined Microscopically | 8 | 8 | 0^f^ | 8 | 8 | 8
Five-day Exposure – Recovery^g^
Animals Initially in Study | 8 | 8 | 8 | 8 | 8 | 8
Early Deaths | 0 | 0 | 0 | 0 | 0 | 0
Scheduled Sacrifice, Terminal | 8 | 8 | 8 | 8 | 8 | 8
Animals Examined Microscopically | 8 | 8 | 8 | 8 | 8 | 8

^a^ Hexanes control contained an equivalent concentration of hexanes (25 ppm) as the 10 ppm TMSD-exposed group.

^b^ Animals were exposed on study day 0 and necropsied on study day 1.

^c^ Exposures at this concentration were not conducted for this group.

^d^ Animals were exposed on study day 0 and necropsied on study day 9.

^e^ Animals were exposed on study days 0–4 and necropsied on study day 5.

^f^ Slides were not evaluated because no effects (except for focal chronic-active inflammation) were observed in the 1 ppm TMSD-exposed group.

^g^ Animals were exposed on study days 0–4 and necropsied on study day 9.

Table 4 Summary of Mean Body Weights of Male Rats in the One-day and Five-day Nose-only Inhalation Studies of Trimethylsilyldiazomethane^a,b^

Exposure Group | Initial Body Weight (g) | Final Body Weight (g) | Changes in Body Weight (g) | Final Weight Relative to Controls (%)
One-day Exposure
0 ppm (air) | 268.7 ± 2.6 | 261.4 ± 2.4 | −7.3 ± 1.1 | –
0 ppm (hexanes)^c^ | 263.7 ± 6.5 | 260.9 ± 3.1 | −2.8 ± 4.4 | −0.2
10 ppm | 267.4 ± 3.3 | 258.6 ± 2.6 | −8.8 ± 1.1 | −1.1
One-day Exposure – Recovery
0 ppm (air) | 267.3 ± 2.7 | 302.5 ± 4.2 | 35.2 ± 1.9 | –
0 ppm (hexanes) | 271.3 ± 2.5 | 307.8 ± 3.3 | 36.5 ± 1.5 | 1.7
10 ppm | 263.9 ± 3.6 | 299.8 ± 4.0 | 35.9 ± 1.4 | −0.9
Five-day Exposure
0 ppm (air) | 272.4 ± 3.8 | 280.5 ± 4.1** | 8.1 ± 1.2** | –
0 ppm (hexanes) | 276.9 ± 2.9 | 283.3 ± 4.1 | 6.4 ± 1.8 | 1.0
0.3 ppm | 279.7 ± 2.9 | 287.4 ± 3.1 | 7.8 ± 1.0 | 2.5
1 ppm | 281.6 ± 1.5 | 288.4 ± 2.1 | 6.9 ± 1.1 | 2.8
3 ppm | 275.8 ± 2.1 | 280.4 ± 2.7 | 4.6 ± 1.6 | 0.0
10 ppm | 280.8 ± 2.6 | 247.5 ± 4.0** | −33.2 ± 2.9** | −11.7
Five-day Exposure – Recovery
0 ppm (air) | 280.2 ± 3.6 | 303.2 ± 3.6** | 23.0 ± 1.7** | –
0 ppm (hexanes) | 275.8 ± 2.7 | 296.5 ± 3.1 | 20.7 ± 3.2 | −2.2
0.3 ppm | 278.9 ± 2.7 | 306.0 ± 2.9 | 27.1 ± 1.6 | 0.9
1 ppm | 278.6 ± 2.4 | 301.7 ± 3.0 | 23.0 ± 1.0 | −0.5
3 ppm | 280.0 ± 2.0 | 303.0 ± 3.6 | 22.9 ± 2.5 | −0.1
10 ppm | 277.8 ± 1.8 | 271.6 ± 1.8** | −6.3 ± 1.5** | −10.4

Statistical significance for an exposure group indicates a significant pairwise test compared to the air control group. Statistical significance for the air control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Statistical analysis for the hexanes control group compared to the air control group was performed using the t-test.

Figure 4

Growth Curves for Male Rats in the One-day and Five-day Nose-only Inhalation Studies of Trimethylsilyldiazomethane

(A) 1-day exposure group, (B) 1-day exposure – recovery group, (C) 5-day exposure group, (D) 5-day exposure – recovery group.

Clinical observations affecting four or more of the eight rats exposed to 10 ppm TMSD in the 5-day exposure and/or 5-day exposure – recovery groups were ruffled coat between study day 2 and 9, discharge from nose/snout, and labored breathing; one rat exhibited hunched posture on study day 7 (Table 5). There were no exposure-related clinical observations in the 1-day exposure and 1-day – exposure recovery groups (Appendix D). Gross pathology observations in rats exposed to 10 ppm TMSD in both the 5-day exposure and 5-day exposure – recovery groups included mottled discoloration of the lung and enlarged, dark mediastinal lymph nodes. (Appendix D).

Table 5 Summary of Clinical Observations for Male Rats in the Five-day Nose-only Inhalation Study of Trimethylsilyldiazomethane

| 0 ppm (air) | 0 ppm (hexanes) | 0.3 ppm | 1 ppm | 3 ppm | 10 ppm
Five-day Exposure ^a^
Ruffled Coat | 0/8 | 0/8 | 0/8 | 0/8 | 0/8 | 4/8 (SD 2)
Discharge from Nose/Snout; Red | 0/8 | 0/8 | 0/8 | 0/8 | 0/8 | 4/8 (SD 4)
Five-day Exposure – Recovery
Ruffled Coat | 0/8 | 0/8 | 0/8 | 0/8 | 0/8 | 7/8 (SD 4)
Discharge from Nose/Snout; Red | 0/8 | 0/8 | 0/8 | 0/8 | 0/8 | 6/8 (SD 6)
Labored Breathing | 0/8 | 0/8 | 0/8 | 0/8 | 0/8 | 4/8 (SD 7)
Hunched Posture | 0/8 | 0/8 | 0/8 | 0/8 | 0/8 | 1/8 (SD 7)

SD = study day.

^a^ Upper row displays cumulative number of animals with observation/total animals started in study. Lower row displays SD of observation onset.

Mean absolute and relative lung weights were significantly decreased at 10 ppm TMSD in the 1-day exposure group and significantly increased at 10 ppm in the 1-day exposure – recovery group compared to the air control group (Table 6). Mean absolute and relative lung weights were significantly increased at 3 and 10 ppm in the 5-day exposure group and at all TMSD exposure concentrations in the 5-day exposure – recovery group compared to the air control group (Table 7). In the 5-day exposure group, mean absolute and relative weights of the right and left kidneys were significantly increased at 1 ppm; mean absolute and relative liver weights were significantly decreased at 10 ppm (Table 7). Mean absolute or relative weight changes for other organs (brain, right epididymis, heart, right and left testes, and thymus in the 5-day exposure group; brain, heart, right and left kidneys, liver, left testis, and thymus in the 5-day exposure – recovery group) were considered secondary to decreased body weight.

Table 6 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male Rats in the One-day Nose-only Inhalation Study of Trimethylsilyldiazomethane^a,b^

| 0 ppm (air) | 0 ppm (hexanes) | 10 ppm
n | 8 | 8 | 8
One-day Exposure
Necropsy Body Wt. (g) | 261.4 ± 2.4 | 260.9 ± 3.1 | 258.6 ± 2.6
Lung
Absolute (g) | 2.25 ± 0.11 | 2.07 ± 0.13 | 1.83 ± 0.11*
Relative (mg/g)^c^ | 8.63 ± 0.43 | 7.90 ± 0.45 | 7.06 ± 0.37*
One-day Exposure – Recovery
Necropsy Body Wt. (g) | 302.5 ± 4.2 | 307.8 ± 3.3 | 299.8 ± 4.0
Lung
Absolute (g) | 1.84 ± 0.06 | 1.97 ± 0.11 | 2.04 ± 0.06*
Relative (mg/g) | 6.08 ± 0.18 | 6.37 ± 0.31 | 6.82 ± 0.19*

Statistical significance for an exposure group indicates a significant pairwise test compared to the air control group.

* Statistically significant at p ≤ 0.05.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

Table 7 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male Rats in the Five-day Nose-only Inhalation Study of Trimethylsilyldiazomethane^a,b^

| 0 ppm (air) | 0 ppm (hexanes) | 0.3 ppm | 1 ppm | 3 ppm | 10 ppm
n | 8 | 8 | 8 | 8 | 8 | 8
Five-day Exposure
Necropsy Body Wt. (g) | 280.5 ± 4.1** | 283.3 ± 4.1 | 287.4 ± 3.1 | 288.4 ± 2.1 | 280.4 ± 2.7 | 247.5 ± 4.0**
Lung
Absolute (g) | 1.51 ± 0.04** | 1.56 ± 0.06 | 1.54 ± 0.04 | 1.69 ± 0.07 | 2.04 ± 0.07** | 4.52 ± 0.12**
Relative (mg/g)^c^ | 5.40 ± 0.15** | 5.49 ± 0.17 | 5.37 ± 0.15 | 5.85 ± 0.23 | 7.28 ± 0.23** | 18.25 ± 0.41**
R. Kidney
Absolute (g) | 0.88 ± 0.03 | 0.90 ± 0.02 | 0.94 ± 0.01 | 1.01 ± 0.03** | 0.88 ± 0.03 | 0.87 ± 0.03
Relative (mg/g) | 3.14 ± 0.07* | 3.17 ± 0.07 | 3.27 ± 0.04 | 3.50 ± 0.11* | 3.13 ± 0.07 | 3.49 ± 0.09*
L. Kidney
Absolute (g) | 0.86 ± 0.03 | 0.91 ± 0.02 | 0.94 ± 0.02 | 0.99 ± 0.03** | 0.88 ± 0.03 | 0.85 ± 0.02
Relative (mg/g) | 3.06 ± 0.09* | 3.23 ± 0.08 | 3.26 ± 0.06 | 3.44 ± 0.09** | 3.13 ± 0.08 | 3.42 ± 0.07**
Liver
Absolute (g) | 10.99 ± 0.35** | 10.93 ± 0.30 | 11.14 ± 0.29 | 11.84 ± 0.38 | 10.44 ± 0.42 | 8.24 ± 0.32**
Relative (mg/g) | 39.15 ± 0.87** | 38.57 ± 0.70 | 38.72 ± 0.74 | 41.04 ± 1.15 | 37.18 ± 1.23 | 33.26 ± 1.06**
Five-day Exposure – Recovery
Necropsy Body Wt. (g) | 303.2 ± 3.6** | 296.5 ± 3.1 | 306.0 ± 2.9 | 301.7 ± 3.0 | 303.0 ± 3.6 | 271.6 ± 1.8**
Lung
Absolute (g) | 1.75 ± 0.07** | 1.82 ± 0.08 | 2.33 ± 0.13** | 2.14 ± 0.16* | 2.67 ± 0.16** | 3.58 ± 0.07**
Relative (mg/g) | 5.76 ± 0.19** | 6.15 ± 0.24 | 7.59 ± 0.37** | 7.08 ± 0.51** | 8.78 ± 0.47** | 13.19 ± 0.24**

Statistical significance for an exposure group indicates a significant pairwise test compared to the air control group. Statistical significance for the air control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

### Pathology

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions of the lung and mediastinal lymph nodes in rats. Summaries of the incidences of nonneoplastic lesions and statistical analyses of primary nonneoplastic lesions are presented in Appendix D. All tissues evaluated were assigned a severity score using a scale of minimal (1), mild (2), moderate (3), or marked (4) representing the involvement of approximately <10%, 10%–25%, 26%–50%, or >50% of the affected tissue, respectively.

No exposure-related histopathological lesions were present in the 1-day exposure and 1-day exposure – recovery groups after a single exposure to TMSD in rats. Exposure-related histopathological lesions were observed in the lung and mediastinal lymph nodes in the 5-day exposure and 5-day exposure – recovery groups after 5 days of repeated exposure to TMSD in rats and are described below. No exposure-related histopathological changes were observed in the lung or mediastinal lymph nodes in the hexane control group.-

Lung: In the lung, exposure-related histopathological findings were observed at concentrations of 3 and 10 ppm TMSD in the 5-day exposure group compared to the air control group (Table 8, Figure 5). At 3 ppm TMSD, chronic-active inflammation was present in the lungs and was characterized by increased infiltrates of lymphocytes, histiocytes, and scattered neutrophils that infiltrated and expanded the alveolar, bronchiolar, and bronchial interstitia, and extended into the alveolar spaces. These histopathological changes also were associated with hyperplastic alveolar epithelia characterized by increased numbers of cuboidal to pleomorphic type II pneumocytes lining the alveolar walls. Frequently, the hyperplastic alveolar cells displayed increased nuclear:cytoplasmic ratio, prominent nucleoli, cellular pleomorphism, and mitotic figures. Hyperplastic bronchiolar epithelial cells also were observed and were characterized by increased numbers of bronchiolar epithelia lining terminal bronchioles. Histiocytic cellular infiltrates, composed of clusters of macrophages in the alveolar spaces, also were observed at 3 ppm TMSD (Figure 5). At 10 ppm TMSD, more advanced histopathological lesions were observed and consisted of chronic-active inflammation with interstitial fibrosis characterized by deposition of a fibrillar to slightly thickened eosinophilic matrix in the alveolar septa or subpleural areas, in addition to regions of acute hemorrhage and pulmonary edema (Figure 5). The pulmonary edema was present in most rats (7/8) in the 10 ppm TMSD 5-day exposure group and consisted of eosinophilic, homogeneous proteinaceous material that expanded the alveolar spaces and/or the interstitium. Pulmonary edema often was associated with large foamy histiocytic infiltrates in the alveolar spaces. Average severity scores of lesions observed in rats exposed to 3 ppm TMSD in the 5-day exposure group were classified as minimal; however, mean severity grades for lesions in the 10 ppm TMSD group ranged from minimal to mild (Table 8).

Table 8 Incidences of Nonneoplastic Lesions of the Lung, Mediastinal Lymph Node, and Larynx in Male Rats in the Five-day Nose-only Inhalation Study of Trimethylsilyldiazomethane^a^

| 0 ppm (air) | 0 ppm (hexanes) | 0.3 ppm | 1 ppm | 3 ppm | 10 ppm
Five-day Exposure
Lung^b^ | 8 | 8 | 0^c^ | 8 | 8 | 8
Inflammation, chronic-active^d^ | 0** | 0 | – | 0 | 7** (1.1)^e^ | 8** (2.8)
Infiltration, cellular, histiocyte | 0* | 0 | – | 0 | 7** (1.0) | 0
Interstitium, fibrosis | 0** | 0 | – | 0 | 0 | 8** (1.0)
Edema | 0** | 0 | – | 0 | 0 | 7** (2.3)
Hemorrhage, acute | 0** | 0 | – | 0 | 0 | 8** (1.0)
Alveolar epithelium, hyperplasia | 0** | 0 | – | 0 | 6** (1.0) | 8** (2.5)
Bronchiole epithelium, hyperplasia | 0** | 0 | – | 0 | 7** (1.0) | 8** (1.0)
Mediastinal Lymph Node | 8 | 8 | 0 | 7 | 8 | 8
Infiltration, cellular, histiocyte | 0** | 2 (1.0) | – | 0 | 1 (1.0) | 8** (2.0)
Larynx | 8 | 8 | 0 | 0 | 0 | 8
Epithelial cell, hyperplasia, squamous | 0 | 0 | – | – | – | 2 (1.0)
Epiglottis, metaplasia, squamous | 0 | 0 | – | – | – | 2 (1.0)
Five-day Exposure – Recovery
Lung | 8 | 8 | 8 | 8 | 8 | 8
Inflammation, chronic-active | 0** | 0 | 0 | 2 (1.0) | 8** (1.0) | 8** (2.6)
Infiltration, cellular, histiocyte | 0** | 0 | 1 (1.0) | 2 (1.0) | 8** (1.0) | 0
Interstitium, fibrosis | 0** | 0 | 0 | 0 | 0 | 8** (1.0)
Edema | 0** | 0 | 0 | 0 | 0 | 7** (1.9)
Hemorrhage, acute | 0** | 0 | 1 (1.0) | 1 (1.0) | 3 (1.0) | 8** (1.0)
Alveolar epithelium, hyperplasia | 0** | 0 | 0 | 1 (1.0) | 2 (1.0) | 8** (2.1)
Bronchiole epithelium, hyperplasia | 0** | 0 | 0 | 0 | 0 | 6** (1.0)
Mediastinal Lymph Node | 8 | 8 | 0 | 8 | 8 | 8
Infiltration, cellular, histiocyte | 1** (1.0) | 0 | – | 0 | 5 (1.0) | 8** (1.9)

Statistical significance for an exposure group indicates a significant pairwise test compared to the air control group. Statistical significance for the air control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^b^ Number of animals with tissue examined microscopically.

^c^ Slides not evaluated.

^d^ Number of animals with lesion.

^e^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 5

Representative Images of the Lung from Male Rats in the Five-day Nose-only Inhalation Study of Trimethylsilyldiazomethane (Five-day Exposure Group) (H&E)

(A) Lung from rat exposed to 0 ppm (air) showing terminal and respiratory bronchioles, alveolar ducts, and alveoli. (B) Lung from rat exposed to 3 ppm TMSD showing inflammatory cell infiltrates in the alveolar septa (severity grade = 1) with numerous histiocytes in the alveolar spaces (severity grade = 1). (C) Lung from rat exposed to 10 ppm TMSD showing chronic-active inflammation with acute hemorrhage (severity grade = 1) and extensive edema (severity grade = 4). Left panels are 4x and right panels are 20x.

In the lung, exposure-related histopathological findings were observed at concentrations ≥0.3 ppm TMSD in the 5-day exposure – recovery group compared to the air control group (Figure 6). Lesions were similar to those described for the 5-day exposure group. At the lowest exposure concentrations of TMSD (0.3 and 1 ppm), chronic-active inflammation, histiocytic infiltrates, acute hemorrhage, and alveolar epithelial hyperplasia were observed in a few animals in one or both groups (Table 8). At 3 ppm, the predominant lung lesions observed in rats were chronic-active inflammation and histiocytic cellular infiltrates in the alveoli, with a few rats showing alveolar epithelial hyperplasia (2/8) and acute hemorrhage (3/8) (Table 8; Figure 6). At 10 ppm, lung lesions consisted of areas of chronic-active inflammation within the alveolar, bronchiolar, and bronchial interstitia that extended into the alveolar spaces. Also, alveolar or bronchiolar hyperplasia, acute hemorrhage, pulmonary edema, and interstitial fibrosis were present (Table 8; Figure 6). Average severity grades of lesions observed in rats exposed to 0.3, 1, and 3 ppm TMSD in the 5-day exposure – recovery group were minimal; however, mean severity grades for lesions in the 10 ppm TMSD group ranged from minimal to mild (Table 8).

Figure 6

Representative Images of the Lung from Male Rats in the Five-day Nose-only Inhalation Study of Trimethylsilyldiazomethane (Five-day Exposure – Recovery Group) (H&E)

(A) Lung from rat exposed to 0 ppm (air) showing terminal and respiratory bronchioles, alveolar ducts, and alveoli. (B) Lung from rat exposed to 3 ppm TMSD showing chronic-active inflammation of the alveolar septa (severity grade = 1) with infiltrates of histiocytes in the alveolar spaces (severity grade = 1). (C) Lung from rat exposed to 10 ppm TMSD showing chronic-active inflammation (severity grade = 2) with hemorrhage (severity grade = 1) and interstitial fibrosis (severity grade=1). Left panels are 4x and right panels are 20x.

Mediastinal lymph node: In the mediastinal lymph node, the major TMSD-induced histopathological change was infiltrates of histiocytic cells that expanded the paracortex, medullar sinuses, and subcapsular sinuses that were present in the 5-day exposure and 5-day exposure – recovery groups after exposure to 3 or 10 ppm TMSD (Table 8).

Larynx: In the larynx, possible exposure-related histopathological findings were observed in two animals at 10 ppm TMSD in the 5-day exposure group: squamous epithelial hyperplasia and squamous epiglottis metaplasia (Table 8).

## Mice: One-day and Five-day Studies

Inhaled TMSD was more toxic in mice than in rats. All mice in the 1-day exposure group survived to study termination, whereas five mice in the 1-day exposure – recovery group, which were exposed to 10 ppm TMSD, died early between study days 3 and 6 (Table 9). In the 5-day exposure and 5-day exposure – recovery groups, all 10 ppm TMSD-exposed mice died or were euthanized early on study day 2 or 3 after only three exposures (none of the 10 ppm-exposed mice survived to study day 5 or 9, whereas mice in all other exposure groups survived to study termination) (Table 9).

Table 9 Summary of the Disposition of Male Mice in the One-day and Five-day Nose-only Inhalation Studies of Trimethylsilyldiazomethane

Exposure Group | 0 ppm (air) | 0 ppm (hexanes)^a^ | 0.3 ppm | 1 ppm | 3 ppm | 10 ppm
One-day Exposure^b^
Animals Initially in Study | 8 | 8 | –^c^ | – | – | 8
Early Deaths | 0 | 0 | – | – | – | 0
Scheduled Sacrifice, Terminal | 8 | 8 | – | – | – | 8
Animals Examined Microscopically | 8 | 8 | – | – | – | 8
One-day Exposure – Recovery^d^
Animals Initially in Study | 8 | 8 | – | – | – | 8
Early Deaths^e^
Found dead | 0 | 0 | – | – | – | 5
Scheduled Sacrifice, Terminal | 8 | 8 | – | – | – | 3
Animals Examined Microscopically | 8 | 8 | – | – | – | 8
Five-day Exposure^f^
Animals Initially in Study | 8 | 8 | 8 | 8 | 8 | 8
Early Deaths^g^
Euthanized, moribund | 0 | 0 | 0 | 0 | 0 | 2
Found dead | 0 | 0 | 0 | 0 | 0 | 6
Scheduled Sacrifice, Terminal | 8 | 8 | 8 | 8 | 8 | 0
Animals Examined Microscopically | 8 | 8 | 8 | 8 | 8 | 8
Five-day Exposure – Recovery^h^
Animals Initially in Study | 8 | 8 | 8 | 8 | 8 | 8
Early Deaths^i^
Euthanized, moribund | 0 | 0 | 0 | 0 | 0 | 1
Found dead | 0 | 0 | 0 | 0 | 0 | 7
Scheduled Sacrifice, Terminal | 8 | 8 | 8 | 8 | 8 | 0
Animals Examined Microscopically | 8 | 8 | 8 | 8 | 8 | 8

TMSD = trimethylsilyldiazomethane.

^a^ Hexanes control contained an equivalent concentration of hexanes (25 ppm) as the 10 ppm TMSD-exposed group.

^b^ Animals were exposed on study day 0 and necropsied on study day 1.

^c^ Exposures at this concentration were not conducted for this group.

^d^ Animals were exposed on study day 0 and necropsied on study day 9.

^e^ Two animals found dead on both study day 3 and study day 4 and one animal found dead on study day 6.

^f^ Animals were exposed on study days 0–4 and scheduled to be necropsied on study day 5.

^g^ Two animals euthanized moribund on study day 3; two animals found dead on study day 2; four animals found dead on study day 3 in the 10 ppm TMSD-exposed exposure group.

^h^ Animals were exposed on study days 0–4 and scheduled to be necropsied on study day 9.

^i^ One animal euthanized moribund on study day 3; two animals found dead on study day 2; five animals found dead on study day 3 in the 10 ppm TMSD-exposed exposure group.

Final mean body weights for the 1-day exposure group were unaffected by TMSD exposure; however, the final mean body weights for all mice in the 1-day exposure group were lower than the initial mean body weights. In the 1-day exposure – recovery group, final mean body weights of the three mice remaining at study day 9 were significantly decreased (26.8% less than the air control group); final mean body weight gain was also significantly decreased in this group (Table 10; Figure 7A and B). Final mean body weights were significantly decreased in the 5-day exposure group mice at 3 ppm (10.2% lower) and 10 ppm (16.5% lower) and also in the 5-day exposure – recovery group mice at 3 ppm (21.7% lower) and 10 ppm (18.4% lower) compared to the air control group (Table 10; Figure 7C and D). Final mean body weight gains were also significantly decreased in both the 5-day exposure group (3 ppm) and the 5-day exposure – recovery group (1 and 3 ppm).

Table 10 Summary of Mean Body Weights of Male Mice in the One-day and Five-day Nose-only Inhalation Studies of Trimethylsilyldiazomethane^a,b^

Exposure Group | Initial Body Weight (g) | Final Body Weight (g) | Changes in Body Weight (g) | Final Weight Relative to Controls (%)
One-day Exposure
0 ppm (air) | 28.1 ± 0.6 | 27.9 ± 0.5 | −0.2 ± 0.1 | –
0 ppm (hexanes)^c^ | 28.0 ± 0.5 | 27.7 ± 0.8 | −0.3 ± 0.4 | −0.7
10 ppm | 27.5 ± 0.9 | 27.2 ± 0.5 | −0.3 ± 0.5 | −2.7
One-day Exposure – Recovery
0 ppm (air) | 28.5 ± 0.4 | 29.3 ± 0.3* | 0.7 ± 0.3* | –
0 ppm (hexanes) | 28.2 ± 0.7 | 29.1 ± 0.8 | 0.9 ± 0.3 | −0.6
10 ppm^d^ | 28.1 ± 0.3 | 21.4 ± 1.5** | −6.5 ± 1.3** | −26.8
Five-day Exposure
0 ppm (air) | 28.8 ± 0.4 | 28.0 ± 0.6** | −0.8 ± 0.2* | –
0 ppm (hexanes) | 28.5 ± 0.6 | 27.9 ± 0.4 | −0.6 ± 0.5 | −0.2
0.3 ppm | 28.0 ± 0.2 | 27.6 ± 0.1 | −0.4 ± 0.2 | −1.3
1 ppm | 28.6 ± 0.2 | 28.3 ± 0.2 | −0.3 ± 0.1 | 1.1
3 ppm | 28.6 ± 0.4 | 25.1 ± 0.5** | −3.5 ± 0.3** | −10.2
10 ppm^e^ | 28.8 ± 0.6 | 23.8 ± 0.4** | NR | −16.5
Five-day Exposure – Recovery
0 ppm (air) | 28.4 ± 0.5 | 28.6 ± 0.5** | 0.3 ± 0.3** | –
0 ppm (hexanes) | 29.1 ± 0.6 | 29.9 ± 0.5 | 0.8 ± 0.2 | 4.5
0.3 ppm | 28.8 ± 0.3 | 29.9 ± 0.4 | 1.1 ± 0.3 | 4.4
1 ppm | 28.8 ± 0.4 | 28.0 ± 0.3 | −0.9 ± 0.3* | −2.3
3 ppm | 29.8 ± 0.5 | 22.4 ± 0.4** | −7.4 ± 0.3** | −21.7
10 ppm^f^ | 28.1 ± 0.6 | 23.0 ± 0.4** | NR | −18.4

Statistical significance for an exposure group indicates a significant pairwise test compared to the air control group. Statistical significance for the air control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

NR = not recorded.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Statistical analysis for the hexanes control group compared to the air control group was performed using the t-test.

^d^ Final body weight at study day (SD) 9 (n = 3).

^e^ Final body weight at SD 3 (n = 5). Change in body weight not reported for SD 3.

^f^ Final body weight at SD 3 (n = 6). Change in body weight not reported for SD 3.

Figure 7

Growth Curves for Male Mice in the One-day and Five-day Nose-only Inhalation Studies of Trimethylsilyldiazomethane

(A) 1-day exposure group, (B) 1-day exposure – recovery group, (C) 5-day exposure group, (D) 5-day exposure – recovery group. The number of animals in each exposure group for each study day is included in Table 9.

No abnormal clinical findings were observed in the 1-day exposure group. In the 1-day exposure – recovery group at 10 ppm, all mice exhibited labored breathing, ruffled coat, and lethargy beginning on study day 2; seven mice exhibited hunched posture beginning on study day 2; one mouse exhibited rapid breathing beginning on study day 4; and one mouse exhibited nasal discharge beginning on study day 3 (Table 11).

Table 11 Summary of Clinical Observations for Male Mice in the One-day and Five-day Nose-only Inhalation Studies of Trimethylsilyldiazomethane

| 0 ppm (air) | 0 ppm (hexanes) | 0.3 ppm | 1 ppm | 3 ppm | 10 ppm
One-day Exposure ^a^
No Abnormalities Found | 8/8 | 8/8 | – | – | – | 8/8
One-day Exposure – Recovery
Labored Breathing | 0/8 | 0/8 | – | – | – | 8/8 (SD 2)
Rapid Breathing | 0/8 | 0/8 | – | – | – | 1/8 (SD 4)
Ruffled Coat | 0/8 | 0/8 | – | – | – | 8/8 (SD 2)
Discharge from Nose/Snout, Clear | 0/8 | 0/8 | – | – | – | 1/8 (SD 3)
Hunched Posture | 0/8 | 0/8 | – | – | – | 7/8 (SD 2)
Lethargic | 0/8 | 0/8 | – | – | – | 8/8 (SD 2)
Five-day Exposure
Labored Breathing | 0/8 | 0/8 | 0/8 | 0/8 | 0/8 | 5/8 (SD 2)
Ruffled Coat | 0/8 | 0/8 | 0/8 | 0/8 | 5/8 (SD 2) | 8/8 (SD 2)
Hunched Posture | 0/8 | 0/8 | 0/8 | 0/8 | 1/8 (SD 5) | 5/8 (SD 2)
Five-day Exposure – Recovery
Labored Breathing | 0/8 | 0/8 | 0/8 | 0/8 | 8/8 (SD 6) | 6/8 (SD 2)
Ruffled Coat | 0/8 | 0/8 | 0/8 | 0/8 | 8/8 (SD 5) | 8/8 (SD 2)
Hunched Posture | 0/8 | 0/8 | 0/8 | 0/8 | 8/8 (SD 6) | 8/8 (SD 2)
Lethargic | 0/8 | 0/8 | 0/8 | 0/8 | 2/8 (SD 7) | 1/8 (SD 3)

SD = study day.

^a^ Upper row displays cumulative number of animals with observation/total animals started in study. Lower row displays SD of observation onset.

Clinical observations affecting five or more of the 3 ppm and/or 10 ppm-exposed mice in the 5-day exposure and 5-day exposure – recovery groups were labored breathing, ruffled coat, and hunched posture that began between study days 2 and 6; two mice were lethargic beginning on study day 7; one mouse was lethargic beginning on study day 3; and one mouse exhibited hunched posture beginning on study day 5 (Table 11). It is notable that when the 1-day exposure – recovery group and both 5-day exposure groups were combined, 8 of 16 (50%) of the 3 ppm-exposed mice and 19 of 24 (79%) of the 10 ppm-exposed mice exhibited labored breathing (Table 11).

In the 1-day exposure group, mean absolute and relative lung weights were significantly increased, whereas mean absolute and relative thymus weights were significantly decreased at 10 ppm (Table 12). In the 1-day exposure – recovery group, only three mice survived to scheduled necropsy on study day 9 due to early deaths. In the 1-day exposure – recovery group, mean absolute and relative weights of the lung were significantly increased at 10 ppm. Mean absolute and relative weights of the liver and thymus were significantly decreased at 10 ppm. Mean absolute weight of the heart was significantly decreased, whereas mean relative weight was significantly increased at 10 ppm (Table 12).

Table 12 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male Mice in the One-day Nose-only Inhalation Study of Trimethylsilyldiazomethane^a,b^

| 0 ppm (air) | 0 ppm (hexanes) | 10 ppm
One-day Exposure
n | 8 | 8 | 8
Necropsy Body Wt. (g) | 27.9 ± 0.5 | 27.7 ± 0.8 | 27.2 ± 0.5
Lung
Absolute (g) | 0.24 ± 0.02 | 0.23 ± 0.02 | 0.32 ± 0.02*
Relative (mg/g)^c^ | 8.43 ± 0.59 | 8.39 ± 0.49 | 11.68 ± 0.75**
Thymus
Absolute (g) | 0.040 ± 0.001 | 0.036 ± 0.002 | 0.032 ± 0.002**
Relative (mg/g) | 1.43 ± 0.08 | 1.29 ± 0.05 | 1.18 ± 0.07*
One-day Exposure – Recovery
n | 8 | 8 | 3
Necropsy Body Wt. (g) | 29.3 ± 0.3 | 29.1 ± 0.8 | 21.4 ± 1.5**
Lung
Absolute (g) | 0.25 ± 0.02 | 0.25 ± 0.02 | 0.42 ± 0.02**
Relative (mg/g) | 8.62 ± 0.51 | 8.48 ± 0.62 | 19.70 ± 2.09**
Heart
Absolute (g) | 0.15 ± 0.00 | 0.15 ± 0.00 | 0.12 ± 0.01**
Relative (mg/g) | 5.00 ± 0.08 | 5.04 ± 0.14 | 5.61 ± 0.15**
Liver
Absolute (g) | 1.50 ± 0.04 | 1.47 ± 0.06 | 0.95 ± 0.11**
Relative (mg/g) | 51.31 ± 0.88 | 50.38 ± 1.11 | 44.22 ± 1.99**
Thymus
Absolute (g) | 0.049 ± 0.002 | 0.048 ± 0.004 | 0.013 ± 0.003**
Relative (mg/g) | 1.67 ± 0.06 | 1.65 ± 0.11 | 0.60 ± 0.07**

Statistical significance for an exposure group indicates a significant pairwise test compared to the air control group.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

Mean absolute and relative lung weights were significantly increased at 0.3, 1, and 3 ppm in the 5-day exposure groups (n = 2 at 10 ppm due to early deaths or euthanasia) and at 1 and 3 ppm in the 5-day exposure – recovery group (n = 1 at 10 ppm due to early deaths or euthanasia) (Table 13). In both the 5-day exposure and the 5-day exposure – recovery groups, mean absolute and relative liver weights were significantly decreased at 3 ppm (Table 13). In the 5-day exposure – recovery group, significant decreases were observed in the mean absolute and relative weight of the right kidney and thymus at 3 ppm (Table 13). Mean absolute or relative weight changes for other organs (liver for 1-day exposure group; brain, right epididymis, right and left kidneys, and right and left testes for 1-day exposure – recovery group; brain, heart, right and left testes, right and left kidney, and thymus for 5-day exposure group; brain, right epididymis, heart, and right and left testes for 5-day exposure – recovery group) were considered secondary to decreased body weight.

Table 13 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male Mice in the Five-day Nose-only Inhalation Study of Trimethylsilyldiazomethane^a,b^

| 0 ppm (air) | 0 ppm (hexanes) | 0.3 ppm | 1 ppm | 3 ppm | 10 ppm
Five-day Exposure
n | 8 | 8 | 8 | 8 | 8 | 2
Necropsy Body Wt. (g) | 28.0 ± 0.6** | 27.9 ± 0.4 | 27.6 ± 0.1 | 28.3 ± 0.2 | 25.1 ± 0.5** | – ^c^
Lung
Absolute (g) | 0.25 ± 0.02** | 0.25 ± 0.02 | 0.31 ± 0.01** | 0.38 ± 0.01** | 0.45 ± 0.01** | –
Relative (mg/g)^d^ | 8.92 ± 0.53** | 8.78 ± 0.55 | 11.04 ± 0.49** | 13.31 ± 0.30** | 17.96 ± 0.45** | –
Liver
Absolute (g) | 1.38 ± 0.03** | 1.47 ± 0.05 | 1.31 ± 0.02 | 1.36 ± 0.02 | 1.06 ± 0.03** | –
Relative (mg/g) | 49.31 ± 0.69** | 52.54 ± 1.44 | 47.57 ± 0.42 | 48.14 ± 0.58 | 42.10 ± 0.52** | –
Five-day Exposure – Recovery
n | 8 | 8 | 8 | 8 | 8 | 1
Necropsy Body Wt. (g) | 28.6 ± 0.5** | 29.9 ± 0.5 | 29.9 ± 0.04 | 28.0 ± 0.3 | 22.4 ± 0.4** | –
Lung
Absolute (g) | 0.26 ± 0.02** | 0.23 ± 0.01 | 0.27 ± 0.01 | 0.41 ± 0.02** | 0.52 ± 0.01** | –
Relative (mg/g) | 9.17 ± 0.60** | 7.82 ± 0.29 | 8.91 ± 0.33 | 14.50 ± 0.51** | 23.30 ± 0.82** | –
R. Kidney
Absolute (g) | 0.23 ± 0.00** | 0.24 ± 0.00 | 0.24 ± 0.00 | 0.22 ± 0.00* | 0.17 ± 0.01** | –
Relative (mg/g) | 8.04 ± 0.09** | 7.90 ± 0.11 | 7.91 ± 0.13 | 7.78 ± 0.04 | 7.41 ± 0.14** | –
L. Kidney
Absolute (g) | 0.21 ± 0.01** | 0.21 ± 0.00 | 0.21 ± 0.00 | 0.19 ± 0.00* | 0.16 ± 0.00** | –
Relative (mg/g) | 7.29 ± 0.11* | 7.15 ± 0.13 | 7.07 ± 0.07 | 6.92 ± 0.07 | 6.92 ± 0.17 | –
Liver
Absolute (g) | 1.40 ± 0.02** | 1.49 ± 0.02 | 1.50 ± 0.03 | 1.35 ± 0.02 | 0.93 ± 0.03** | –
Relative (mg/g) | 49.05 ± 0.65** | 49.82 ± 0.58 | 50.06 ± 0.69 | 48.36 ± 0.43 | 41.54 ± 0.70** | –
Thymus
Absolute (g) | 0.042 ± 0.002** | 0.040 ± 0.001 | 0.041 ± 0.002 | 0.038 ± 0.003 | 0.013 ± 0.001** | –
Relative (mg/g) | 1.48 ± 0.06** | 1.33 ± 0.04 | 1.38 ± 0.08 | 1.36 ± 0.11 | 0.59 ± 0.04** | –

Statistical significance for an exposure group indicates a significant pairwise test compared to the air control group. Statistical significance for the air control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Weights are not provided because not enough animals survived to scheduled necropsy.

^d^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

Gross pathology findings in the 10 ppm TMSD-exposed mice included mottled discoloration of the lung in the 1-day exposure – recovery group; this finding also was present in the 3 ppm and 10 ppm TMSD-exposed mice in the 5-day exposure and 5-day exposure – recovery groups (Appendix D).

### Pathology

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions of the lung and larynx in mice. Summaries of the incidences of nonneoplastic lesions and statistical analyses of primary nonneoplastic lesions are presented in Appendix D. All tissues evaluated were assigned a severity grade using a scale of minimal (1), mild (2), moderate (3), or marked (4) representing involvement of approximately <10%, 10%–25%, 26%–50%, or >50% of the affected tissue, respectively.

No exposure-related histopathological lesions were present in mice in the 1-day exposure group after a single exposure to TMSD. As described below, exposure-related histopathological lesions were observed in the lung and larynx in the 1-day exposure – recovery group at 10 ppm (Table 14) and in the 5-day exposure and 5-day exposure – recovery groups after 5 days of repeated exposure to 1 or 3 ppm TMSD and 2 or 3 days of exposure to 10 ppm TMSD (Table 15). No exposure-related histopathological changes were observed in the lung or larynx in the hexane control group.

Table 14 Incidences of Nonneoplastic Lesions of the Lung and Larynx in Male Mice in the One-day Nose-only Inhalation Study of Trimethylsilyldiazomethane^a^

One-day Exposure – Recovery Group | 0 ppm (air) | 0 ppm (hexanes) | 10 ppm
n^b^ | 8 | 8 | 8^c^
Lung
Inflammation, acute^d^ | 0 | 0 | 5* (1.2)^e^
Inflammation, chronic-active | 0 | 0 | 3 (1.7)
Infiltration, cellular, histiocyte | 2 (1.0) | 0 | 3 (1.3)
Interstitium, fibrosis | 0 | 0 | 3 (2.0)
Edema | 0 | 0 | 5* (2.4)
Hemorrhage, acute | 0 | 0 | 5* (1.0)
Alveolar epithelium, hyperplasia | 0 | 0 | 4* (2.3)
Bronchiole epithelium, hyperplasia | 0 | 0 | 3 (1.0)
Necrosis | 0 | 0 | 5* (2.0)
Larynx
Squamous epithelium, hyperplasia | 0 | 0 | 5* (1.2)
Squamous epithelium, ulcer | 0 | 0 | 1 (1.0)
Inflammation, acute | 0 | 0 | 4* (1.0)

Statistical significance for an exposure group indicates a significant pairwise test compared to the air control group.

* Statistically significant at p ≤ 0.05.

^a^ Statistical analysis performed by Fisher’s exact (pairwise) test.

^b^ Number of animals examined microscopically.

^c^ Only three animals survived until scheduled termination; two animals each were found dead on study day (SD) 3 and SD 4; one animal was found dead on SD 6.

^d^ Number of animals with lesion.

^e^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Table 15 Incidences of Nonneoplastic Lesions of the Lung and Larynx in Male Mice in the Five-day Nose-only Inhalation Study of Trimethylsilyldiazomethane^a^

| 0 ppm (air) | 0 ppm (hexanes) | 0.3 ppm | 1 ppm | 3 ppm | 10 ppm^b^
Five-day Exposure
Lung^c^ | 8 | 8 | 8 | 8 | 8 | 8
Inflammation, acute^d^ | 0** | 0 | 0 | 0 | 0 | 8** (1.8)^e^
Inflammation, chronic-active | 0** | 0 | 0 | 0 | 8** (1.9) | 0
Infiltration, cellular, histiocyte | 0** | 0 | 0 | 7** (1.0) | 0 | 0
Edema | 0** | 0 | 0 | 7** (1.0) | 8** (1.4) | 8** (2.0)
Hemorrhage, acute | 0* | 0 | 0 | 0 | 8** (1.0) | 8** (1.1)
Alveolar epithelium, hyperplasia | 0 | 0 | 0 | 0 | 8** (1.1) | 0
Bronchiole epithelium, hyperplasia | 0 | 0 | 0 | 0 | 8** (1.0) | 0
Necrosis | 0** | 0 | 0 | 0 | 8** (2.3) | 8** (2.8)
Larynx | 8 | 8 | 0 | 0 | 8 | 7
Squamous epithelium, hyperplasia | 0 | 0 | – ^f^ | – | 0 | 2 (1.0)
Squamous epithelium, ulcer | 0* | 0 | – | – | 0 | 3 (1.0)
Inflammation, acute | 0 | 0 | – | – | 0 | 1 (1.0)
Five-day Exposure – Recovery
Lung | 8 | 8 | 8 | 8 | 8 | 8
Inflammation, acute | 0** | 0 | 0 | 0 | 0 | 8** (1.9)
Inflammation, chronic-active | 0 | 0 | 0 | 8** (1.9) | 8** (2.9) | 0
Infiltration, cellular, histiocyte | 0 | 1 (1.0) | 0 | 0 | 0 | 0
Interstitium, fibrosis | 0 | 0 | 0 | 8** (1.0) | 8** (1.6) | 0
Edema | 0** | 0 | 0 | 0 | 6** (1.7) | 8** (2.3)
Hemorrhage, acute | 0** | 0 | 0 | 1 (1.0) | 7** (1.0) | 7** (1.0)
Alveolar epithelium, hyperplasia | 0 | 0 | 0 | 8** (1.8) | 8** (3.4) | 0
Bronchiole epithelium, hyperplasia | 0 | 0 | 0 | 8** (1.0) | 8** (3.0) | 0
Necrosis | 0** | 0 | 0 | 0 | 8** (1.5) | 8** (2.4)
Larynx | 8 | 8 | 0 | 8 | 8 | 8
Squamous epithelium, hyperplasia | 0 | 0 | – | 0 | 3 (1.0) | 1 (1.0)
Squamous epithelium, ulcer | 0* | 0 | – | 0 | 4* (1.0) | 4* (1.0)
Inflammation, acute | 0 | 0 | – | 0 | 5* (1.0) | 0

Statistical significance for an exposure group indicates a significant pairwise test compared to the air control group. Statistical significance for the air control indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^b^ No animals survived until scheduled termination. In the 5-day exposure group, two animals were found dead on study day (SD) 2 and four on SD 3, and two animals were euthanized moribund on SD 3. In the 5-day exposure – recovery group, two animals were found dead on SD 2 and five on SD 3, and one animal was euthanized moribund on SD 3.

^c^ Number of animals examined microscopically.

^d^ Number of animals with lesion.

^e^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

^f^ Slides not evaluated because no effect was observed at 3 ppm.

Lung: No histopathological changes were observed in the lungs of mice in the 1-day exposure group at 10 ppm TMSD compared to the air control group. Histopathological changes observed in the 1-day exposure – recovery group mice at 10 ppm TMSD included acute and chronic-active inflammation, histiocytic infiltrates within alveoli, interstitial fibrosis, pulmonary edema, necrosis, acute hemorrhage, and hyperplasia of the alveolar or bronchiolar epithelium (Table 14). Average severity grades of these lesions were minimal to mild (Table 14); five mice in this exposure group were found dead between study day 3 and 6 (Table 9). Exposure-related histopathological findings were observed at concentrations of 1, 3, and 10 ppm TMSD in the 5-day exposure group (Table 15; Figure 8). At 1 ppm TMSD, lesions consisted of histiocytic cellular infiltrates in the alveoli, characterized by variable numbers of histiocytes in the alveolar spaces, and pulmonary edema that consisted of faint eosinophilic fibrillar fluid within the alveolar spaces (Figure 8). At 3 ppm TMSD, histopathological findings were more severe and consisted of chronic-active inflammation characterized by infiltrating histiocytes, lymphocytes, fewer neutrophils that were admixed with fibrin, in addition to necrosis and necrotic cellular debris, acute hemorrhage, and pulmonary edema that ranged from an eosinophilic fibrillar to homogenous fluid. Areas of alveolar epithelial hyperplasia also occurred, which were characterized by alveolar walls lined by cuboidal to pleomorphic type II pneumocytes with large, round nuclei, prominent nucleoli, and variably frequent mitoses. Bronchioles also were hyperplastic and were occasionally lined by piling epithelial cells (Figure 8). At 10 ppm TMSD, acute hemorrhage characterized by red blood cells within the alveolar spaces and interstitium and acute inflammation, pulmonary edema, and necrosis were observed in mice exposed for 2 or 3 days and euthanized or found dead on study day 2 or 3. Necrosis in the lung was quite evident and characterized by loss of alveolar septal architecture and replacement with necrotic cellular debris and fibrin (Figure 8).

Figure 8

Representative Images of the Lung from Male Mice in the Five-day Nose-only Inhalation Study of Trimethylsilyldiazomethane (Five-day Exposure Group) (H&E)

(A) Lung from mouse exposed to 0 ppm (air) showing terminal bronchiole and alveoli. (B) Lung from mouse exposed to 1 ppm TMSD showing histiocytic cell infiltrates (severity grade = 1) in the alveolar sacs mixed with fine eosinophilic fibrillar fluid. (C) Lung from mouse exposed to 3 ppm TMSD showing inflammatory cell infiltrates (severity grade = 2) in the alveolar spaces mixed with eosinophilic fibrillar fluid; also, focal necrosis of the alveolar septa (severity grade = 2). (D) Lung from mouse exposed to 10 ppm TMSD (necropsy on study day 2) showing area of necrosis (severity grade = 4) mixed with acute inflammatory cell infiltrates (severity grade = 1), fibrinous debris, edema (severity grade = 3), and focal hemorrhage (severity grade = 2). Left panels are 4x and right panels are 20x.

In the 5-day exposure group, average severity grades of lesions observed in mice exposed to 1 and 3 ppm TMSD were minimal to mild. At 10 ppm TMSD, severity grades for lesions ranged from minimal to moderate (Table 15); all mice in this exposure group were euthanized or found dead on study day 2 or 3 (Table 9).

In the 5-day exposure – recovery group, exposure-related histopathological lesions of the lung were identified in mice exposed to 1 and 3 ppm TMSD at scheduled necropsy on study day 9 (Table 15; Figure 9). Histopathological findings included chronic-active inflammation characterized by infiltrating histiocytes, lymphocytes, fewer neutrophils that were admixed with fibrin, and pulmonary edema (3 ppm only). Alveolar and bronchiolar epithelial cell hyperplasia, acute hemorrhage, necrosis (3 ppm only), and interstitial fibrosis characterized by increased collagen fibers expanding the alveolar septa or surrounding bronchioles were present (Figure 9). Often, the fibrosis was associated with inflammation. At 10 ppm TMSD, acute hemorrhage, acute inflammation, pulmonary edema, and necrosis were observed in mice exposed for 2 or 3 days and euthanized or found dead at study day 2 or 3. In the 5-day exposure – recovery group, average severity grades of lesions observed at necropsy in mice exposed to 1, 3, or 10 ppm TMSD were minimal to moderate (Table 15); all mice in the 10 ppm group were euthanized or found dead on study day 2 or 3 (Table 9).

Figure 9

Representative Images of the Lung from Male Mice in the Five-day Nose-only Inhalation Study of Trimethylsilyldiazomethane (Five-day Exposure – Recovery Group) (H&E)

(A) Lung from mouse exposed to 0 ppm (air) showing terminal bronchiole, alveolar duct, and alveoli. (B) Lung from mouse exposed to 1 ppm TMSD showing chronic-active inflammation (severity grade = 2) of the alveolar septa with early interstitial fibrosis (severity grade = 1). (C) Lung from mouse exposed to 3 ppm TMSD showing chronic-active inflammation (severity grade = 3) with alveolar and bronchiolar epithelial hyperplasia (severity grade = 4 and severity grade = 3, respectively), necrosis (severity grade = 1), and interstitial fibrosis (severity grade = 2). Left panels are 4x and right panels are 20x.

Larynx: In the larynx, exposure-related histopathological lesions were observed at concentrations of 10 ppm TMSD in the 1-day exposure – recovery group (Table 14) and in the 5-day exposure group (Table 15) and at concentrations of 3 and 10 ppm TMSD in the 5-day exposure – recovery group (Table 15; Figure 9) compared to the air control groups. These histopathological lesions consisted of hyperplasia and ulceration of the squamous epithelium in both the 3 and 10 ppm TMSD groups, with acute inflammation characterized by neutrophils infiltrating the mucosa and submucosa of the larynx present in mice in the 3 ppm group (Figure 10).

Figure 10

Representative Images of the Larynx from Male Mice in the Five-day Nose-only Inhalation Study of Trimethylsilyldiazomethane (Five-day Exposure – Recovery Group) (H&E)

(A) Larynx from mouse exposed to 0 ppm (air). (B) Larynx from mouse exposed to 3 ppm TMSD showing hyperplasia and ulceration (severity grade = 1) of the squamous epithelium with acute inflammatory cell infiltrates (severity grade = 1) in the submucosa and mucosa and adjacent hemorrhagic debris. Left panels are 4x and right panels are 20x.