# Materials and Methods

## Procurement and Characterization of Trimethylsilyldiazomethane

Trimethylsilyldiazomethane (TMSD), 2 M in a solution of mixed hexanes, was obtained from Sigma-Aldrich (St. Louis, MO) in a single lot (SHBB9290V). A mixture of hexanes only (no TMSD) was obtained from Sigma-Aldrich (St. Louis, MO) in a single lot (SHBF3717V) and used as a control. Reports on analyses performed to support the TMSD study are on file at the National Institute of Environmental Health Sciences (NIEHS).

The identity and purity of lot SHBB9290V of TMSD and of lot SHBF3717V of mixed hexanes were determined at the study laboratory. The identities of TMSD and hexanes were confirmed by ^1^H and ^13^C nuclear magnetic resonance (NMR) spectroscopy. The concentration of TMSD, determined using ^1^H NMR, was 2.65 M. Gas chromatography with mass selective detection (GC/MSD) was used to identify the major peaks and any peak areas ≥0.1% of the total peak area.

The mass spectra of lot SHBB9290V of TMSD contained nine peaks ≥0.1% by area. In addition to the primary TMSD peak (36.1%) and a (chloromethyl)trimethylsilane peak (3.30%), two major peaks consistent with n-hexane (33.6%) and methylcyclopentane (25.7%) were identified. The remaining peaks were all <2% of the total peak area and accounted for additional hydrocarbons and impurities related to TMSD (Table A-1).

The mass spectra of lot SHBF3717V of mixed hexanes consisted of five peaks ≥0.1% by total peak area, all of which were isomers of hexane. The major peaks for n-hexane, methylcyclopentane, and 3-methylpentane were 64.2%, 17.4%, and 16.7% of the total peak area, respectively. Peaks for 2-methylpentane and cyclohexane were <2% of the total peak area (Table A-2).

After scheduled termination of the animals, bulk chemical and mixed hexanes control materials were reanalyzed by the study laboratory using GC/MSD. Analysis indicated no statistically significant differences in the purities of TMSD and hexanes control materials relative to a frozen reference standard.

## Vapor Generation and Exposure System

A schematic of the TMSD vapor generation and delivery system is shown in Figure 2. The system consisted of two parts: the vaporization subsystem and the delivery subsystem. Both subsystems were housed in a glove box. The generation and delivery system for the hexanes control was similar to that for the TMSD system.

Figure 2

Trimethylsilyldiazomethane Generation, Distribution, and Exposure System

TMSD was pumped to the vaporization column using a syringe pump capable of delivering a stable and precisely determined flow of chemical to the generator. The syringe needle was inserted in the vaporizer column through a septum. Air entered the column from the bottom, vaporized the chemical, and carried it to the delivery system.

The exposure vapor was directed to a pneumatic slide valve. This valve served as the exposure on-off valve and was operated by a solenoid actuated by the exposure control unit (ECU). During “on-exposure” periods, the slide valve was actuated, and the vapor was directed through the valve to the exposure carousel. At each exposure carousel, vapor was delivered uniformly to each nose tube.

During “off-exposure” periods when animals were loaded or removed from each carousel, filtered and conditioned air was supplied to each exposure carousel from the facility compressed air system. Also during this period, the exposure vapor air stream was directed through a scrubber system within the glove box prior to facility exhaust.

The animals were exposed in nose-only inhalation carousels developed at Battelle. The rodent exposure carousel (Figure 2) consisted of stackable tiers with eight nose-only exposure ports per tier. Each stainless-steel exposure unit consisted of three modules providing 24 ports for animal exposure and test atmosphere sampling. Vented enclosures mounted on stainless-steel stands surrounded each exposure carousel and were designed to contain the exposure units. This carousel design provided uniform concentration and fresh aerosol of test chemical to each animal connected to the exposure system. The test atmosphere entered the carousel through the top. After filling an inlet manifold, the test atmosphere flowed radially to each of eight evenly spaced ports into each animal containment tube mounted on one of three different levels of the carousel. This design minimized any effect of the animals on the atmosphere because no exhaled air from one animal could reach the breathing zone of another. The temperature and humidity of the aerosol systems were not monitored or controlled and corresponded to the ambient conditions in the room.

One end of the tube that restrained the individual animal was tapered to approximately fit the shape of the animal’s head, and the diameter of the cylindrical portion of the tube was configured such that it was difficult for the animal to turn in the tube. The back portion of the tube was covered with a plastic cap. The tube containing the animal was fastened to the inhalation carousel by a bracket with the nose portion of the tube protruding into the carousel.

## Vapor Concentration Monitoring

XAD-4 sorbent tubes were used for sampling TMSD and hexanes control exposure atmospheres. Sample flow rates and sampling times were documented (approximately 0.45 L/min for 30 minutes). Tube contents (front beds, back beds, and glass wool plugs) were transferred into 15 mL vials and extracted with 4 mL of 1,2,4-trimethylbenzene with vortexing for 15 minutes. Sample aliquots were transferred to GC vials with limited volume inserts for GC/MSD analysis. Samples were compared to solvent standard curves for TMSD and n-hexane as a component of the TMSD test article and n-hexane as a component of the mixed hexanes control article. The analysis was performed at the Battelle Columbus test site using an Agilent 6890 GC equipped with a 5973N MSD using the instrument settings listed in Table A-11. Average measured TMSD and hexanes concentrations for the 1-day and 5-day exposures are shown in Table 1.

Table 1 Summary of Target and Measured Trimethylsilyldiazomethane and Total Hexanes Concentrations for Male Rats and Mice in the One-day and Five-day Nose-only Inhalation Studies^a^

Exposure Group | Target TMSD Concentrations (ppm) | Measured TMSD Concentrations (ppm) | | Measured Total Hexanes Concentrations (ppm)
Exposure Group | Target TMSD Concentrations (ppm) | Rats | Mice | Rats | Mice
One-day Exposure | Room air | ND | ND | BLOQ | ND
One-day Exposure | Filtered air (0) | ND | ND | BLOQ | ND
One-day Exposure | Hexanes^b^ (0) | NA | NA | 25.1 ± 0.7 | 24.1 ± 0.6
One-day Exposure | 10 | 11.3 ± 1.0 | 11.2 ± 0.2 | 26.9 ± 1.6 | 27.1 ± 0.6
Five-day Exposure | Room air | ND | ND | BLOQ | BLOQ
Five-day Exposure | Filtered air (0) | ND | ND | BLOQ | BLOQ
Five-day Exposure | Hexanes^b^ (0) | NA | NA | 24.5 ± 1.4 | 25.6 ± 1.5
Five-day Exposure | 0.3 | 0.283 ± 0.047 | 0.299 ± 0.031 | 0.845 ± 0.098 | 1.05 ± 0.07
Five-day Exposure | 1 | 1.06 ± 0.10 | 1.04 ± 0.17 | 3.20 ± 0.21 | 3.48 ± 0.37
Five-day Exposure | 3 | 2.87 ± 0.25 | 2.68 ± 0.16 | 7.96 ± 0.45 | 7.90 ± 0.31
Five-day Exposure | 10 | 10.3 ± 0.8 | 10.2 ± 0.7 | 25.4 ± 1.6 | 25.3 ± 1.2

ND = not detectable; NA = not applicable; BLOQ = below limit of quantitation.

^a^ Data shown as mean ± standard deviation.

^b^ The target hexanes concentration was 25 ppm.

## Chamber Atmosphere Characterization

For homogeneity analysis, TMSD and hexanes sampling ports were sampled at the Battelle West Jefferson testing facility onto XAD-4 sorbent tubes for 30 minutes at a flow rate of approximately 0.45 L/min. At each concentration, six samples were shipped refrigerated to the Battelle Columbus test site: two from the top tier, two from the middle, and two from the bottom, for a total n = 6 for each target concentration. In each tier, two individual samples came from ports 2 and 6. The averaged results by tier for each target concentration to evaluate the homogeneity between the carousel locations and the averaged determined concentrations for each concentration to evaluate homogeneity of the entire carousel are presented in Table A-12, Table A-13, and Table A-14.

A condensation particle counter (Model 3022A; TSI Incorporated; St. Paul, MN) was used to count the particles before the start of generation and during generation. Particle counts <200 particles/cm^3^ are typical of an exposure atmosphere when no generation is occurring. Particle counts above this level, especially if the counts increase with exposure concentration and are above the level during the off-exposure period, suggest a contribution to the aerosol concentration due to the generation system. The results of the particle count measurements are given in Table A-15. The data indicate no concentrations >200 particles/cm^3^, either before or during the exposures; hence, the generation systems did not add particles to the aerosol concentration.

Analysis of generated vapor concentrations during the evaluation of exposure system homogeneity indicated reproducible TMSD and hexanes concentrations during 30-minute exposures of both rats and mice. The exposure system demonstrated homogeneity, with the carousel sampling within 10% relative standard deviation (RSD) for TMSD and total hexanes component concentrations in TMSD and hexanes. Final evaluation of target concentrations indicated that the TMSD vapor concentrations could be maintained between 15% and 20% of target. Relative consistency of the total hexanes concentrations was observed, with RSDs within 10% to 15% in respective exposure groups. Because the vapor generation was predicated on achieving TMSD targets, values for hexanes concentrations could have been biased toward concentrations associated with specific generator settings; therefore, relative error was not reported for hexanes.

## Animal Source

Male Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN). Male B6C3F1/N mice were obtained from Taconic Biosciences, Inc. (Germantown, NY).

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Battelle Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health and National Toxicology Program (NTP) animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Exposure Concentration Selection Rationale

A pilot study was performed (data not shown) to select a range of TMSD exposure concentrations to avoid high mortality or, alternatively, no chemical-induced effects. In the pilot study, rats and mice (approximately 8–10 weeks old) were exposed by nose-only inhalation to TMSD at Battelle. During the prestart exposure system characterization, animals were exposed by nose-only inhalation to targeted vapor concentrations of 0 (air), 0.2, 1, 5, or 20 ppm TMSD (n = 2/exposure concentration) for 30 minutes per day for up to three exposures. The highest TMSD exposure concentration tested (20 ppm) was selected on the basis of findings from an acute inhalation toxicity study with diazomethane in rabbits.^12^ The lowest TMSD exposure concentration tested (0.2 ppm) was selected for the pilot study because it is the occupational exposure limit (OEL; 8-hour time-weighted average [TWA]) for diazomethane. Both 20 ppm-exposed mice were found dead following the second exposure, and the lowest achievable exposure concentration was approximately 0.3 ppm. The exposure concentrations for the main study were adjusted accordingly on the basis of the outcomes of this pilot study.

Concentrations of 0 (air), 0 (hexanes), 0.3, 1, 3, and 10 ppm were selected to characterize the acute TMSD inhalation exposure response. The hexanes control generator for the 0 (hexanes) control group was set to a concentration equal to the estimated total hexanes content (25 ppm) in the 10 ppm TMSD generator. This was done to assess the effects of hexanes exposure alone at approximately an equivalent hexanes exposure concentration to that present in the highest TMSD exposure groups. Although the proportions of the individual hexane isomers varied between the TMSD lot and the mixed hexanes lot, the compositions of the test and control articles were sufficiently similar to determine whether hexanes were responsible for toxicity associated with exposure to TMSD.

## Health and Safety

As with all NTP studies, extensive effort was expended to ensure the health and safety of study personnel, but this effort was undertaken with utmost consideration in this study of TMSD (see Appendix A) given the reported fatalities. There are no short-term (e.g., 10- to 30-minute) or 8-hour TWA daily occupational exposure limits for TMSD. An OEL of 0.1 ppm, however, was referenced in a Sigma-Aldrich TMSD Safety Data Sheet. For diazomethane, a similar chemical, the 8-hour TWA Occupational Safety and Health Administration (OSHA) permissible exposure limit (PEL) and the American Conference of Governmental Industrial Hygienists (ACGIH) threshold limit value (TLV) are both 0.2 ppm. For n-hexane, the OSHA PEL is 500 ppm, the ACGIH TLV is 50 ppm, and the National Institute for Occupational Safety and Health (NIOSH) 10-hour TWA recommended exposure limit (REL) also is 50 ppm.

Occupational action levels typically are 50% of a TLV. Exceeding an action level in a work environment would prompt evaluation of the effectiveness of controls and might trigger additional engineering and administrative controls to limit personnel exposure, supplemented with increased use of appropriate personal protective equipment. Battelle therefore used 0.1 ppm TMSD (a value listed as the OEL in a TMSD Safety Data Sheet and that is 50% of the TLV for diazomethane) as its OEL.

## One-day and Five-day Studies

Rats and mice were approximately 7 to 8 weeks old on receipt; they were quarantined for 11 days and were approximately 9 to 11 weeks old on the first day of the studies. Rats and mice were uniquely identified and randomly assigned to one of six exposure groups before the start of the study. Randomization was stratified by body weight that produced similar group mean weights using NTP Provantis software (Instem, Sone, UK).

Before the studies began, 10 rats and 10 mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Additionally, the health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Groups of eight male rats and eight male mice were exposed to 0 (air), 0 (hexanes), or 10 ppm TMSD (in hexanes) by nose-only inhalation for 1 day (30 minutes) with or without a 9-day recovery period after exposure (1-day exposure, 1-day exposure – recovery). In addition, groups of eight male rats and eight male mice were exposed to 0 (air), 0 (hexanes), 0.3, 1, 3, or 10 ppm TMSD (in hexanes) by nose-only inhalation for up to 5 days (30 minutes/day) with or without a 5-day recovery period after exposure (5-day exposure, 5-day exposure – recovery). The 0 (hexanes) control group was exposed to 25 ppm hexanes only (0 ppm TMSD), which is the concentration of hexanes in the highest TMSD exposure concentration (10 ppm). For the groups without a recovery phase (1-day exposure and 5-day exposure), animals were necropsied the day after the single or final exposure, respectively. For the groups with a recovery phase, animals were necropsied 9 days after the single exposure (1-day exposure – recovery) or 5 days after the final exposure (5-day exposure – recovery). Details of the study design are summarized in Figure 3.

Figure 3

Experimental Design in the One-day and Five-day Nose-only Inhalation Studies of Trimethylsilyldiazomethane

SD = study day.

Feed and water were available ad libitum except during exposures. Rats and mice were pair housed upon receipt and during the first week of quarantine and were individually housed thereafter. Rats and mice were observed twice daily for signs of mortality or moribundity. After the onset of dyspnea following exposure, animals were observed every 1–2 hours postexposure until 11:00 p.m. for signs of moribundity/mortality. Formal clinical observations were recorded twice daily on exposure days (once before and once after exposure), once daily during recovery, and prior to necropsy. Individual body weights were recorded daily for all animals in the study. Further details of animal maintenance are summarized in Table 2. Information on feed composition and contaminants is provided in Appendix B.

Table 2 Experimental Design and Materials and Methods in the One-day and Five-day Nose-only Inhalation Studies of Trimethylsilyldiazomethane

Rats | Mice
Study Laboratory
Battelle (Columbus, OH) | Same as rats
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) | B6C3F1/N
Animal Source
Envigo (formerly Harlan Laboratories, Inc.; Indianapolis, IN) | Taconic Biosciences, Inc. (Germantown, NY)
Time Held before Studies
1-day exposure studies: 11 days 5-day exposure studies: 13 days | 1-day exposure studies: 12 days 5-day exposure studies: 18 days
Average Age When Studies Began
1-day exposure studies: 9 weeks 5-day exposure studies: 10 weeks | 1-day exposure studies: 9 to 10 weeks 5-day exposure studies: 10 to 11 weeks
Date of First Exposure
1-day exposure studies: October 12, 2015 5-day exposure studies: October 14, 2015 | 1-day exposure studies: October 13, 2015 5-day exposure studies: October 19, 2015
Duration of Exposure
1 day or 5 days | Same as rats
Date of Last Exposure
1-day exposure studies: October 12, 2015 5-day exposure studies: October 18, 2015 | 1-day exposure studies: October 13, 2015 5-day exposure studies: October 23, 2015
Necropsy Dates
1-day exposure: October 13, 2015 1-day exposure – recovery: October 21, 2015 5-day exposure: October 19, 2015 5-day exposure – recovery: October 23, 2015 | 1-day exposure: October 14, 2015 1-day exposure – recovery: October 22, 2015 5-day exposure: October 24, 2015 5-day exposure – recovery: October 28, 2015
Average Age at Necropsy
1-day exposure studies: 9 to 11 weeks 5-day exposure studies: 10 to 11 weeks | 1-day exposure studies: 10 to 11 weeks 5-day exposure studies: 11 to 12 weeks
Size of Study Groups
8 males | Same as rats
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as rats
Animals per Cage
1 | Same as rats
Method of Animal Identification
Tail tattoo and cage card | Same as rats
Diet
NTP-2000 irradiated wafer feed (Zeigler Brothers Inc., Gardners, PA), available ad libitum except during exposure, changed at least once weekly | Same as rats^a^
Water
Tap water (West Jefferson, OH municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum except during exposure | Same as rats
Cages
Solid polycarbonate (Lab Products, Inc., Seaford, DE); changed weekly | Same as rats
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corporation, Montville, NJ), changed with cage changes | Same as rats
Rack Filters
Spun-bonded polyester (Snow Filtration Company, Cincinnati, OH), changed at least every 2 weeks | Same as rats
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated at least every 2 weeks | Same as rats
Animal Room Environment
Temperature: 72°F ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Same as rats
Exposure Concentrations
1-day exposure studies: 0 (air), 0 (hexanes), 10 ppm TMSD (in hexanes) by nose-only inhalation 5-day exposure studies: 0 (air), 0 (hexanes), 0.3, 1, 3, or 10 ppm TMSD (in hexanes) by nose-only inhalation | Same as rats
Type and Frequency of Observation
Observed twice daily and every 1 to 2 hours postexposure following the last scheduled clinical observation of the day until 11:00 p.m. Animals were weighed daily. Clinical observations were recorded twice daily on exposure days and once daily during recovery and on the day of removal from study. | Same as rats
Method of Euthanasia
Exsanguination while under CO_2_/O_2_ anesthesia | Same as rats
Necropsy
Necropsies were performed on all animals. Organs weighed were brain, left and right epididymis, heart, left and right kidney, liver, lung, left and right testis, and thymus. | Necropsies were performed on all animals. Organs weighed were brain, left and right epididymis, heart, left and right kidney, liver, lung, left and right testis, and thymus. No organ weights were determined for animals that died early.
Histopathology
Histopathological evaluations of brain (7 sections including [1] olfactory bulbs, [2] front-parietal cortex including basal ganglia, [3] mid-parietal cortex and thalamus, [4] mid-brain with substantia nigra and red nucleus, [5] posterior colliculi, [6] mid-cerebellum including cranial nerve VIII, and [7] posterior medulla), gross lesions, heart and aorta, kidney (left), larynx, liver (two sections including left lateral lobe and median lobe), lung and mainstem bronchi (left), nasal cavity and nasal turbinates (3 sections), nerve (sciatic, tibial, and trigeminal with ganglion), mediastinal lymph nodes, pharynx, and trachea were performed as available on all study rats. Organs/tissues were examined to a no-effect level, as were corresponding tissues, in the 0 ppm air and hexanes control animals. | Same as rats

^a^ One feeder on one occasion was changed after 11 days.

Necropsies were performed on all animals. Organ weights were determined for the brain, liver, thymus, left and right kidneys, left and right testes, left and right epididymides, heart, and lung from all animals that survived to scheduled sacrifice or were euthanized early due to moribund condition (no organ weights were determined for animals that died early). Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes, which were first fixed in Davidson’s solution, and testes and epididymides, which were first fixed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4–6 μm, and stained with hematoxylin and eosin. Complete histopathological examinations were performed by the study laboratory pathologist for all animals (including those that died early) on the nasal cavity and turbinates, larynx, pharynx, trachea, left lung and mainstem bronchi, mediastinal lymph nodes, heart and aorta, left kidney, liver, brain, and peripheral nerves (sciatic and trigeminal nerves with ganglion; tibial nerve in rats only). This evaluation was conducted to a no-effect level and included the corresponding tissues in the air control group and hexanes control group. Table 2 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathological slides by a quality assessment (QA) pathologist, the findings in the respiratory system and any discrepancies between the study laboratory pathologist (SP) and QA pathologist were reviewed by an NTP Pathology Working Group (PWG). Any inconsistencies in the diagnoses made by the SP and QA pathologist were resolved through the NTP pathology peer-review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the SP, NTP pathologists, and QA pathologist. Details of these review procedures have been described, in part, by Maronpot and Boorman^18^ and Boorman et al.^19^

## Statistical Methods

For all statistical analyses, pairwise and trend comparisons were performed between the exposed groups and the air control group. A separate pairwise comparison was performed between the hexanes control group and the air control group.

### Calculation and Analysis of Nonneoplastic Lesion Incidences

The incidences of nonneoplastic lesions are presented as numbers of animals bearing such lesions at a specific anatomical site and the numbers of animals with that site examined microscopically. Fisher’s exact (pairwise) test,^20^ a procedure that uses the overall proportion of affected animals, was used to determine significance between TMSD-exposed and air control animals, and also between the hexanes control animals and air control animals. The Cochran-Armitage trend test was used to test for significant trends.^21^ All p values for lesion incidence were calculated using one-sided tests.

### Analysis of Continuous Variables

Before statistical analysis, extreme values identified by the outlier test of Dixon and Massey^22^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

Pairwise comparisons between exposed and air control groups in the analysis of organ and body weight data, which historically have approximately normal distributions, were performed using the parametric multiple comparison procedures of Dunnett^23^ and Williams.^24,25^ The Jonckheere test^26^ was used to assess the significance of the exposure-related trends and to determine whether the trend-sensitive test (the Williams test) was more appropriate for pairwise comparisons than would be the test that does not assume a monotonic exposure-related trend (the Dunnett test). For the comparisons between the hexanes control group and the air control group for organ and body weights, a Student t-test was used.^22-26^

## Quality Assurance Methods

The 1-day and 5-day studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^27^ In addition, the 1-day and 5-day study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Report.