# Introduction

Trimethylsilyldiazomethane (TMSD) (Figure 1) is a methylating reagent widely used in organic chemistry and analytical methods.^1-7^ TMSD is commonly used for the derivatization of carboxylic acid groups (e.g., R-COOH) for the production of methyl esters (e.g., R-COOCH_3_). Methyl esters are amenable to analysis by gas chromatography (GC) and thus are ideal derivatives for the characterization of carboxylic acids via GC.

Figure 1

Trimethylsilyldiazomethane (CASRN 18107-18-1; Chemical Formula: C_4_H_10_N_2_Si; Molecular Weight: 114.22)

Synonyms: (Trimethylsilyl) diazomethane; diazo(trimethylsilyl)methane; diazomethyl(trimethyl)silane; (diazomethyl)trimethylsilane; diazomethyltrimethyl silane; silane, (diazomethyl)trimethyl-; TMS-diazomethane; TMSCHN_2_.

## Background

TMSD is related to the toxic compound diazomethane which is highly reactive (flammable and explosive). Diazomethane was previously reported to cause severe pulmonary injury, chemical pneumonitis, and death in humans after inhalation exposure.^2,8-11^ An acute inhalation toxicity study was described for diazomethane in which rabbits were exposed to atmospheres containing 2–12 ppm diazomethane (one to four exposures for 5–20 minutes/exposure). This exposure regimen induced bronchopneumonia and death by day 7.^12^ Inhalation exposure of cats to 175 ppm diazomethane for 10 minutes was also reported to be lethal within 3 days.^12^ The occupational exposure limit (OEL) for diazomethane is 0.2 ppm (8-hour time-weighted average). This concentration was chosen on the basis of limited exposure data and because diazomethane is thought to have a similar mechanism of action to that of phosgene.^13^ These animal toxicity data and the OEL for diazomethane are reported in the Hazardous Substances Data Bank.^12^

## Chemical Use and Human Exposure

TMSD is less reactive than diazomethane and is considered a safer, less toxic alternative^2-4,6^; however, few toxicity data for TMSD are available to support this claim. TMSD is currently readily sold commercially by chemical suppliers in solvents such as hexane or diethyl ether.^2-4,6^ Exposure to TMSD in an occupational setting (e.g., a chemical laboratory) is most likely to occur via dermal contact and/or inhalation, although a dermal toxicity study in rabbits concluded that TMSD (approximately 1,000 mg/kg) was not acutely toxic via dermal exposure.^12,14^ No inhalation studies with TMSD were performed before the current National Toxicology Program (NTP) studies were initiated.

## Case Reports

Accidental exposure to TMSD in the workplace resulted in the death of two chemists, one in the United States and one in Canada, in 2008.^15-17^ The deaths occurred approximately 15 (U.S. case report) and 26 (Canadian case report) hours after exposure to TMSD. Both deaths were determined to be the result of acute respiratory distress syndrome from lung injury believed to have been caused by exposure to TMSD. Extensive pleural and pericardial effusion, marked congestion of the lung, and histopathological findings that included the presence of delayed, massive, and diffuse pulmonary edema were reported in the autopsy findings from the U.S. incident. Both exposed individuals initially reported “asthma-like” symptoms (including cough, pleuritic chest pain, and severe, progressive dyspnea), suggesting airway/lung effects. In the U.S. case report, TMSD (in diethyl ether solvent) was spilled outside a fume hood and some contacted the individual’s skin (potential for both inhalation and dermal exposure). In the Canadian case study, the individual was working with TMSD (in hexane solvent) in a nonfunctioning fume hood and there was no evidence of dermal contact (potential for inhalation exposure only), suggesting that dermal contact was not required for lethal exposure in humans. Inhalation of TMSD was the common route of exposure in both cases. It was not clear whether the chemists were exposed specifically to TMSD vapors or whether the exposure was in fact to diazomethane vapors as a reaction byproduct of TMSD.

## Study Rationale

The Occupational Safety and Health Administration (OSHA) nominated TMSD to NTP for toxicity testing largely as the result of the accidental deaths of two chemists in 2008. Other reasons for the nomination included the known inhalation toxicity of the related compound diazomethane and the lack of toxicity data for TMSD.^17^ Due to these considerations, the objective of this NTP study was to evaluate the acute inhalation toxicity of TMSD in vivo. Specifically, the aim was to determine whether acute inhalation exposure to TMSD induces asthma-like symptoms and lung injury (including pulmonary edema) in male rats and mice as described in the human case reports and, if so, at what exposure concentrations. The study was conducted only on males given that TMSD is a very reactive chemical and no sex-related differences were expected. Some exposure groups were euthanized 24 hours after the last exposure and some groups were held after cessation of chemical exposure to determine whether lung lesions progressed or resolved over time. These in vivo acute inhalation exposure data can be used by OSHA and other agencies (e.g., National Institute for Occupational Safety and Health) to help mitigate TMSD exposure risks in the production and use of TMSD in chemical laboratories. These data also can be used to update the Material Safety Data Sheet for TMSD (and other chemical reviews) and to alert chemical suppliers to the dangers of TMSD.