# Appendix D Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TOX-101.

## D.1 Study Tables – Rats

I01 – Animal Removal Summary

I02 – Animal Removals

I03 – Growth Curves

I04 – Mean Body Weight Summary

I04G – Mean Body Weight Gain

I05 – Clinical Observations Summary

PA02 – Neoplastic Lesion Summary with Percent Incidence

PA03 – Non-Neoplastic Lesion Summary with Percent Incidence

PA05 – Incidence Rates of Neoplastic Lesions with Systemic Lesions Abridged

PA06 – Organ Weights Summary

PA08 – Statistical Analysis of Neoplastic Lesions

PA10 – Statistical Analysis of Non-Neoplastic Lesions

PA14 – Individual Animal Pathology Data

PA18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grade

PA46 – Summary of Gross Pathology

## D.2 Individual Animal Data – Rats

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Gross Pathology Data

Individual Animal Histopathology Data

Individual Animal Organ Weight Data

Individual Animal Removal Reasons Data

## D.3 Study Tables – Mice

I01 – Animal Removal Summary

I02 – Animal Removals

I03 – Growth Curves

I04 – Mean Body Weight Summary

I04G – Mean Body Weight Gain

I05 – Clinical Observations Summary

PA02 – Neoplastic Lesion Summary with Percent Incidence

PA03 – Non-Neoplastic Lesion Summary with Percent Incidence

PA05 – Incidence Rates of Neoplastic Lesions with Systemic Lesions Abridged

PA06 – Organ Weights Summary

PA08 – Statistical Analysis of Neoplastic Lesions

PA10 – Statistical Analysis of Non-Neoplastic Lesions

PA14 – Individual Animal Pathology Data

PA18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grade

PA46 – Summary of Gross Pathology

## D.4 Individual Animal Data – Mice

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Gross Pathology Data

Individual Animal Histopathology Data

Individual Animal Organ Weight Data

Individual Animal Removal Reasons Data