# Appendix C Sentinel Animal Program

## C.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that might affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or exposed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

For these toxicity studies, blood samples were collected and allowed to clot, and the serum was separated. All samples were processed appropriately with serology testing sent to IDEXX BioResearch (formerly Rodent Animal Diagnostic Laboratory [RADIL], University of Missouri), Columbia, MO, for determination of the presence of pathogens. Evaluation for endo- and ectoparasites was performed in-house by the testing laboratory.

The laboratory methods and agents for which testing was performed are listed below; the times at which samples were collected during the studies are also listed in Table C-1. and Table C-2.

Table C-1 Methods and Results for Sentinel Animal Testing in Rats

One-day and Five-day Exposure Studies
Collection Time Point | Quarantine
Number Examined (Males) | 10
Method/Test
Multiplex Fluorescent Immunoassay
Kilham rat virus (KRV) | −
Mycoplasma pulmonis | −
Parvo NS-1 | −
Pneumonia virus of mice (PVM) | −
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | −
Rat minute virus (RMV) | −
Rat parvo virus (RPV) | −
Rat theilovirus (RTV) | −
Sendai | −
Theiler's murine encephalomyelitis virus (TMEV) | −
Toolan’s H–1 | −
In-house Evaluation
Endoparasite evaluation (evaluation of cecal content) | −
Ectoparasite evaluation (evaluation of perianal surface) | −

– = negative result.

Table C-2 Methods and Results for Sentinel Animal Testing in Mice

One-day and Five-day Exposure Studies
Collection Time Point | Quarantine
Number Examined (Males) | 10
Method/Test
Multiplex Fluorescent Immunoassay
Ectromelia virus | −
Epizootic diarrhea of infant mice (EDIM) | −
Lymphocytic choriomeningitis virus (LCMV) | −
Mycoplasma pulmonis | −
Mouse hepatitis virus (MHV) | −
Mouse norovirus (MNV) | −
Parvo NS-1 | −
Mouse parvovirus (MPV) | −
Minute virus of mice (MVM) | −
Pneumonia virus of mice (PVM) | −
Rat theilovirus (RTV) | −
Reovirus (REO3) | −
Sendai | −
Theiler’s murine encephalomyelitis virus (TMEV) GDVII | −
In-house Evaluation
Endoparasite evaluation (evaluation of cecal content) | −
Ectoparasite evaluation (evaluation of perianal surface) | −

– = negative result.

## C.2 Results

All test results were negative.