# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Rat and Mouse Ration

Table B-1 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 23.00
Ground #2 Yellow Shelled Corn | 22.44
Wheat Middlings | 15.0
Oat Hulls | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5
Purified Cellulose | 5.5
Soy Protein Concentrate | 4.0
Fish Meal (60% Protein) | 4.0
Corn Oil (without Preservatives) | 3.0
Soy Oil (without Preservatives) | 3.0
Dried Brewer’s Yeast | 1.0
Calcium Carbonate (USP) | 0.9
Vitamin Premix^a^ | 0.5
Mineral Premix^b^ | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4
Sodium Chloride | 0.3
Choline Chloride (70% Choline) | 0.26
Methionine | 0.2

USP = United States Pharmacopeia.

^a^ Rice hulls and limestone as carrier.

^b^ Calcium carbonate as carrier.

Table B-2 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration^a^

| Amount | Source
Vitamins
Vitamin A | 4,000 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 1,000 IU | D-activated animal sterol
Vitamin K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | 100 IU | –
Niacin | 23 mg | –
Folic Acid | 1.1 mg | –
α-Pantothenic Acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 μg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished product.

Table B-3 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.85 ± 0.495 | 14.5–15.2 | 2
Crude Fat (% by Weight) | 8.15 ± 0.071 | 8.1–8.2 | 2
Crude Fiber (% by Weight) | 9.96 ± 0.205 | 9.81–10.1 | 2
Ash (% by Weight) | 5.09 ± 0.141 | 4.99–5.19 | 2
Amino Acids (% of Total Diet)
Arginine | 0.805 ± 0.075 | 0.67–0.97 | 29
Cystine | 0.220 ± 0.021 | 0.15–.25 | 29
Glycine | 0.702 ± 0.038 | 0.62–0.80 | 29
Histidine | 0.342 ± 0.070 | 0.27–0.68 | 29
Isoleucine | 0.549 ± 0.040 | 0.43–0.66 | 29
Leucine | 1.100 ± 0.063 | 0.96–1.24 | 29
Lysine | 0.700 ± 0.104 | 0.31–0.86 | 29
Methionine | 0.409 ± 0.042 | 0.26–0.49 | 29
Phenylalanine | 0.623 ± 0.047 | 0.471–0.72 | 29
Threonine | 0.513 ± 0.041 | 0.43–0.61 | 29
Tryptophan | 0.155 ± 0.027 | 0.11–0.2 | 29
Tyrosine | 0.422 ± 0.066 | 0.28–0.54 | 29
Valine | 0.666 ± 0.040 | 0.55–0.73 | 29
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.94 ± 0.235 | 3.49–4.55 | 29
Linolenic | 0.297 ± 0.064 | 0.005–0.368 | 29
Vitamins
Vitamin A (IU/kg) | 5,980 ± 416 | 3,040–8,920 | 2
α-Tocopherol (ppm) | 2,456 ± 12,817 | 13.6–69,100 | 29
Thiamine (ppm)^a^ | 8.6 ± 0.990 | 7.9–9.3 | 2
Riboflavin (ppm) | 8.17 ± 2.841 | 4.2–17.5 | 29
Niacin (ppm) | 78.66 ± 8.11 | 66.4–98.2 | 29
Pantothenic Acid (ppm) | 26.42 ± 11.05 | 17.4–81.0 | 29
Pyridoxine (ppm)^a^ | 9.75 ± 2.045 | 6.44–14.3 | 29
Folic Acid (ppm) | 1.58 ± 0.43 | 1.15–3.27 | 29
Biotin (ppm) | 0.323 ± 0.093 | 0.2–0.704 | 29
Vitamin B_12_ (ppb) | 50.41 ± 34.89 | 18.3–174 | 29
Choline (as Chloride) (ppm) | 2,593 ± 633.8 | 1,160–3,790 | 29
Minerals
Calcium (%) | 0.928 ± 0.091 | 0.863–0.992 | 2
Phosphorus (%) | 0.571 ± 0.008 | 0.565–0.577 | 2
Potassium (%) | 0.668 ± 0.029 | 0.626–0.733 | 29
Chloride (%) | 0.392 ± 0.044 | 0.3–0.517 | 29
Sodium (%) | 0.195 ± 0.027 | 0.16–0.283 | 29
Magnesium (%) | 0.217 ± 0.054 | 0.185–0.49 | 29
Iron (ppm) | 191.6 ± 36.18 | 135–311 | 29
Manganese (ppm) | 50.11 ± 9.42 | 21–73.1 | 29
Zinc (ppm) | 57.3 ± 25.54 | 43.3–184 | 29
Copper (ppm) | 7.57 ± 2.49 | 3.21–16.3 | 29
Iodine (ppm) | 0.513 ± 0.221 | 0–0.972 | 29
Chromium (ppm) | 1.02 ± 1.04 | 0.33–3.97 | 28
Cobalt (ppm) | 0.222 ± 0.152 | 0.0857–0.864 | 27

^a^ As hydrochloride.

Table B-4 Contaminant Levels in NTP-2000 Rat and Mouse Ration

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.253 ± 0.023 | 0.236–0.269 | 2
Cadmium (ppm) | 0.049 ± 0.006 | 0.045–0.053 | 2
Lead (ppm) | 0.0875 ± 0.032 | 0.065–0.11 | 2
Mercury (ppm)^a^ | 0.01 ± 0.0 | 0.01–0.01 | 2
Selenium (ppm) | 0.1745 ± 0.006 | 0.17–0.179 | 2
Aflatoxins (ppb)^a^ | <5.0 | – | 2
Nitrate Nitrogen (ppm)^b^ | 15.85 ± 0.354 | 15.6–16.1 | 2
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | – | 2
BHA (ppm)^a,c^ | <1.00 | – | 2
BHT (ppm)^a,c^ | <1.00 | – | 2
Aerobic Plate Count (CFU/gm) | <10.0 | – | 2
Coliform (MPN/gm) | <3 | – | 2
Escherichia coli (MPN/gm)^a^ | <3.0 | – | 2
Salmonella (MPN/gm) | Negative | – | 2
Total Nitrosamines (ppb)^d^ | 10.6 ± 3.04 | 8.4–12.7 | 2
N,N-Dimethylamine (ppb)^d^ | 1.6 ± 2.26 | 0.0–3.2 | 2
N,N-Pyrrolidine (ppb)^d^ | 9.0 ± 0.78 | 8.4–9.5 | 2
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 2
β-BHC^a^ | <0.02 | – | 2
γ-BHC^a^ | <0.01 | – | 2
δ-BHC^a^ | <0.01 | – | 2
Heptachlor^a^ | <0.01 | – | 2
Aldrin^a^ | <0.01 | – | 2
Heptachlor Epoxide^a^ | <0.01 | – | 2
DDE^a^ | <0.01 | – | 2
DDD^a^ | <0.01 | – | 2
DDT^a^ | <0.01 | – | 2
HCB^a^ | <0.01 | – | 2
Mirex^a^ | <0.01 | – | 2
Methoxychlor^a^ | <0.05 | – | 2
Dieldrin^a^ | <0.01 | – | 2
Endrin^a^ | <0.01 | – | 2
Telodrin^a^ | <0.01 | – | 2
Chlordane^a^ | <0.05 | – | 2
Toxaphene^a^ | <0.10 | – | 2
Estimated PCBs^a^ | <0.20 | – | 2
Ronnel^a^ | <0.01 | – | 2
Ethion^a^ | <0.02 | – | 2
Trithion^a^ | <0.05 | – | 2
Diazinon^a^ | <0.10 | – | 2
Methyl Chlorpyrifos | 0.092 ± 0.024 | 0.075–0.109 | 2
Methyl Parathion^a^ | <0.02 | – | 2
Ethyl Parathion^a^ | <0.02 | – | 2
Malathion | 0.02 ± 0.0 | 0.02–0.02 | 2
Endosulfan I^a^ | <0.01 | – | 2
Endosulfan II^a^ | <0.01 | – | 2
Endosulfan Sulfate^a^ | <0.03 | – | 2

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ If all values were below the detection limit, the detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.