# Appendix A Chemical Characterization and Generation of Exposure Concentrations

## A.1 Procurement and Characterization of Trimethylsilyldiazomethane

Trimethylsilyldiazomethane (TMSD), 2 M in a solution of mixed hexanes (CASRN 18107-18-1, lot SHBB9290V), and the hexanes control article, a mixture of hexanes only (no TMSD) (referred to as hexanes control; CASRN not provided, lot SHBF3717V), were originally obtained from Sigma-Aldrich (Saint Louis, MO) via Government Scientific Source, Inc. (Reston, VA). Both the test article and hexanes control article were received from the National Institute of Environmental Health Sciences (NIEHS) chemistry support services contractor, Battelle, on May 6, 2015, at the Battelle Columbus test site. At the time of receipt, aliquots of the test article and hexanes control article were taken and stored frozen at −20°C to serve as frozen reference samples. Reports on analyses performed in support of the TMSD studies are on file at NIEHS.

Identification and purity analyses were performed by the testing laboratory. The identities were determined by ^1^H and ^13^C nuclear magnetic resonance (NMR) spectroscopy (Figure A-2, Figure A-3, Figure A-4, Figure A-5). The concentration of TMSD in the mixed hexanes solution was determined by ^1^H NMR spectroscopy using an internal standard and was 2.65 M, which was slightly higher than 2.1 M specified in the manufacturer’s certificate of analysis. Gas chromatography with mass selective detection (GC/MSD) was used to identify the major peaks and any degradants or impurities with areas ≥0.1% of the total peak area (Figure A-6, Figure A-7). Additional purity analyses were performed throughout the study by GC/MSD using area percent purity profiles and major peak area comparisons to frozen reference samples of each material.

For the TMSD and mixed hexanes test and control articles, triplicate replicates of the bulk articles were prepared in 1,2,4-trimethylbenzene. In addition, standards of potential hexane components or impurities, n-hexane, methylcyclopentane, (chloromethyl)trimethylsilane, and 3-methylpentane observed in the chemical identity and purity screen were prepared in 1,2,4-trimethylbenzene. All samples were analyzed using an Agilent (Santa Clara, CA) 6890 GC equipped with a 5973N MSD. The mass spectra of lot SHBB9290V of TMSD contained 9 peaks ≥0.1% by area. In addition to the primary TMSD peak (36.1%) and a (chloromethyl)trimethylsilane peak (3.30%), two major peaks were consistent with the mixed hexanes solution: n-hexane (33.6%) and methylcyclopentane (25.7%). The remaining peaks were all <2% of the total peak area and accounted for additional hydrocarbons and impurities related to TMSD (Table A-1). The mass spectra of lot SHBF3717V of mixed hexanes consisted of five peaks ≥0.1% by total peak area, all of which were isomers of hexane. The major peaks for n-hexane, methylcyclopentane, and 3-methylpentane were 64.2%, 17.4%, and 16.7% of the total peak area, respectively. Peaks for 2-methylpentane and cyclohexane were <2% of the total peak area (Table A-2).

Stability analysis of the TMSD and hexanes standard solutions in 1,2,4-trimethylbenzene met the criterion for stability up to 7 days when stored refrigerated, with the relative error (RE) within 15% of the initial concentrations. Stability of TMSD and hexanes on XAD-4 sorbent (unextracted) and in solution with 1,2,4-trimethylbenzene (extracted) was demonstrated at refrigerated temperatures up to 7 days. The stability of TMSD during storage on unextracted sorbent at refrigerated temperatures was better than storage in extracted form. The average RE of the low- and high-exposure unextracted samples were within 6% of the respective initial concentrations for TMSD, whereas the extracted samples were within 18%. No significant difference was found between the two methods of storage for total hexanes in either TMSD or hexanes control groups. The extracted and unextracted samples demonstrated REs within 6% for TMSD low- and high-exposure samples. For the hexanes control group, RE was within 12% for both low- and high-exposure samples.

After scheduled termination of the animals, bulk chemical and mixed hexanes control articles were reanalyzed by the study laboratory using GC/MSD along with respective frozen reference standards taken at the time of receipt at the testing facility. The TMSD bulk test article was a yellow liquid upon receipt and remained so over the course of the study. The hexanes bulk control article was a colorless liquid upon receipt and remained so over the course of the study. For the bulk chemical reanalysis of TMSD, analysis indicated that hexamethyldisiloxane was present at a higher percentage (1.02%) in the sample compared to the initial analysis (0.79%) or frozen reference (0.44%). Aside from this result, the data indicated no statistically significant differences in the purities of TMSD and hexanes control articles and their respective frozen reference standards (data not shown).

## A.2 Vapor Generation and Exposure System

A schematic of the TMSD vapor generation and delivery system is shown in Figure A-1. The system consisted of two parts: the vaporization subsystem and the delivery subsystem. Both subsystems were housed in a glove box. The generation and delivery system for the hexanes control was similar to that for the TMSD system. The test chemical was pumped to the vaporization column using a syringe pump capable of delivering a stable and precisely determined flow of chemical to the generator. The syringe needle was inserted in the vaporizer column through a septum. Air entered the column from the bottom, vaporized the chemical, and carried it to the delivery system. The exposure vapor was directed to a pneumatic slide valve. This valve served as the exposure on-off valve and was operated by a solenoid actuated by the exposure control unit (ECU).

During “on-exposure” periods, the slide valve was actuated and the vapor directed through the valve to the nose-only exposure carousel. At each exposure carousel, vapor was delivered uniformly to each nose tube. During “off-exposure” periods when animals were loaded or removed from each carousel, filtered and conditioned air was supplied to each exposure carousel from the facility compressed air system. Also during this period, the exposure vapor air stream was directed through a scrubber system within the glove box prior to facility exhaust.

The animals were exposed in nose-only inhalation carousels developed at Battelle. The rodent exposure carousel (Figure A-1) consisted of stackable tiers with eight nose-only exposure ports per tier. Each stainless-steel exposure unit consisted of three modules providing 24 ports for animal exposure and test atmosphere sampling. Each port received approximately 500 mL/min of exposure atmosphere, for a total exposure unit inlet flow of approximately 12 L/min. Vented enclosures mounted on stainless-steel stands surrounded each exposure carousel and were designed for containment of the exposure units. This carousel design provided uniform concentration and fresh vapor of test chemical to each animal connected to the exposure system. Internal tubing was constructed of electropolished stainless steel. The materials of construction reduced turbulence within the aerosol flow path and reduced the potential for particle loss to internal surfaces.

The test atmosphere entered the carousel through the top. After filling an inlet manifold, the test atmosphere then flowed radially to each of eight evenly spaced ports into each animal containment tube mounted on one of three different levels of the carousel. This design minimized any effect of the animals on the atmosphere because no exhaled air from one animal could reach the breathing zone of another. The temperature and humidity of the aerosol systems were not monitored or controlled and corresponded to the ambient conditions in the room.

One end of the tube that restrained the individual animal was tapered to approximately fit the shape of the animal’s head, and the diameter of the cylindrical portion of the tube was configured such that it was difficult for the animal to turn in the tube. The back portion of the tube was covered with a plastic cap. The tube containing the animal was fastened to the inhalation carousel by a bracket with the nose portion of the tube protruding into the carousel.

Each exposure carousel was surrounded by a ventilated enclosure maintained at a pressure slightly negative relative the room’s pressure. The purpose of the enclosure was to minimize the release of test atmosphere from the carousel to the room. Each enclosure was ventilated at a rate of approximately 450 L/min. Three separate exposure carousels and cabinets were used for the studies: one for the TMSD exposures, one for the hexanes control group, and a third for the air control group.

Exposure operation proceeded in stages: equilibration, normal operation, and shutdown. The equilibration period began by initiating the syringe pump, transferring test chemical to the vaporization column. During this period, the test chemical vapor was exhausted through a scrubber in the glove box and filtered off-exposure air was delivered to the exposure carousel inlet. After the system equilibrated, exposure was initiated using the on-exposure switch on the ECU. Concurrent with this action, a solenoid valve was actuated, directing exposure vapor from the bypass line to the inlet of the carousel and placing the generation system in the normal operating stage. Shutdown at the end of the exposure period began with an ECU-initiated actuation of the solenoid valve that diverted the flow of test chemical vapor to exhaust and returned off-exposure air to the inlet of the exposure carousel. Exposures for the TMSD-exposed groups were conducted sequentially from high concentration to low.

## A.3 Vapor Concentration Monitoring

Samples from each exposure (TMSD) and control (hexanes and air) atmosphere were collected at the Battelle West Jefferson testing facility from nose-only ports onto XAD-4 sorbent tubes (8 mm × 150 mm, SKC, Inc., Eighty Four, PA) for 30 minutes at flow rates ranging from 0.4 to 0.5 L/min. Room air samples also were collected for the duration of the exposure sampling. Samples were collected on October 12, 14, 15, 16, 17, and 18, 2015 (rat studies) and on October 13, 19, 20, 21, 22, and 23, 2015 (mouse studies).

Analysis of the filtered air and room air samples produced TMSD and total hexanes results that were either nondetectable (ND) or below the limit of quantitation (BLOQ) for the respective analyte. The analytical limits of quantitation (LOQs) for TMSD and n-hexane were approximately 2.04 μg/mL and 2.00 μg/mL, respectively. These amounts correspond to vapor concentrations of approximately 0.13 ppm TMSD and 0.29 ppm total hexanes, using their respective solution-to-vapor concentration conversion equations with a dilution volume of 4 mL and assuming a sampling flow rate of 0.45 L/min for 30 minutes.

### A.3.1 Rats

Summaries of TMSD and total hexanes concentration results are shown in Table A-3 and Table A-4 (1-day exposure) and in Table A-5 and Table A-6 (5-day exposure) for rat exposures. The relative standard deviations (RSDs) for all TMSD exposure concentrations were within 13%. TMSD concentrations were within 20% of the respective target concentrations, except for the 0.3 ppm exposure on October 15, 2015, which was 22.5% below target. Over the 5 days of exposure, the grand average RSDs for the TMSD exposure concentrations were within 10% for the 1, 3, and 10 ppm exposure concentrations and within 17% for the 0.3 ppm exposure concentration. The grand average determined TMSD concentrations were within 7% of the respective target exposure concentrations for all concentrations.

The RSDs for all hexanes exposure concentrations were within 11% for each exposure concentration. Over the 5 days of exposure, the grand average RSD for the total hexanes exposure concentrations were within 7% for the 1, 3, and 10 ppm TMSD exposure concentrations and within 12% for the 0.3 ppm exposure concentration.

### A.3.2 Mice

Summaries of TMSD and total hexanes concentration results are shown in Table A-7 and Table A-8 (1-day exposure) and in Table A-9 and Table A-10 (5-day exposure) from mouse exposures. The RSDs for all TMSD exposure concentrations were within 13%, except for the 1 ppm exposure on October 23, 2015, which was 16%. TMSD concentrations were within 18% of the respective target concentrations, with the exception of the 1 ppm exposure on October 23, 2015, which was 21.4% below target. Over the 5 days of exposure, the grand average RSDs for the TMSD exposure concentrations were within 8% for the 3 and 10 ppm exposure concentrations and within 12% for the 0.3 ppm exposure concentration. The grand average RSD for the 1 ppm exposure concentration was within 16%. The grand average determined TMSD concentrations were within 4% of the respective target exposure concentrations for the 0.3, 1, and 10 ppm exposures. The grand average determined TMSD concentration for the 3 ppm TMSD exposure was within 11% of the target concentration.

The RSDs for all hexanes exposure concentrations were within 12%, except for the 1 ppm exposure on October 23, 2015, which was 14.3%. Over the 5 days of exposure, the grand average RSDs for the total hexanes exposure concentrations were within 8% for the 0.3, 3, and 10 ppm TMSD exposure concentrations and within 11% for the 1 ppm exposure concentration. Comparison of the hexanes control to the total hexanes concentration for the highest TMSD exposure concentration indicated comparable results according to the delivery settings used and provided a high-exposure benchmark for the effect of hexanes only on animal exposure.

Analysis of the filtered air and room air samples produced TMSD and total hexanes results that were either ND or BLOQ for the respective analyte. The analytical LOQs for TMSD and n-hexane were approximately 2.04 μg/mL and 2.00 μg/mL, respectively. These amounts correspond to vapor concentrations of approximately 0.13 ppm TMSD and 0.29 ppm total hexanes, using their respective solution-to-vapor concentration conversion equations with a dilution volume of 4 mL and assuming a sampling flow rate of 0.45 L/min for 30 minutes.

## A.4 Chamber Atmosphere Characterization

Sample analyses were performed at the Battelle Columbus test site. All analyses used a GC/MSD method validated before the start of the study (Table A-11).

For homogeneity, TMSD and hexanes sampling ports were sampled at the Battelle West Jefferson testing facility onto XAD-4 sorbent tubes for 30 minutes at a flow rate of approximately 0.45 L/min. At each concentration, six samples were shipped refrigerated to the Battelle Columbus test site: two from the top tier, two from the middle, and two from the bottom, for a total n = 6 for each target concentration. In each tier, two individual samples came from ports 2 and 6. Table A-12 shows the averaged results by tier (n = 2) for each target concentration level (n = 6) to evaluate the homogeneity between the carousel locations. Table A-13 and Table A-14 show the averaged determined concentrations for each concentration level (n = 6) to evaluate homogeneity of the entire carousel. For the purposes of homogeneity evaluation, the low concentration (0.2 ppm) exposed group was generated at an elevated concentration to ensure no results were BLOQ. The hexanes control generator was set to a concentration equal to the estimated total hexanes content in the TMSD high-exposure group generator to assess the highest hexanes concentration present in the TMSD-exposed groups.

Evaluation of the homogeneity for both TMSD and total hexanes in the TMSD and hexanes exposure samples indicated that the carousel sampling from all three tiers was within 10% RSD for all concentrations. The TMSD concentrations were within 15% of target except for the 0.2 ppm and 5 ppm groups. The higher RE value was a result of comparison with the 0.2 ppm target. The actual concentration was purposely set to a higher value to ensure detection during analysis. RE for total hexanes was not reported. The hexanes control results were provided as a relative comparison with the highest total hexanes concentrations present in TMSD vapor concentrations as the system generator settings were identical. These results were comparable.

Consistent delivery of TMSD was observed in the exposure atmosphere at the nose-only ports. Total hexanes were measured as a ratio of a given TMSD concentration because TMSD was in a solution of mixed hexanes. Because the vapor generation was predicated on achieving TMSD targets, values for hexanes concentrations could have been biased toward concentrations associated with specific generator settings. Therefore, a comparison with a target concentration was not reported for total hexanes. Consistent delivery of hexanes was observed. Comparison of the hexanes control with the total hexanes concentration for the highest TMSD exposure concentration indicated comparable results according to the delivery settings used and provided a high-exposure benchmark for the effect of hexane-only exposure on animals.

### A.4.1 Test for Aerosol in Exposure Atmosphere

A condensation particle counter (Model 3022A; TSI Incorporated; St. Paul, MN) was used to count the particles before the start of generation and during generation. Particle counts <200 particles/cm^3^ are typical of an exposure atmosphere when no generation is occurring. Particle counts above this level, especially if the counts increase with exposure concentration and are above the level during the off-exposure period, would suggest a contribution to the aerosol concentration due to the generation system. The results of the particle count measurements are given in Table A-15. The data indicates no concentrations >200 particles/cm^3^ either before or during the exposure, hence no contribution to the aerosol concentration due to the generation systems (a single before-exposure measurement was used for the TMSD-exposed groups).

### A.4.2 Health and Safety

As with all NTP studies, extensive effort was expended to ensure the health and safety of study personnel. This section summarizes selected health and safety aspects applicable to all NTP inhalation studies, as well as those specific to TMSD and hexanes. Detailed information is on file at NIEHS.

There are no short-term (e.g., 10- to 30-minute) or 8-hour time-weighted average (TWA) daily occupational exposure limits for TMSD. An occupational exposure limit (OEL) of 0.1 ppm, however, was referenced in a Sigma-Aldrich TMSD Safety Data Sheet. For diazomethane, a similar chemical, the 8-hour TWA Occupational Safety and Health Administration (OSHA) permissible exposure limit (PEL) and the American Conference of Governmental Industrial Hygienists (ACGIH) threshold limit value (TLV) are both 0.2 ppm. For n-hexane, the OSHA PEL is 500 ppm, the ACGIH TLV is 50 ppm, and the National Institute for Occupational Safety and Health (NIOSH) 10-hour TWA recommended exposure limit (REL) also is 50 ppm.

Occupational action levels typically are 50% of a TLV. Exceeding an action level in a work environment would have prompted evaluation of the effectiveness of controls and might have triggered additional engineering and administrative controls to limit personnel exposure, supplemented with increased use of appropriate personal protective equipment (PPE). Battelle therefore used 0.1 ppm TMSD (a value listed as the OEL in a TMSD Safety Data Sheet and that is 50% of the TLV for diazomethane) as its OEL.

Protection from explosion was considered. The high concentration on study is <10% of the lower explosive limit (1.1% LEL; 10% is 1,110 ppm).

No incompatible chemicals (e.g., oxidizing materials) were used or introduced into the generation and delivery systems for TMSD and hexanes.

Primary engineering control was achieved by the use of local exhaust ventilation systems. Personnel were instructed to confine the opening of container, transferring, and use of TMSD and hexanes, to include handling of samples, in a functional laboratory hood or ventilated enclosure. Ventilation systems were monitored for airflow efficiency and monitoring records were maintained.

Staff were trained on the Battelle Chemical Safety Summaries for both TMSD and hexanes. In addition, all personnel involved in the TMSD and hexanes studies were provided health and safety training to comply with the Occupational Safety and Health Administration (OSHA) Laboratory Standard requirements. Personnel who worked with TMSD or hexanes or exposed study animals were assigned to the Battelle occupational health surveillance program.

To complement engineering and administrative controls, additional hazard control was accomplished with the use of personal protective clothing and equipment. In addition, during initial startup of exposure generation activities, a photoionization detector (PID) was run. TMSD and hexanes generation handling activities were performed in a ventilated glove box. The purpose of the PID was to continuously monitor for changes at the exposure carousel enclosure (based on hexanes) to detect abnormal conditions. Passive sampling, which has a greater resolution and specificity, was also conducted and demonstrated that containment was effective. This allowed selection of appropriate PPE, including full-face respiratory protection. The PID was also run during the in-life phase to monitor for unexpected concentrations or release throughout the duration of the studies. Chemistry activities were performed in a working laboratory hood with appropriate PPE.

The design of the generation and exposure system and the minimum exhaust flow for the block of exposure rooms used for the studies suggested that detectable concentrations would not be expected in the building exhaust. In support of inhalation system design and safety evaluation, exposure and exhaust atmospheres of hexanes and TMSD were evaluated. Sampling for both TMSD and hexanes exhaust analyses occurred at the nose-only port, collecting front (primary sample delivery) and backup tubes (check for sample breakthrough) in quadruplicate. Additional samples were acquired (no backup tubes) within the carousel cabinet, at the exhaust scrubber, inside the glove box (housing the syringe pump), and within the room (field blank). These samples were acquired in duplicate. Samples were shipped refrigerated from the Battelle West Jefferson testing facility to the Battelle Columbus test site to be analyzed.

The evaluation of hexanes control exhaust was performed using an arbitrarily high concentration as a target for the nose-only port to ensure detection of potential leaks in the system. Results for this exhaust analysis are summarized in Table A-16. For the carousel cabinet with two replicates, standard deviation is not calculated, so precision of duplicates was reported in place of RSD.

In the TMSD exhaust analysis, no TMSD was detected, but hexanes were present in small amounts (≤0.13% of the hexanes concentration measured at the nose-only port) in the carousel cabinet, at the exhaust flow scrubber, and inside the glove box. This concentration is roughly the same order of magnitude of hexanes present during the hexanes exhaust analysis, with differences likely due to secure sampling fixtures. Comparison of the mixed hexanes control with the hexanes component in the TMSD test article indicated that comparable concentrations were obtained. The absence of TMSD and hexanes in the backup tubes for the nose-only port samples indicated that no breakthrough occurred.

Specific procedures were implemented for spill control, clean-up, and emergency planning and response.

Table A-1 Area Percent Purity Profile − Trimethylsilyldiazomethane

Peak ID | Average Percent of Total Area
n-Hexane | 33.6
Methylcyclopentane | 25.7
Trimethylsilanol | 0.13
Cyclohexane | 0.21
Hexamethyldisiloxane | 0.79
Heptane | 0.15
Trimethylsilyldiazomethane | 36.1
(Chloromethyl)trimethylsilane | 3.30
Trimethylsilylmethanol | 0.07

Table A-2 Area Percent Purity Profile – Mixed Hexanes

Peak ID | Average Percent of Total Area
2-Methylpentane | 0.84
3-Methylpentane | 16.7
n-Hexane | 64.2
Methylcyclopentane | 17.4
Cyclohexane | 0.87

Table A-3 Summary of Trimethylsilyldiazomethane Chamber Concentrations for Rats in the One-day Nose-only Inhalation Study

Exposure Date | Date Analyzed^a^ | Target TMSD Concentration (ppm) | Determined TMSD Concentration^b^ (ppm) | RSD | Mean RE
October 12, 2015 | October 12, 2015 | Room air | ND | NA | NA
| | 0 (air) | ND | NA | NA
| | 10 | 11.3 ± 1.0 | 8.8 | 12.9

TMSD = trimethylsilyldiazomethane; RSD = relative standard deviation; RE = relative error; ND = not detected; NA = not applicable.

^a^ Date first chromatograms were acquired.

^b^ Data are presented as mean ± standard deviation.

Table A-4 Summary of Total Hexanes Chamber Concentrations for Rats in the One-day Nose-only Inhalation Study of Trimethylsilyldiazomethane

Exposure Date | Date Analyzed^a^ | Target TMSD Concentration (ppm) | Determined Total Hexanes Concentration^b^ (ppm) | RSD
October 12, 2015 | October 12, 2015 | Room air | BLOQ | NA
| | 0 (air) | BLOQ | NA
| | 0 (hexanes) | 25.1 ± 0.7 | 2.8
| | 10 | 26.9 ± 1.6 | 6.0

TMSD = trimethylsilyldiazomethane; RSD = relative standard deviation; BLOQ = below limit of quantitation; NA = not applicable.

^a^ Date first chromatograms were acquired.

^b^ Data are presented as mean ± standard deviation.

Table A-5 Summary of Trimethylsilyldiazomethane Chamber Concentrations for Rats in the Five-day Nose-only Inhalation Study

Exposure Date | Date Analyzed^a^ | Target TMSD Concentration (ppm) | Determined TMSD Concentration^b^ (ppm) | Grand RSD | Grand Mean RE
October 14–18, 2015 | October 14–19, 2015 | Room air | ND | NA | NA
| | 0 (air) | ND | NA | NA
| | 0.3 | 0.283 ± 0.047 | 16.5 | −5.5
| | 1 | 1.06 ± 0.10 | 9.1 | 6.5
| | 3 | 2.87 ± 0.25 | 8.8 | −4.4
| | 10 | 10.3 ± 0.8 | 8.0 | 3.0

TMSD = trimethylsilyldiazomethane; RSD = relative standard deviation; RE = relative error; ND = not detected; NA = not applicable.

^a^ Date first chromatograms were acquired.

^b^ Data are presented as mean ± standard deviation.

Table A-6 Summary of Total Hexanes Chamber Concentrations for Rats in the Five-day Nose-only Inhalation Study of Trimethylsilyldiazomethane

Exposure Date | Date Analyzed^a^ | Target TMSD Concentration (ppm) | Determined Total Hexanes Concentration^b^ (ppm) | Grand RSD
October 14–18, 2015 | October 14–19, 2015 | Room air | BLOQ | NA
| | 0 ppm (air) | BLOQ | NA
| | 0 ppm (hexanes) | 24.5 ± 1.4 | 5.9
| | 0.3 | 0.845 ± 0.098 | 11.6
| | 1 | 3.20 ± 0.21 | 6.4
| | 3 | 7.96 ± 0.45 | 5.7
| | 10 | 25.4 ± 1.6 | 6.3

TMSD = trimethylsilyldiazomethane; RSD = relative standard deviation; BLOQ = below limit of quantitation; NA = not applicable.

^a^ Date first chromatograms were acquired.

^b^ Data are presented as mean ± standard deviation.

Table A-7 Summary of Trimethylsilyldiazomethane Chamber Concentrations for Mice in the One-day Nose-only Inhalation Study

Exposure Date | Date Analyzed^a^ | Target TMSD Concentration (ppm) | Determined TMSD Concentration^b^ (ppm) | RSD | Mean RE
October 13, 2015 | October 13, 2015 | Room air | ND | NA | NA
| | Filtered air (0) | ND | NA | NA
| | 10 | 11.2 ± 0.2 | 2.1 | 11.9

TMSD = trimethylsilyldiazomethane; RSD = relative standard deviation; RE = relative error; ND = not detected; NA = not applicable.

^a^ Date first chromatograms were acquired.

^b^ Data are presented as mean ± standard deviation.

Table A-8 Summary of Total Hexanes Chamber Concentrations for Mice in the One-day Nose-only Inhalation Study of Trimethylsilyldiazomethane

Exposure Date | Date Analyzed^a^ | Target TMSD Concentration (ppm) | Determined Total Hexanes Concentration^b^ (ppm) | RSD
October 13, 2015 | October 13, 2015 | Room air | ND | NA
| | Filtered air (0) | ND | NA
| | Hexanes (0) | 24.1 ± 0.6 | 2.7
| | 10 | 27.1 ± 0.6 | 2.2

TMSD = trimethylsilyldiazomethane; RSD = relative standard deviation; ND = not detected; NA = not applicable.

^a^ Date first chromatograms were acquired.

^b^ Data are presented as mean ± standard deviation.

Table A-9 Summary of Trimethylsilyldiazomethane Chamber Concentrations for Mice in the Five-day Nose-only Inhalation Study

Exposure Date | Date Analyzed^a^ | Target TMSD Concentration (ppm) | Determined TMSD Concentration^b^ (ppm) | Grand RSD | Grand Mean RE
October 19–23, 2015 | October 22–27, 2015 | Room air | ND | NA | NA
| | Filtered air (0) | ND | NA | NA
| | 0.3 | 0.299 ± 0.031 | 10.4 | −0.5
| | 1 | 1.04 ± 0.17 | 16.0 | 3.9
| | 3 | 2.68 ± 0.16 | 5.9 | −10.6
| | 10 | 10.2 ± 0.7 | 7.4 | 1.5

TMSD = trimethylsilyldiazomethane; RSD = relative standard deviation; RE = relative error; ND = not detected; NA = not applicable.

^a^ Date first chromatograms were acquired.

^b^ Data are presented as mean ± standard deviation.

Table A-10 Summary of Total Hexanes Chamber Concentrations for Mice in the Five-day Nose-only Inhalation Study of Trimethylsilyldiazomethane

Exposure Date | Date Analyzed^a^ | Target TMSD Concentration (ppm) | Determined Total Hexanes Concentration^b^ (ppm) | Grand RSD
October 19–23, 2015 | October 22–27, 2015 | Room air | BLOQ | NA
| | Filtered air (0) | BLOQ | NA
| | Hexanes (0) | 25.6 ± 1.5 | 6.0
| | 0.3 | 1.05 ± 0.07 | 6.6
| | 1 | 3.48 ± 0.37 | 10.7
| | 3 | 7.90 ± 0.31 | 3.9
| | 10 | 25.3 ± 1.2 | 4.8

TMSD = trimethylsilyldiazomethane; RSD = relative standard deviation; BLOQ = below limit of quantitation; NA = not applicable.

^a^ Date first chromatograms were acquired.

^b^ Data are presented as mean ± standard deviation.

Table A-11 Gas Chromatography/Mass Selective Detection System Settings

Column | RTX-1301 (Restek, Bellefonte, PA)
Column Dimensions | 30 m × 0.25 mm (ID); 1-μm film thickness
Autosampler | CombiPAL (CTC Analytics, Leap Technologies, Carrboro, NC)
Carrier Gas and Flow Rate | Helium at 1.5 mL/minute
Oven Temperature | 35°C hold for 12 minutes, increase at 40°C/minute to 240°C, final hold 2 minutes
Injector Temperature | 140°C
Injection Volume/Mode | 2 μL, Split 10:1
Detector/Mode | MSD, EI+, Scan 35–300 m/z
Auxiliary Temperature | 260°C
Source Temperature | 230°C
Quad Temperature | 150°C
Run Time | 19 minutes
Data Acquisition System | ChemStation Version D.02.00.275
Data Analysis System | MassLynx Version 4.0

ID = internal diameter; MSD = mass selective detection; EI+ = electron impact ionization + .

Table A-12 Trimethylsilyldiazomethane and Total Hexanes Homogeneity Results for Carousel Sampling Locations

Target TMSD Exposure Concentration (ppm) | Average Determined Concentration (ppm)
Target TMSD Exposure Concentration (ppm) | Top Tier | | Middle Tier | | Bottom Tier
Target TMSD Exposure Concentration (ppm) | TMSD | Total Hexanes | TMSD | Total Hexanes | TMSD | Total Hexanes
0 ppm (hexanes) | NA | 53.9 | NA | 53.7 | NA | 56.4
0.2 | 0.572 | 1.52 | 0.580 | 1.49 | 0.568 | 1.36
1 | 1.18 | 3.04 | 1.14 | 3.06 | 1.11 | 3.03
5 | 5.72 | 14.3 | 5.80 | 14.6 | 5.80 | 14.7
20 | 22.8 | 52.8 | 19.8 | 49.5 | 21.6 | 51.0

TMSD = trimethylsilyldiazomethane; NA = not applicable.

Table A-13 Trimethylsilyldiazomethane Homogeneity Results for Carousel

Target TMSD Exposure Concentration (ppm) | Average Determined TMSD Concentration (ppm)^a^ | RSD | Average RE
0.2 | 0.573 ± 0.028 | 4.9 | 186.7
1 | 1.14 ± 0.06 | 5.6 | 14.2
5 | 5.78 ± 0.29 | 5.0 | 15.5
20 | 21.4 ± 2.0 | 9.4 | 7.2

TMSD = trimethylsilyldiazomethane; RSD = relative standard deviation; RE = relative error.

^a^ Data are presented as mean ± standard deviation.

Table A-14 Total Hexanes Homogeneity Results for Carousel

Target TMSD Exposure Concentration (ppm) | Average Determined Total Hexanes Concentration (ppm)^a^ | RSD
0 ppm (hexanes) | 54.7 ± 3.0 | 5.4
0.2 | 1.45 ± 0.12 | 8.3
1 | 3.05 ± 0.06 | 2.0
5 | 14.5 ± 0.7 | 4.7
20 | 51.1 ± 2.5 | 4.9

TMSD = trimethylsilyldiazomethane; RSD = relative standard deviation.

^a^ Data are presented as mean ± standard deviation.

Table A-15 Particle Counts in Exposure Atmosphere before and during Generation

Exposure Group | Particle Count before Exposure (particle/cm^3^)^a^ | Particle Count during Exposure (particle/cm^3^)^a^
Hexanes Control | 10 | 34
0.3 ppm TMSD | 9 | 15
1 ppm TMSD | 9 | 18
3 ppm TMSD | 9 | 18
10 ppm TMSD | 9 | 9
Room 1–560 (collected after exposure) | 730 | NA

TMSD = trimethylsilyldiazomethane; NA = not applicable.

^a^ Values shown are rounded.

Table A-16 Summary of Mixed Hexanes Exhaust Analysis

Sampling Description | Average Determined Total Hexanes Concentration^a^ (ppm) | RSD
Nose-only Port – Front^b^ | 125 ± 8 | 6.2
Nose-only Port – Backup | BLOQ | NA
Carousel Cabinet | 1.05 | 0.864^c^
Exhaust Flow Scrubber | ND | NA
Inside Glove Box | BLOQ | NA
Field Blank (Exposure Room) | ND | NA

RSD = relative standard deviation; BLOQ = below the limit of quantitation; NA = not applicable; ND = not detected.

^a^ Data shown are mean ± standard deviation.

^b^ n = 3; one replicate excluded as an outlier via Q-test.

^c^ n = 2; precision of duplicates reported.

Figure A-1

Trimethylsilyldiazomethane Generation, Distribution, and Exposure System

Figure A-2

^1^H Nuclear Magnetic Resonance Spectrum of Trimethylsilyldiazomethane

Figure A-3

^13^C Nuclear Magnetic Resonance Spectrum of Trimethylsilyldiazomethane

Figure A-4

^1^H Nuclear Magnetic Resonance Spectrum of Mixed Hexanes

Figure A-5

^13^C Nuclear Magnetic Resonance Spectrum of Mixed Hexanes

Figure A-6

Total Ion Chromatogram from Gas Chromatography/Mass Selective Detection Analysis of Trimethylsilyldiazomethane

Figure A-7

Total Ion Chromatogram from Gas Chromatography/Mass Selective Detection Analysis of Mixed Hexanes