# Revision Notice

An error was identified in the NTP Technical Report on the Toxicity Studies of Aspergillus fumigatus Administered by Inhalation to B6C3F1/N Mice (TOX 100). A bacterial reverse mutation assay study for a different test substance was included in error for TOX 100. Aspergillus fumigatus was not tested in the bacterial reverse mutation assay. This error has been corrected in the Abstract, Materials and Methods, Results, References, Appendix B, and Appendix E of this revised report.