# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Technical Report on the Toxicity Studies of Aspergillus fumigatus Administered by Inhalation to B6C3F1/N Mice by letter in December 2020–January 2021 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Peer review the draft NTP Technical Report on the Toxicity Studies of Aspergillus fumigatus.
2. Comment on NTP’s interpretations of the data.

NTP carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Natalie M. Johnson, Ph.D.
  Associate Professor, Department of Environmental & Occupational Health
  Texas A&M University
  College Station, Texas, USA
- Dennis W. Wilson, D.V.M., Ph.D.
  Professor Emeritus of Pathology, Department of Pathology, Microbiology, and Immunology
  University of California School of Veterinary Medicine
  Davis, California, USA