# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed studies, evaluated and interpreted results, and reported findings
  D.R. Germolec, Ph.D., Study Scientist
  C.R. Blystone, Ph.D.
  M.C. Cora, D.V.M.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  D.E. Malarkey, D.V.M., Ph.D.
  G.K. Roberts, Ph.D.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, M.S.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Integrated Laboratory Systems, LLC, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  C.J. Willson, D.V.M., Ph.D., Study Pathologist
- Coordinated NTP Pathology Working Group (3-month studies) (November 27, 2018)
  R. Moore, D.V.M.
- National Institute for Occupational Safety and Health, Morgantown, West Virginia, USA
  Developed test article and exposure system, conducted studies, evaluated and interpreted results, and reported findings
  D.H. Beezhold, Ph.D., Co-Principal Investigator
  B.J. Green, Ph.D., Co-Principal Investigator
  L. Battelli, M.S.
  T.L. Croston, Ph.D.
  W.T. Goldsmith, B.S.
  B. Law, M.S.
  A.R. Lemons, M.S.
  W.G. McKinney, M.S.
  A.P. Nayak, Ph.D.
  M. Orandle, D.V.M., Ph.D.
- Battelle, Columbus, Ohio, USA
  Evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  K.M. Gideon, M.E.T.M.
  K.M. Patton, D.V.M., Ph.D.
- ASRC Federal, Research Triangle Park, North Carolina, USA
  Prepared data for report
  P. Brown, B.S.
  H. Gong, M.S.
  C. Martini, B.S.
  C. Myers, M.S.
  N. Sayers, B.S.
  M. Shaw, B.S.
  R. Whittlesey, M.S.