# References

1 Hawksworth DL. The magnitude of fungal diversity: The 1.5 million species estimate revised. Mycol Res. 2001;105:1422–1432. 10.1017/S0953756201004725
2 Afanou KA, Straumfors A, Skogstad A, Nilsen T, Synnes O, Skaar I, Hjeljord L, Tronsmo A, Green BJ, Eduard W. Submicronic fungal bioaerosols: High-resolution microscopic characterization and quantification. Appl Environ Microbiol. 2014; 80(22):7122–7130. 10.1128/AEM.01740-14 25217010
3 Green BJ, Schmechel D, Summerbell RC. Aerosolized fungal fragments. In: Adan O, Samson R, editors. Fundamentals of Mold Growth in Indoor Environments and Strategies for Healthy Living. Springer; 2011. p. 211–243. 10.3920/978-90-8686-722-6_8
4 Green BJ, Sercombe JK, Tovey ER. Fungal fragments and undocumented conidia function as new aeroallergen sources. J Allergy Clin Immunol. 2005; 115(5):1043–1048. 10.1016/j.jaci.2005.02.009 15867864
5 Green BJ, Tovey ER, Sercombe JK, Blachere FM, Beezhold DH, Schmechel D. Airborne fungal fragments and allergenicity. Med Mycol. 2006; 44 Suppl 1:S245–S255. 10.1080/13693780600776308 17050446
6 Green BJ, Beezhold DH. Industrial fungal enzymes: An occupational allergen perspective. J Allergy (Cairo). 2011;2011:682574. 10.1155/2011/682574 21747869
7 Centers for Disease Control and Prevention (CDC). Update: Pulmonary hemorrhage/hemosiderosis among infants-Cleveland, Ohio, 1993-1996. MMWR Morb Mortal Wkly Rep. 1997; 46(2):33–35. 9011781
8 Centers for Disease Control and Prevention (CDC). Acute pulmonary hemorrhage/hemosiderosis among infants-Cleveland, January 1993-November 1994. MMWR Morb Mortal Wkly Rep. 1994; 43(48):881–883. 7969010
9 Calvo AM, Wilson RA, Bok JW, Keller NP. Relationship between secondary metabolism and fungal development. Microbiol Mol Biol Rev. 2002; 66(3):447–459. 10.1128/MMBR.66.3.447-459.2002 12208999
10 Centers for Disease Control and Prevention (CDC). Update: Pulmonary hemorrhage/hemosiderosis among infants-Cleveland, Ohio, 1993-1996. MMWR Morb Mortal Wkly Rep. 2000; 49(9):180–184. 11795499
11 Institute of Medicine (IOM). Damp indoor spaces and health. Washington, DC: The National Academies Press; 2004.
12 World Health Organization (WHO). WHO guidelines for indoor air quality: Dampness and mould. Geneva: WHO Regional Ofﬁce for Europe; 2009.
13 Jaakkola MS, Quansah R, Hugg TT, Heikkinen SA, Jaakkola JJ. Association of indoor dampness and molds with rhinitis risk: A systematic review and meta-analysis. J Allergy Clin Immunol. 2013; 132(5):1099–1110.e1018. 10.1016/j.jaci.2013.07.028 24028857
14 Mendell MJ, Mirer AG, Cheung K, Tong M, Douwes J. Respiratory and allergic health effects of dampness, mold, and dampness-related agents: A review of the epidemiologic evidence. Environ Health Perspect. 2011; 119(6):748–756. 10.1289/ehp.1002410 21269928
15 Quansah R, Jaakkola MS, Hugg TT, Heikkinen SA, Jaakkola JJ. Residential dampness and molds and the risk of developing asthma: A systematic review and meta-analysis. PLoS One. 2012; 7(11):e47526. 10.1371/journal.pone.0047526 23144822
16 Kanchongkittiphon W, Mendell MJ, Gaffin JM, Wang G, Phipatanakul W. Indoor environmental exposures and exacerbation of asthma: An update to the 2000 review by the Institute of Medicine. Environ Health Perspect. 2015; 123(1):6–20. 10.1289/ehp.1307922 25303775
17 Mudarri DH. Valuing the economic costs of allergic rhinitis, acute bronchitis, and asthma from exposure to indoor dampness and mold in the US. J Environ Public Health. 2016;2016:2386596. 10.1155/2016/2386596 27313630
18 Buskirk AD, Green BJ, Lemons AR, Nayak AP, Goldsmith WT, Kashon ML, Anderson SE, Hettick JM, Templeton SP, Germolec DR, et al. A murine inhalation model to characterize pulmonary exposure to dry Aspergillus fumigatus conidia. PLoS One. 2014; 9(10):e109855. 10.1371/journal.pone.0109855 25340353
19 Nayak AP, Green BJ, Lemons AR, Marshall NB, Goldsmith WT, Kashon ML, Anderson SE, Germolec DR, Beezhold DH. Subchronic exposures to fungal bioaerosols promotes allergic pulmonary inflammation in naive mice. Clin Exp Allergy. 2016; 46(6):861–870. 10.1111/cea.12724 26892490
20 Nayak AP, Croston TL, Lemons AR, Goldsmith WT, Marshall NB, Kashon ML, Germolec DR, Beezhold DH, Green BJ. Aspergillus fumigatus viability drives allergic responses to inhaled conidia. Ann Allergy Asthma Immunol. 2018; 121(2):200–210.e202. 10.1016/j.anai.2018.04.008 29660515
21 Sugui JA, Kwon-Chung KJ, Juvvadi PR, Latgé J-P, Steinbach WJ. Aspergillus fumigatus and related species. Cold Spring Harb Perspect Med. 2015; 5(2):a019786. 10.1101/cshperspect.a019786 25377144
22 Latgé J-P. Aspergillus fumigatus and aspergillosis. Clin Microbiol Rev. 1999; 12(2):310–350. 10.1128/CMR.12.2.310 10194462
23 Kwon-Chung KJ, Sugui JA. Aspergillus fumigatus—What makes the species a ubiquitous human fungal pathogen? PLoS Pathog. 2013; 9(12):e1003743. 10.1371/journal.ppat.1003743 24348239
24 Brakhage AA, Langfelder K. Menacing mold: The molecular biology of Aspergillus fumigatus. Annu Rev Microbiol. 2002; 56(1):433–455. 10.1146/annurev.micro.56.012302.160625 12142473
25 Viegas C, Faria T, dos Santos M, Carolino E, Gomes AQ, Sabino R, Viegas S. Fungal burden in waste industry: An occupational risk to be solved. Environ Monit Assess. 2015; 187(4):199. 10.1007/s10661-015-4412-y 25796518
26 Gutarowska B, Skora J, Stepien L, Szponar B, Otlewska A, Pielech-Przybylska K. Assessment of microbial contamination within working environments of different types of composting plants. J Air Waste Manag Assoc. 2015; 65(4):466–478. 10.1080/10962247.2014.960954 25947216
27 van Kampen V, Sander I, Liebers V, Deckert A, Neumann HD, Buxtrup M, Willer E, Felten C, Jackel U, Klug K, et al. Concentration of bioaerosols in composting plants using different quantification methods. Ann Occup Hyg. 2014; 58(6):693–706. 24759376
28 Clark CS, Rylander R, Larsson L. Levels of gram-negative bacteria, Aspergillus fumigatus, dust, and endotoxin at compost plants. Appl Environ Microbiol. 1983; 45(5):1501–1505. 10.1128/aem.45.5.1501-1505.1983 6347061
29 Pearson C, Littlewood E, Douglas P, Robertson S, Gant TW, Hansell AL. Exposures and health outcomes in relation to bioaerosol emissions from composting facilities: A systematic review of occupational and community studies. J Toxicol Environ Health B Crit Rev. 2015; 18(1):43–69. 10.1080/10937404.2015.1009961 25825807
30 Fischer G, Muller T, Schwalbe R, Ostrowski R, Dott W. Species-specific profiles of mycotoxins produced in cultures and associated with conidia of airborne fungi derived from biowaste. Int J Hyg Environ Health. 2000; 203(2):105–116. 10.1078/S1438-4639(04)70015-2 11109562
31 Gladding TL, Gwyther CL. A study of the potential release of bioaerosols from containers as a result of reduced frequency residual waste collections. Sci Total Environ. 2017;576:481–489. 10.1016/j.scitotenv.2016.10.060 27810739
32 Viegas C, Faria T, Carolino E, Sabino R, Gomes AQ, Viegas S. Occupational exposure to fungi and particles in animal feed industry. Med Pr. 2016; 67(2):143–154. 10.13075/mp.5893.00289 27221292
33 Madsen AM, Tendal K, Schlunssen V, Heltberg I. Organic dust toxic syndrome at a grass seed plant caused by exposure to high concentrations of bioaerosols. Ann Occup Hyg. 2012; 56(7):776–788. 22553153
34 Gerfaud-Valentin M, Reboux G, Traclet J, Thivolet-Bejui F, Cordier JF, Cottin V. Occupational hypersensitivity pneumonitis in a baker: A new cause. Chest. 2014; 145(4):856–858. 10.1378/chest.13-1734 24687706
35 Tinley PD, Eddy K, Collier P. Contaminants in human nail dust: An occupational hazard in podiatry? J Foot Ankle Res. 2014; 7(1):15. 10.1186/1757-1146-7-15 24552311
36 Sabino R, Faisca VM, Carolino E, Verissimo C, Viegas C. Occupational exposure to Aspergillus by swine and poultry farm workers in Portugal. J Toxicol Environ Health A. 2012; 75(22-23):1381–1391. 10.1080/15287394.2012.721170 23095156
37 Saad-Hussein A, Morcos NY, Rizk SA, Ibrahim KS, El-Zaher NA, Moubarz G. Aspergillus hazardous problem in ceramic workers. Toxicol Ind Health. 2012; 28(10):886–893. 10.1177/0748233711425077 22082828
38 Makela R, Kauppi P, Suuronen K, Tuppurainen M, Hannu T. Occupational asthma in professional cleaning work: A clinical study. Occup Med (Lond). 2011; 61(2):121–126. 10.1093/occmed/kqq192 21285030
39 Karvala K, Nordman H, Luukkonen R, Nykyri E, Lappalainen S, Hannu T, Toskala E. Occupational rhinitis in damp and moldy workplaces. Am J Rhinol. 2008; 22(5):457–462. 10.2500/ajr.2008.22.3209 18954502
40 Curtis L, Cali S, Conroy L, Baker K, Ou CH, Hershow R, Norlock-Cruz F, Scheff P. Aspergillus surveillance project at a large tertiary-care hospital. J Hosp Infect. 2005; 59(3):188–196. 10.1016/j.jhin.2004.05.017 15694975
41 Dutkiewicz J, Olenchock SA, Sorenson WG, Gerencser VF, May JJ, Pratt DS, Robinson VA. Levels of bacteria, fungi, and endotoxin in bulk and aerosolized corn silage. Appl Environ Microbiol. 1989; 55(5):1093–1099. 10.1128/aem.55.5.1093-1099.1989 2757375
42 Latgé J-P. The pathobiology of Aspergillus fumigatus. Trends Microbiol. 2001; 9(8):382–389. 10.1016/S0966-842X(01)02104-7 11514221
43 Godish TJ, Godish DR. Mold infestation of wet spray-applied cellulose insulation. J Air Waste Manag Assoc. 2006; 56(1):90–95. 10.1080/10473289.2006.10464434 16499151
44 Burge HA, Solomon WR, Muilenberg ML. Evaluation of indoor plantings as allergen exposure sources. J Allergy Clin Immunol. 1982; 70(2):101–108. 10.1016/0091-6749(82)90236-6 7096819
45 Eduard W. Fungal spores: A critical review of the toxicological and epidemiological evidence as a basis for occupational exposure limit setting. Crit Rev Toxicol. 2009; 39(10):799–864. 10.3109/10408440903307333 19863384
46 Sporik RB, Arruda LK, Woodfolk J, Chapman MD, Platts-Mills TA. Environmental exposure to Aspergillus fumigatus allergen (Asp f I). Clin Exp Allergy. 1993; 23(4):326–331. 10.1111/j.1365-2222.1993.tb00330.x 8319130
47 Croston TL, Nayak AP, Lemons AR, Goldsmith WT, Gu JK, Germolec DR, Beezhold DH, Green BJ. Influence of Aspergillus fumigatus conidia viability on murine pulmonary microRNA and mRNA expression following subchronic inhalation exposure. Clin Exp Allergy. 2016; 46(10):1315–1327. 10.1111/cea.12783 27473664
48 Kramer MN, Kurup VP, Fink JN. Allergic bronchopulmonary aspergillosis from a contaminated dump site. Am Rev Respir Dis. 1989; 140(4):1086–1088. 10.1164/ajrccm/140.4.1086 2679261
49 Poole CJ, Wong M. Allergic bronchopulmonary aspergillosis in garden waste (compost) collectors—occupational implications. Occup Med (Lond). 2013; 63(7):517–519. 10.1093/occmed/kqt097 23975883
50 Hagemeyer O, Bunger J, van Kampen V, Raulf-Heimsoth M, Drath C, Merget R, Bruning T, Broding HC. Occupational allergic respiratory diseases in garbage workers: Relevance of molds and actinomycetes. Adv Exp Med Biol. 2013;788:313–320. 10.1007/978-94-007-6627-3_42 23835992
51 Madsen AM, Zervas A, Tendal K, Nielsen JL. Microbial diversity in bioaerosol samples causing ODTS compared to reference bioaerosol samples as measured using Illumina sequencing and MALDI-TOF. Environ Res. 2015;140:255–267. 10.1016/j.envres.2015.03.027 25880607
52 Kodzius R, Rhyner C, Konthur Z, Buczek D, Lehrach H, Walter G, Crameri R. Rapid identification of allergen-encoding cDNA clones by phage display and high-density arrays. Comb Chem High Throughput Screen. 2003; 6(2):147–154. 10.2174/1386207033329751 12678710
53 Nierman WC, Pain A, Anderson MJ, Wortman JR, Kim HS, Arroyo J, Berriman M, Abe K, Archer DB, Bermejo C, et al. Genomic sequence of the pathogenic and allergenic filamentous fungus Aspergillus fumigatus. Nature. 2005; 438(7071):1151–1156. 10.1038/nature04332 16372009
54 Reijula K, Tuomi T. Mycotoxins of aspergilli: Exposure and health effects. Front Biosci. 2003;8:s232–s235. 10.2741/978 12700107
55 Bignell E, Cairns TC, Throckmorton K, Nierman WC, Keller NP. Secondary metabolite arsenal of an opportunistic pathogenic fungus. Philos Trans R Soc Lond B Biol Sci 2016; 371(1709). 10.1098/rstb.2016.0023
56 Inglis DO, Binkley J, Skrzypek MS, Arnaud MB, Cerqueira GC, Shah P, Wymore F, Wortman JR, Sherlock G. Comprehensive annotation of secondary metabolite biosynthetic genes and gene clusters of Aspergillus nidulans, A. fumigatus, A. niger and A. oryzae. BMC Microbiol. 2013;13:91. 10.1186/1471-2180-13-91 23617571
57 Kwon-Chung KJ, Sugui JA. What do we know about the role of gliotoxin in the pathobiology of Aspergillus fumigatus? Med Mycol. 2009; 47 Suppl 1:S97–S103. 10.1080/13693780802056012 18608908
58 Fischer G, Muller T, Ostrowski R, Dott W. Mycotoxins of Aspergillus fumigatus in pure culture and in native bioaerosols from compost facilities. Chemosphere. 1999; 38(8):1745–1755. 10.1016/S0045-6535(98)00391-9 10101846
59 Frisvad J, Samson R. Chemotaxonomy and morphology of Aspergillus fumigatus and related taxa. In: Samson R, Pitt J, editors. Modern Concepts in Penicillium and Aspergillus Classification. Springer; 1990. p. 201–208. 10.1007/978-1-4899-3579-3_17
60 Waring P, Beaver J. Gliotoxin and related epipolythiodioxopiperazines. Gen Pharmacol: Vasc Sys. 1996; 27(8):1311-1316. 10.1016/s0306-3623(96)00083-3
61 Amitani R, Taylor G, Elezis E-N, Llewellyn-Jones C, Mitchell J, Kuze F, Cole PJ, Wilson R. Purification and characterization of factors produced by Aspergillus fumigatus which affect human ciliated respiratory epithelium. Infect Immun. 1995; 63(9):3266–3271. 10.1128/iai.63.9.3266-3271.1995 7543879
62 Cole RJ, Cox RH. 11 - Epipolythiopiperazine-3,6-diones. In: Cole RJ, Cox RH, editors. Handbook of Toxic Fungal Metabolites. San Diego: Academic Press; 1981. p. 569–613. 10.1016/B978-0-12-179760-7.50016-4
63 Bünger J, Westphal G, Mönnich A, Hinnendahl B, Hallier E, Müller M. Cytotoxicity of occupationally and environmentally relevant mycotoxins. Toxicology. 2004; 202(3):199–211. 10.1016/j.tox.2004.05.007 15337583
64 Gauthier T, Wang X, Dos Santos JS, Fysikopoulos A, Tadrist S, Canlet C, Artigot MP, Loiseau N, Oswald IP, Puel O. Trypacidin, a spore-borne toxin from Aspergillus fumigatus, is cytotoxic to lung cells. PLoS One. 2012; 7(2):e29906. 10.1371/journal.pone.0029906 22319557
65 Deshpande S. Handbook of food toxicology. CRC Press; 2002. 10.1201/9780203908969
66 Dhumal SS, Salunkhe DK. Mycotoxins in foods. In: Tu AT, editor. Handbook of Natural Toxins: Food Poisoning. 1992. p. 291.
67 Stevanović J, Stanimirović Z, Pejin II, Lazarević M. Monitoring of mitotic index and frequency of micronuclei in evaluation of genotoxic potential of fumagillin (dicyclohexylamine) in vivo. Acta Vet (Beogr). 2006; 56(5-6):437–448. 10.2298/AVB0606437S
68 Stevanovic J, Stanimirovic Z, Radakovic M, Stojic V. In vitro evaluation of the clastogenicity of fumagillin. Environ Mol Mutagen. 2008; 49(8):594–601. 10.1002/em.20409 18613037
69 Fromme H, Gareis M, Völkel W, Gottschalk C. Overall internal exposure to mycotoxins and their occurrence in occupational and residential settings–An overview. Int J Hyg Environ Health. 2016; 219(2):143–165. 10.1016/j.ijheh.2015.11.004 26725999
70 Feng Y, Holte D, Zoller J, Umemiya S, Simke LR, Baran PS. Total synthesis of Verruculogen and Fumitremorgin A enabled by ligand-controlled C–H borylation. J Am Chem Soc. 2015; 137(32):10160–10163. 10.1021/jacs.5b07154 26256033
71 Watson DH, Moss MO. Toxic fungal metabolites in food. CRC Crit Rev Food Sci Nutr. 1985; 22(3):177–198. 10.1080/10408398509527414 3902369
72 Ueno Y, Hsieh DP. The toxicology of mycotoxins. CRC Crit Rev Toxicol. 1985; 14(2):99–132. 10.3109/10408448509089851 3158480
73 van Loevezijn A. Solid phase synthesis of fumitremorgin-type alkaloids based on cyclization/cleavage strategy. Amsterdam, The Netherlands: University of Amesterdam; 2002. https://pure.uva.nl/ws/files/3685409/20236_UBA002000834_06.pdf.
74 Khoufache K, Puel O, Loiseau N, Delaforge M, Rivollet D, Coste A, Cordonnier C, Escudier E, Botterel F, Bretagne S. Verruculogen associated with Aspergillus fumigatus hyphae and conidia modifies the electrophysiological properties of human nasal epithelial cells. BMC Microbiol. 2007; 7(1):5. 10.1186/1471-2180-7-5 17244350
75 Stoltz DR, Khera KS, Bendall R, Gunner SW. Cytogenetic studies with cyclamate and related compounds. Science. 1970; 167(3924):1501–1502. 10.1126/science.167.3924.1501 5415282
76 Stanimirovic Z, Stevanovic J, Bajic V, Radovic I. Evaluation of genotoxic effects of fumagillin by cytogenetic tests in vivo. Mutat Res. 2007; 628(1):1–10. 10.1016/j.mrgentox.2006.09.014 17258933
77 Weyel DA, Ellakkani M, Alarie Y, Karol M. An aerosol generator for the resuspension of cotton dust. Toxicol Appl Pharmacol. 1984; 76(3):544–547. 10.1016/0041-008X(84)90359-4 6506079
78 Frazer DG, Robinson VA, DeLong DS, Rose D, Tucker J, Weber KC, Olenchock SA, Jayaraman K. A system for exposing laboratory animals to cotton dust aerosol that is stabilized with feedback control In: Wakelyn PJ, Jacobs RR, editors. Proc 11th Cotton Dust Res Conf. Memphis, TN: National Cotton Council; 1987. p. 74-78.
79 Frazer DG, Robinson V, Olenchock SA, Hahon N, Barger M, Castranova V. Comparison of the guinea pig's physiological and cellular response to the respirable fraction of untreated, heat treated, microwave irradiated, and ethylene oxide treated DB 1/88 bulk cotton dust In: Wakelyn PJ, Jacobs RR, editors. Proc 15th Cotton Dust Res Conf. Memphis, TN: National Cotton Council; 1991. p. 246-251.
80 Frazer DG, Jones WG, Petsonk EL, Kullman GJ, Barger MW, Afshari A, Jones T, Castranova V. Organic dust exposure from compost handling: Response of an animal model. Am J Ind Med. 1993; 24(4):375–385. 10.1002/ajim.4700240404 8250058
81 McKinney W, Chen B, Frazer D. Computer controlled multi-walled carbon nanotube inhalation exposure system. Inhal Toxicol. 2009; 21(12):1053–1061. 10.1080/08958370802712713 19555230
82 Raabe OG, Al-Bayati MA, Teague SV, Rasolt A. Regional deposition of inhaled monodisperse coarse and fine aerosol particles in small laboratory animals. Inhaled Part. 1988;VI:53–63. 10.1016/B978-0-08-034185-9.50011-5
83 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
84 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
85 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
86 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
87 Dixon W, Massey F. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw Hill; 1957. p. 145–147, 276–278, 412.
88 Code of Federal Regulations (CFR). 21:Part 58.
89 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605–627.
90 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981; 67(2):233–241. 7021938
91 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA, Flamm WG, Lorentzen RJ, editors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing Co. Inc; 1985. p. 13–59.
92 Schmid W. The micronucleus test. Mutat Res. 1975; 31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
93 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity. A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983; 123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
94 Shelby MD, Erexson GL, Hook GJ, Tice RR. Evaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ Mol Mutagen. 1993; 21(2):160–179. 10.1002/em.2850210210 8444144
95 Shelby MD, Witt KL. Comparison results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995; 25(4):302–313. 10.1002/em.2850250407 7607185
96 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F(1) mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163-194. 10.1002/1098-2280(2000)36:3<163:AID-EM1>3.0.CO;2-P
97 National Toxicology Program (NTP). CEBS Data for Tox 100 - Aspergillis. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2020. 10.22427/NTP-DATA-TOX-100
98 Glaab T, Mitzner W, Braun A, Ernst H, Korolewitz R, Hohlfeld JM, Krug N, Hoymann HG. Repetitive measurements of pulmonary mechanics to inhaled cholinergic challenge in spontaneously breathing mice. J Appl Physiol (1985). 2004; 97(3):1104-1111. 10.1152/japplphysiol.01182.2003
99 Athanassiadou F, Kourti M, Papageorgiou T, Danielidis J. Invasive aspergillosis of the larynx in a child with acute lymphoblastic leukemia. Pediatr Infect Dis J. 2005; 24(2):190–191. 10.1097/01.inf.0000153171.16525.28 15702056
100 Barnes C, Berkowitz R, Curtis N, Waters K. Aspergillus laryngotracheobronchial infection in a 6-year-old girl following bone marrow transplantation. Int J Pediatr Otorhinolaryngol. 2001; 59(1):59–62. 10.1016/S0165-5876(01)00429-3 11376819
101 Bjorkholm M, Kalin M, Grane P, Celsing F. Long-term treatment of invasive sinus, tracheobroncheal, pulmonary and intracerebral aspergillosis in acute lymphoblastic leukaemia. Infection. 2012; 40(1):81–85. 10.1007/s15010-011-0158-9 21779887
102 Kingdom TT, Lee KC. Invasive aspergillosis of the larynx in AIDS. Otolaryngol Head Neck Surg. 1996; 115(1):135–137. 10.1016/S0194-5998(96)70149-3 8758643
103 Nagasawa M, Itoh S, Tomizawa D, Kajiwara M, Sugimoto T, Kumagai J. Invasive subglottal aspergillosis in a patient with severe aplastic anemia: A case report. J Infect. 2002; 44(3):198–201. 10.1053/jinf.2001.0935 12099752
104 Ran Y, Lu Y, Cao L, Li C, Dai Y, Yang H, Liu Y, Bai H, Zhang C. Primary laryngeal aspergillosis related to oral sex? A case report and review of the literature. Med Mycol Case Rep. 2012;2:1–3. 10.1016/j.mmcr.2012.11.002 24432202
105 Richardson BE, Morrison VA, Gapany M. Invasive aspergillosis of the larynx: Case report and review of the literature. Otolaryngol Head Neck Surg. 1996; 114(3):471–473. 10.1016/S0194-5998(96)70221-8 8649885
106 Everds NE, Snyder PW, Bailey KL, Bolon B, Creasy DM, Foley GL, Rosol TJ, Sellers T. Interpreting stress responses during routine toxicity studies: A review of the biology, impact, and assessment. Toxicol Pathol. 2013; 41(4):560–614. 10.1177/0192623312466452 23475558
107 Hoselton SA, Samarasinghe AE, Seydel JM, Schuh JM. An inhalation model of airway allergic response to inhalation of environmental Aspergillus fumigatus conidia in sensitized BALB/c mice. Med Mycol. 2010; 48(8):1056–1065. 10.3109/13693786.2010.485582 20482452
108 Samarasinghe AE, Hoselton SA, Schuh JM. A comparison between intratracheal and inhalation delivery of Aspergillus fumigatus conidia in the development of fungal allergic asthma in C57BL/6 mice. Fungal Biol. 2011; 115(1):21–29. 10.1016/j.funbio.2010.09.013 21215951
109 Innes JR, Ulland BM, Valerio MG, Petrucelli L, Fishbein L, Hart ER, Pallotta AJ, Bates RR, Falk HL, Gart JJ, et al. Bioassay of pesticides and industrial chemicals for tumorigenicity in mice: A preliminary note. J Natl Cancer Inst. 1969; 42(6):1101–1114. 5793189
110 Ochiai E, Kamei K, Watanabe A, Nagayoshi M, Tada Y, Nagaoka T, Sato K, Sato A, Shibuya K. Inhalation of Stachybotrys chartarum causes pulmonary arterial hypertension in mice. Int J Exp Pathol. 2008; 89(3):201–208. 10.1111/j.1365-2613.2008.00585.x 18460072
111 Mircescu MM, Lipuma L, van Rooijen N, Pamer EG, Hohl TM. Essential role for neutrophils but not alveolar macrophages at early time points following Aspergillus fumigatus infection. J Infect Dis. 2009; 200(4):647–656. 10.1086/600380 19591573
112 Gersuk GM, Underhill DM, Zhu L, Marr KA. Dectin-1 and TLRs permit macrophages to distinguish between different Aspergillus fumigatus cellular states. J Immunol. 2006; 176(6):3717–3724. 10.4049/jimmunol.176.6.3717 16517740
113 Daley E, Emson C, Guignabert C, de Waal Malefyt R, Louten J, Kurup VP, Hogaboam C, Taraseviciene-Stewart L, Voelkel NF, Rabinovitch M, et al. Pulmonary arterial remodeling induced by a Th2 immune response. J Exp Med. 2008; 205(2):361–372. 10.1084/jem.20071008 18227220
114 Vonk-Noordegraaf A, Haddad F, Chin KM, Forfia PR, Kawut SM, Lumens J, Naeije R, Newman J, Oudiz RJ, Provencher S, et al. Right heart adaptation to pulmonary arterial hypertension: Physiology and pathobiology. J Am Coll Cardiol. 2013; 62(25) Supplement:D22–D33. 10.1016/j.jacc.2013.10.027 24355638
115 Ghosh S, Hoselton SA, Schuh JM. Allergic inflammation in Aspergillus fumigatus-induced fungal asthma. Curr Allergy Asthma Rep. 2015; 15(10):59. 10.1007/s11882-015-0561-x 26288940
116 Shreiner AB, Murdock BJ, Sadighi Akha AA, Falkowski NR, Christensen PJ, White ES, Hogaboam CM, Huffnagle GB. Repeated exposure to Aspergillus fumigatus conidia results in CD4+ T cell-dependent and -independent pulmonary arterial remodeling in a mixed Th1/Th2/Th17 microenvironment that requires interleukin-4 (IL-4) and IL-10. Infect Immun. 2012; 80(1):388–397. . 10.1128/IAI.05530-11 22064716
117 Nagayoshi M, Tada Y, West J, Ochiai E, Watanabe A, Toyotome T, Tanabe N, Takiguchi Y, Shigeta A, Yasuda T, et al. Inhalation of Stachybotrys chartarum evokes pulmonary arterial remodeling in mice, attenuated by Rho-kinase inhibitor. Mycopathologia. 2011; 172(1):5–15. 10.1007/s11046-011-9400-3 21505873
118 Bozza S, Gaziano R, Spreca A, Bacci A, Montagnoli C, di Francesco P, Romani L. Dendritic cells transport conidia and hyphae of Aspergillus fumigatus from the airways to the draining lymph nodes and initiate disparate Th responses to the fungus. J Immunol. 2002; 168(3):1362–1371. 10.4049/jimmunol.168.3.1362 11801677
119 Sutton P, Newcombe NR, Waring P, Mullbacher A. In vivo immunosuppressive activity of gliotoxin, a metabolite produced by human pathogenic fungi. Infect Immun. 1994; 62(4):1192–1198. 10.1128/iai.62.4.1192-1198.1994 7510665
120 Nieminen SM, Mäki-Paakkanen J, Hirvonen MR, Roponen M, von Wright A. Genotoxicity of gliotoxin, a secondary metabolite of Aspergillus fumigatus, in a battery of short-term test systems. Mutat Res. 2002; 520(1-2):161–170. 10.1016/S1383-5718(02)00202-4 12297156
121 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry-and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571