# Discussion

Aspergillus fumigatus is a saprophytic fungal species with a worldwide distribution.^22,23^ As referenced in Figure 2, the asexual life cycle predominates and involves the production of long chains of unicellular spores (conidia).^21,22^ Abiotic or biotic disturbance to the asexual reproductive structures results in the aerosolization of respirable spores into the environment.^21,22^ A. fumigatus is thermotolerant and can grow and persist in a broad range of soil temperatures (12°C–65°C).^23^ Because of these growth parameters, A. fumigatus has become an occupational hazard within the biowaste and general waste management industries.^25,26^ Viable A. fumigatus concentrations as high as 1 × 10^6^ colony-forming units (CFU) per m^3^ have been reported in working environments within the biowaste industry.^27-29^ Although relative abundance and concentrations might not be as high as those identified in the biowaste industry, A. fumigatus spore exposures occur daily, and estimates of 100 conidia/m^3^ indoor exposure have been reported.^22-24,42^ In damp indoor environments, exposure may be elevated due to fungal contamination of cellulose-based building materials with subsequent sporulation.^43^

To date, no reference limits for A. fumigatus have been proposed by the National Institute for Occupational Safety and Health (NIOSH) or the American Conference of Governmental Industrial Hygienists. Several European governmental agencies have suggested acceptable levels of A. fumigatus, including 500 CFU/m^3^ (Environment Agency of the United Kingdom) and an occupational exposure limit (OEL) of 50,000 CFU/m^3^ for mesophilic fungal contaminants (Germany’s Federal Institute for Occupational Safety and Health).^29^ Despite the number of exposure assessment studies and focus on A. fumigatus as an opportunistic fungal pathogen, limited datasets have characterized the toxicity of inhalation exposures to A. fumigatus. The present report describes a 3-month inhalation toxicology study of B6C3F1/N mice exposed to A. fumigatus viable conidia, with both heat-inactivated conidia as a particle control and an air-only control group. An estimated pulmonary deposition of 1 × 10^5^ A. fumigatus spores twice per week was selected for a 3-month pulmonary immunology study,^19,20^ as well as the 3-month study presented in this report. The estimated lung burden in the mice in these studies would be equivalent to that of a worker breathing a constant workplace air concentration of 4.7 × 10^6^ spores/m^3^ (4.3 μg/m^3^) for 1 week, working 8 hours per day for 5 days or equivalent to a worker breathing 3.2 × 10^4^ spores/m^3^ (0.029 μg/m^3^) for 8 hours per day, 5 days per week over a 40-year working career. This daily exposure is comparable to exposures in various occupational environments,^45^ including the biowaste industry,^27,28^ and is comparable to the German OEL of 50,000 CFU/m^3^ proposed for mesophilic fungal contaminants.^29^

Inhalation exposure for 3 months to an estimated pulmonary dose of 1 × 10^5^ viable A. fumigatus conidia did not elicit overt toxicity or result in >10% body weight loss compared to the air control group. There was evidence that A. fumigatus conidia produced histological changes in the larynx, lung, and bronchial lymph nodes. Although gross lesions were limited to the bronchial lymph nodes, a variety of nonneoplastic lesions were present in these organs in increased incidences in mice exposed to the viable A. fumigatus spores compared to mice in the heat-inactivated particle control groups and air control groups. Consistent lesions in the epithelium of the larynx at the base of the epiglottis were observed in both sexes of viable A. fumigatus-exposed mice. Low incidences of epithelial lesions were additionally reported overlying the arytenoid cartilage. Changes were characterized by squamous metaplasia of the larynx epithelium that included the loss of cilia and replacement of the cuboidal to columnar cells by flattened stratified squamous epithelium. This type of metaplastic epithelial change is a biological response to chronic irritation or injury. Similar pathological changes in laryngotracheal histology have been described in mice that were exposed to A. fumigatus via an orotracheal tube.^98^ Although human cases of tracheobronchial and laryngeal aspergillosis have also been reported in the literature,^99-105^ fungal hyphae were not observed in the larynx histological sections in this study, indicating that there was no active laryngeal fungal growth or infection in the animals exposed to the viable A. fumigatus.

Statistically significant increases in absolute and relative lung weights were observed for both sexes exposed to viable A. fumigatus compared to air control mice. The increased lung weights corresponded histologically to chronic active inflammation that involved perivascular infiltrates that often extended into immediately surrounding pulmonary interstitial tissue as well as intra-alveolar infiltration of macrophages. These data corresponded to the increase in peripheral blood neutrophil counts in males in the viable A. fumigatus-exposed group compared to the air control group. Increased lung weights were also associated with bronchiolar epithelial hyperplasia, bronchus-associated lymphoid tissue hyperplasia, and medial hypertrophy of arteries and arterioles.

In addition to the increased neutrophil count observed in the male viable A. fumigatus-exposed group compared to the air control group, the total white blood cell and differential counts were increased in the A. fumigatus-exposed group when compared to the heat-inactivated particle control group. The relevance of the observed hematologic changes between the male heat-inactivated particle control group and A. fumigatus-exposed group was questionable, however, due to the exposure-related changes observed in the heat-inactivated control group. Exposure of the male mice to heat-inactivated particles caused histopathological changes, although at a lower incidence or severity compared to the A. fumigatus-exposed group. In addition, lung inflammation was observed in the male heat-inactivated particle control group, although it differed from the A. fumigatus-exposed group—chronic inflammation versus chronic active inflammation (i.e., more neutrophils), respectively. A closer look at the heat-inactivated particle control male hematologic data revealed that the white blood cell count was lower than the air control group, although this was not statistically significant. The reduction in white blood cell count was driven mostly by a decrease in the lymphocyte count; the eosinophil count was also lower. The combination of these changes is suggestive of a chronic stress leukogram^106^ (i.e., exposure to the heat-inactivated particles could have caused chronic stress to the mice). In the A. fumigatus-exposed group, the inflammatory effects of exposure to the viable A. fumigatus outweighed any potential hematologic changes that one might observe from chronic stress of exposure. For these reasons, the observed hematologic pairwise changes between the male heat-inactivated particle control group and A. fumigatus-exposed group were considered to be due to biological variability and not an exposure-related effect.

Several rodent inhalation models of A. fumigatus pulmonary immunological responses have been published, reporting similar lung histopathological results, including increases in epithelial thickness, goblet cell metaplasia, and peribronchial collagen deposition compared to air control mice.^107,108^ The hybrid B6C3F1/N mouse strain used in this exposure study is resistant to disease and has low spontaneous disease rates compared with other strains and hybrids.^109^ The B6C3F1/N mouse strain has been widely used to study systemic toxicological responses and was selected for consistency with other National Toxicology Program (NTP) toxicology studies. Although the female parent of the hybrid B6C3F1/N mouse strain, C57BL/6, is Th1-biased, histopathological results of the airways are consistent with previously observed histopathology following fungal exposure in other strains of mice including BALB/cJ (Th2-biased)^18,19^ and ddY mice.^110^ The histological results of the current study agree with an earlier pulmonary immunology study conducted in BALB/cJ mice that used the same pulmonary dosing and exposure schedule, including the heat-inactivated particle control exposure.^19^ Histopathological analysis revealed fungal exposure-dependent pulmonary inflammation, cellular infiltration, goblet cell metaplasia, and peribronchial and perivascular collagen deposition. Flow cytometry analysis revealed significantly increased numbers of CD4+ T cells expressing cytokines that were associated with an allergic phenotype (Th2; IL-5 and IL-13). Following 13 weeks of A. fumigatus exposure, serum concentrations of immunoglobulin G (IgG1) and immunoglobulin E (IgE) were significantly increased in mice exposed to viable conidia compared to mice exposed to the heat-inactivated particle control or to air only.^20^ Additionally, T cells (IFN-γ+ or IL-17A+) that co-expressed IL-13 were observed in the airways of viable A. fumigatus-exposed mice compared to air control mice.^19^ Examination of the expressed genes confirmed expression of the Il4, Il13, and Il33 genes in mice exposed to the viable A. fumigatus.^47^ That preliminary study demonstrated a novel mechanism for immune responses to inhaled A. fumigatus and indicated the presence of germinating conidia in mice exposed to viable spores. The emergence of hyphae from germinating spores in the viable A. fumigatus group was hypothesized to lead to an allergic phenotype because similar immune responses were not observed in the heat-inactivated particle control group.^19^ Croston and colleagues also showed germinating A. fumigatus spores to be associated with C-type lectin domain family 7 member A surface receptors (Dectin-1; increased expression of Clec7a), which were predicted to interact with the cytokines IL-13 and IL-33.^47^ Spore germination may also be a precursor for the recruitment of neutrophils as shown by Mircescu et al.^111^ and may explain the higher numbers of neutrophils in the lungs of viable A. fumigatus-exposed male mice compared to air control mice. Similarly, germinating A. fumigatus conidia expose cell wall (1–3)-β-D glucan that binds to the pattern recognition receptor, Dectin-1, mediating downstream NF-κB, proinflammatory cytokines, and reactive oxygen species by monocyte-derived macrophages.^112^ In the current study, germinating A. fumigatus were directly observed (Figure 9B), albeit in very low numbers, and the neutrophilic perivascular infiltrates were only present in the mice exposed to viable A. fumigatus.

The data from the current study demonstrate that exposure to viable A. fumigatus was associated with the thickening of small- to medium-sized arteriole walls (medial hypertrophy) within the lungs of all exposed male and female mice. In male and female viable A. fumigatus-exposed mice, arterial medial hypertrophy was mild to moderately severe and affected approximately 10% to 75% of pulmonary arterioles. Remodeling of pulmonary arteries is characterized by the hypertrophy and hyperplasia of vascular smooth muscle and is defined as a lesion associated with pulmonary arterial hypertension^113^ that can affect pulmonary arterial pressure.^114^ Previous studies have shown that arteriole hypertrophy/hyperplasia is commonly associated with chronic inflammation such as hypersensitivity pneumonitis or chronic obstructive pulmonary disease, and immune-mediated processes have been implicated. Daley and colleagues showed that mice intranasally primed with A. fumigatus antigen developed thickening in the small- to medium-sized arteriole walls^113^ similar to that observed in male and female viable A. fumigatus-exposed mice in the current study. Although the specific A. fumigatus antigen remains uncharacterized, a Th2 antigen-mediated response characterized by an influx of CD4+ T cells, IL-4 and IL-13, and additional effectors into the airways are criteria identified for the induction of arteriole hyperplasia.^113,115^ In addition, Shreiner and colleagues identified a potential role of IL-10, independent of CD4+ T cells, as a driver of pulmonary arterial remodeling following repeated intranasal exposure to A. fumigatus conidia.^116^ Subchronic inhalation exposure to viable A. fumigatus conidia that resulted in the same allergic phenotype as previously reported^19^ is likely to be involved in the mechanism for the medial hypertrophy observed in all male and female mice exposed to viable A. fumigatus in the current study. A previously published study examining the pulmonary immune response following subchronic A. fumigatus exposure showed that inhalation of heat-inactivated particle controls did not result in medial hyperplasia (hypertrophy). As the responses following exposure to A. fumigatus are thought to be driven by the release of high molecular weight antigens during metabolic activation of spores, the lack of viability of the particle control or the destruction of antigens during the heat-inactivation process are variables that could contribute to the absence of medial hyperplasia/hypertrophy in the heat-inactivated particle control-exposed mice.^20^ Subchronic studies that exposed mice to 1 × 10^4^ Stachybotrys chartarum spores also showed similar arteriole lesions^110^ that depended on Th2-associated inflammation.^117^

Increased incidences of lymphocyte hyperplasia and plasma cell hyperplasia were observed in the bronchial lymph nodes of viable A. fumigatus-exposed mice compared to air control mice. These histopathological lesions were associated with gross enlargement of the affected bronchial lymph nodes. In a previous subchronic A. fumigatus inhalation study conducted by NIOSH, gross enlargement and expansion of lymph node cellularity was also observed.^19^ Flow cytometry analysis revealed lymph node preparations to consist primarily of B lymphocytes, CD4+ T cells, and CD8+ T cells that produced cytokine profiles similar to those obtained from bronchoalveolar lavage fluid.^19^ Mice that were intratracheally exposed to A. fumigatus conidia and hyphae also showed the expansion of thoracic lymph node cellularity that was in part due to the migration of dendritic cells with phagocytized A. fumigatus to peripheral lymph nodes for antigen presentation.^118^ The associated plasma cell infiltrates that expanded the medullary and subcapsular sinuses, as well as the medullary cords, supported bronchial lymph node enlargement through the proliferation of B cell lymphocytes in response to A. fumigatus antigen presentation.

A. fumigatus produces secondary metabolites with characterized toxicological effects.^55-57^ One observation of the current study was metaplasia of the larynx epithelium, loss of cilia, and marked airway inflammation in viable A. fumigatus-exposed mice. Collectively, these results suggest the involvement of secreted A. fumigatus secondary metabolites, such as gliotoxin, helvolic acid, or fumagillin, that have been shown previously to mediate direct tissue injury and remodeling. Previous studies have demonstrated cytotoxicity of A. fumigatus preparations to lung cells that included inhibition of cilia beat frequency, epithelial damage, and induction of cell apoptosis.^54,61,64,119^ Similarly, tremorgenic bioactive alkaloids, including fumitremorgin, tryptoquivaline, and verruculogen, demonstrated in previous studies of A. fumigatus,^58,70,71^ were not characterized in viable A. fumigatus preparations from the current study. Clinical observations associated with these secondary metabolites, however, also were not observed in mice exposed to the viable A. fumigatus conidia. Several of the secondary metabolites are additionally capable of adducting DNA, which could result in downstream genotoxic effects. In the current study, tests for micronucleus induction in bone marrow proerythrocytes showed no increases in the frequency of micronucleated polychromatic erythrocytes or micronucleated normochromatic erythrocytes in the peripheral blood of mice exposed to viable A. fumigatus or to the heat-inactivated particle control, indicating an absence of induced chromosomal damage. Although individual secondary metabolites were not investigated in this subchronic toxicity study, the results of previous studies suggest that in vivo germination of A. fumigatus spores following respiratory deposition may be a potential source of secondary metabolites with possible pulmonary and genotoxic effects.^120^

Significant findings from the current 3-month inhalation study in B6C3F1/N mice included increased lung weights in viable A. fumigatus-exposed mice relative to the air control groups accompanied by increased incidence of nonneoplastic lesions. In males and females exposed to viable A. fumigatus, lesions were primarily restricted to the larynx, lung, and bronchial lymph nodes. Laryngeal lesions consisted of squamous metaplasia of the epithelium localized at the base of the epiglottis. Lung histopathology findings included chronic active inflammation, medial hypertrophy of arteries and arterioles, goblet cell metaplasia, and bronchiolar epithelial hyperplasia. Lymphocyte hyperplasia and plasma cell hyperplasia were observed in lymph nodes. In male mice, the increased lung weights and observed histopathology were consistent with the increased circulating neutrophil counts compared with the air control groups. The results of the current 3-month toxicity study corroborate the results of a recent subchronic A. fumigatus pulmonary immunology study conducted by NIOSH with the same exposure system that showed Th2 antigen-mediated allergic inflammation in response to subchronic A. fumigatus inhalation exposure.^19,20^ In the current study, NTP also provides evidence of medial hypertrophy of the pulmonary arterioles in A. fumigatus-exposed mice but not in heat-inactivated particle-exposed mice, which has been previously characterized to be mediated by an influx of CD4+ IL-13-producing T cells. The results of the micronucleus test in peripheral blood of exposed mice were negative and demonstrated an absence of chromosomal damage. In conclusion, the results of the subchronic inhalation exposure of mice to viable spores of A. fumigatus provide evidence that the targets of A. fumigatus included the larynx, lung, and bronchial lymph nodes. The magnitude of effects appeared to depend on the viability of A. fumigatus spores, with histopathology revealing enhanced toxicity with exposure to viable spores compared to heat-inactivated particle controls, possibly due to the germination of the viable spores.

Under the conditions of this 3-month study, target organs identified in B6C3F1/N mice following inhalation exposure to A. fumigatus spores were the larynx, lung, and bronchial lymph nodes. Significant differences were observed between viable A. fumigatus exposure and both air control and heat-inactivated particle control exposures. These results build on initial NIOSH pulmonary immunology studies using the same exposure parameters and demonstrate that the immunological responses and histopathology could be enhanced by the viability of the A. fumigatus spores.