# Results

## Data Availability

The National Toxicology Program (NTP) and the National Institute for Occupational Safety and Health (NIOSH) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TOX-100.^97^

## Three-month Study

All male mice survived to the end of the study. Two female mice, one in the air control group and one in the heat-inactivated particle control group, died on day 73 and day 84, respectively. Both mice were found dead when removed from nose-only pods following exposure. Gross examination showed discoloration of the lungs, but the cause of death could not be determined (Appendix E).

Final survival and body weight data are shown in Table 2. Terminal mean body weights of male and female mice exposed to viable A. fumigatus spores were not significantly different from the air control groups or the heat-inactivated particle control groups, nor were terminal mean body weights significantly different between the heat-inactivated particle control groups and air control groups. The body weight gain among groups of both male and female mice over the course of the study was similar, as illustrated in Figure 5. Clinical observations collected throughout the duration of the study revealed no remarkable findings (Appendix E).

Table 2 Summary of Survival and Mean Body Weights of Male and Female Mice in the Three-month Inhalation Study of Aspergillus fumigatus Spores^a^

Exposure Agent | Survival | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Air Controls (%)
Male
Air Control | 10/10 | 25.7 ± 0.4 | 31.8 ± 0.7 | 6.0 ± 0.6 | –
Heat-inactivated Particle Control | 10/10 | 25.7 ± 0.5 | 32.1 ± 0.8 | 6.3 ± 0.7 | 101
Viable A. fumigatus | 10/10 | 26.4 ± 0.7 | 30.8 ± 1.2 | 4.3 ± 0.6 | 97
Female
Air Control | 9/10^b^ | 20.4 ± 0.4 | 26.6 ± 0.9 | 6.2 ± 0.5 | –
Heat-inactivated Particle Control | 9/10^c^ | 20.9 ± 0.5 | 26.7 ± 0.8 | 6.0 ± 0.5 | 101
Viable A. fumigatus | 10/10 | 20.8 ± 0.3 | 25.8 ± 1.0 | 5.0 ± 0.9 | 97

^a^ Weights and weight changes are presented as mean ± standard error. One-way analysis of variance was conducted, and no significant differences were observed between groups.

^b^ Day of death: 73.

^c^ Day of death: 84.

Figure 5

Growth Curves for Male and Female Mice in the Three-month Inhalation Study of Aspergillus fumigatus Spores

Data points represent mean body weight in grams, and error bars represent the standard deviation of the mean for male (A) and female (B) mice. Open circle: air control; open triangle: heat-inactivated particle control; open square: viable A. fumigatus.

Absolute lung weights were significantly increased in viable A. fumigatus-exposed mice compared to the air control groups (males: 43% and females: 68%) and compared to the heat-inactivated particle control groups (males: 36% and females: 52%) (Table 3). Similarly, mean relative lung weights of mice exposed to viable A. fumigatus were also significantly increased in male (47% and 45%) and female (75% and 59%) mice relative to the air control and heat-inactivated particle control groups, respectively (Table 3). The increases in absolute and relative lung weight between viable A. fumigatus-exposed and air control mice correlated with several histopathological lesions in the lungs of exposed mice.

Table 3 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male and Female Mice in the Three-month Inhalation Study of Aspergillus fumigatus Spores^a,b^

| Air Control | Heat-inactivated Particle Control | Viable A. fumigatus
Male
n | 10 | 10 | 10
Necropsy Body Wt. (g) | 31.8 ± 0.7 | 32.1 ± 0.8 | 30.8 ± 1.2
Lung
Absolute (g) | 0.21 ± 0.01 | 0.22 ± 0.01 | 0.30 ± 0.01**^##^
Relative (mg/g)^c^ | 6.71 ± 0.26 | 6.81 ± 0.27 | 9.89 ± 0.60**^##^
Female
n | 9 | 9 | 10
Necropsy Body Wt. (g) | 26.6 ± 0.9 | 26.7 ± 0.8 | 25.8 ± 1.0
Lung
Absolute (g) | 0.19 ± 0.01 | 0.21 ± 0.01 | 0.32 ± 0.01**^##^
Relative (mg/g) | 7.17 ± 0.15 | 7.90 ± 0.35 | 12.53 ± 0.66**^##^

** Statistically significant pairwise difference from air control at p ≤ 0.01.

^##^ Statistically significant pairwise difference from heat-inactivated particle control at p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed using one-way analysis of variance with post-hoc Tukey HSD test for all pairwise comparisons.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

A minimal (<4%) but statistically significant increase in the erythrocyte count in the female viable A. fumigatus group relative to the heat-inactivated particle control group was observed (Appendix E). There were no other changes in the female erythron and no changes observed in the male erythron (Appendix E). The minimal change in the female erythrocyte count was not considered related to exposure.

Relative to the air control groups, the neutrophil count was significantly increased in the viable A. fumigatus-exposed male mice (Table 4). In addition, the total leukocyte, neutrophil, lymphocyte, monocyte, and eosinophil counts were significantly increased in the viable A. fumigatus male mice compared to the heat-inactivated particle control group.

Table 4 Summary of Select Hematology Data for Male and Female Mice in the Three-month Inhalation Study of Aspergillus fumigatus Spores^a,b^

| Air Control | Heat-inactivated Particle Control | Viable A. fumigatus
Male
n | 10 | 10 | 10
Leukocytes (10^3^/µL) | 3.47 ± 0.16 | 2.87 ± 0.23 | 4.32 ± 0.37^##^
Neutrophils (10^3^/µL) | 0.56 ± 0.04 | 0.49 ± 0.04 | 0.97 ± 0.10*^##^
Lymphocytes (10^3^/µL) | 2.79 ± 0.14 | 2.28 ± 0.21 | 3.07 ± 0.26^#^
Monocytes (10^3^/µL) | 0.02 ± 0.01 | 0.02 ± 0.01 | 0.07 ± 0.03^##^
Eosinophils (10^3^/µL) | 0.10 ± 0.01 | 0.08 ± 0.00 | 0.20 ± 0.03^##^
Female
n | 8 | 9 | 9
Leukocytes (10^3^/µL) | 2.94 ± 0.33 | 2.85 ± 0.22 | 3.91 ± 0.42
Neutrophils (10^3^/µL) | 0.39 ± 0.05 | 0.43 ± 0.04 | 0.62 ± 0.07
Lymphocytes (10^3^/µL) | 2.47 ± 0.27 | 2.32 ± 0.20 | 3.07 ± 0.35
Monocytes (10^3^/µL) | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.09 ± 0.04
Eosinophils (10^3^/µL) | 0.06 ± 0.01 | 0.07 ± 0.01 | 0.12 ± 0.02

* Statistically significant pairwise difference from air control at p ≤ 0.05.

^#^ Statistically significant pairwise difference from heat-inactivated particle control at p ≤ 0.05.

^##^ Statistically significant pairwise difference from heat-inactivated particle control at p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Dunn (pairwise) test.

Gross pathology findings can be found in Appendix E. Enlarged gray bronchial lymph nodes were identified in 5/10 females in the viable A. fumigatus group. This observation corresponded histologically to hyperplasia (either lymphocyte hyperplasia, plasma cell hyperplasia, or both). One female in the heat-inactivated particle control group and one female air control mouse, both of which were found dead after exposure, had red discoloration of the lungs. Overall, no gross lesions were identified in any of the other organs evaluated in male or female study groups.

The incidences of nonneoplastic lesions were increased in the larynx, lung, and bronchial lymph nodes of viable A. fumigatus-exposed mice compared to the heat-inactivated particle control or air control groups. The incidences of nonneoplastic lesions were increased in the lung of heat-inactivated particle control-exposed mice compared to the air control groups (Table 5, Table 6, Table 7; Appendix E).

Table 5 Incidences of Nonneoplastic Lesions of the Larynx in Male and Female Mice in the Three-month Inhalation Study of Aspergillus fumigatus Spores^a^

| Air Control | Heat-inactivated Particle Control | Viable A. fumigatus
Male^b^ | 10 | 10 | 10
Epiglottis, Metaplasia, Squamous^c^ | 3 (1.0)^d^ | 0 | 9**^##^ (1.0)
Female | 10 | 9 | 10
Epiglottis, Metaplasia, Squamous | 0 | 1 (1.0) | 9**^##^ (1.0)
Epithelium, Ulcer | 0 | 0 | 1 (1.0)
Squamous Epithelium, Hyperplasia | 0 | 0 | 1 (1.0)

** Statistically significant pairwise difference from air control at p ≤ 0.01.

^##^ Statistically significant pairwise difference from heat-inactivated particle control at p ≤ 0.01.

^a^ Statistical analysis performed by the one-sided Fisher’s exact test.

^b^ Number of animals examined microscopically.

^c^ Number of animals with lesion.

^d^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Table 6 Incidences of Nonneoplastic Lesions of the Lung in Male and Female Mice in the Three-month Inhalation Study of Aspergillus fumigatus Spores^a^

| Air Control | Heat-inactivated Particle Control | Viable A. fumigatus
n | 10 | 10 | 10
Male^b^
Artery, Medial, Hypertrophy^c^ | 0 | 0 | 10**^##^ (2.1)^d^
Bronchiole, Epithelium, Hyperplasia | 0 | 0 | 9**^##^ (1.0)
Inflammation, Chronic | 0 | 3 (1.7) | 0
Inflammation, Chronic Active | 0 | 0 | 10**^##^ (2.7)
BALT, Lymphocyte, Hyperplasia | 0 | 7** (1.0) | 10** (1.0)
Goblet Cell, Metaplasia | 0 | 0 | 10**^##^ (1.9)
Lung, Fungus | 0 | 5* | 1
Lung, BALT, Fungus | 0 | 4* | 0
Female
Artery, Medial, Hypertrophy | 0 | 0 | 10**^##^ (2.6)
Bronchiole, Epithelium, Hyperplasia | 0 | 1 (1.0) | 8**^##^ (1.0)
Inflammation, Chronic | 0 | 7** (1.9) | 0
Inflammation, Chronic Active | 0 | 1 (3.0) | 10**^##^ (2.8)
BALT, Lymphocyte, Hyperplasia | 0 | 8** (1.0) | 10** (1.4)
Goblet Cell, Metaplasia | 0 | 1 (1.0) | 10**^##^ (1.8)
Lung, Fungus | 0 | 0 | 10**^##^
Lung, BALT, Fungus | 0 | 1 | 0

* Statistically significant pairwise difference from air control at p ≤ 0.05.

** Statistically significant pairwise difference from air control at p ≤ 0.01.

^##^ Statistically significant pairwise difference from heat-inactivated particle control at p ≤ 0.01.

BALT = bronchus-associated lymphoid tissue.

^a^ Statistical analysis performed by the one-sided Fisher’s exact test.

^b^ Number of animals examined microscopically.

^c^ Number of animals with lesion.

^d^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Table 7 Incidences of Nonneoplastic Lesions of the Bronchial Lymph Node in Male and Female Mice in the Three-month Inhalation Study of Aspergillus fumigatus Spores^a^

| Air Control | Heat-inactivated Particle Control | Viable A. fumigatus
Male^b^ | 7 | 9 | 9
Lymphocyte, Hyperplasia^c^ | 0 | 0 | 6*^##^ (1.8)^d^
Plasma Cell, Hyperplasia | 0 | 0 | 5*^#^ (1.6)
Inflammation, Granulomatous | 0 | 0 | 1 (1.0)
Lymph Node, Bronchial, Fungus | 0 | 2 | 0
Female | 8 | 10 | 10
Lymphocyte, Hyperplasia | 0 | 1 (1.0) | 9**^##^ (1.8)
Plasma Cell, Hyperplasia | 0 | 0 | 8**^##^ (1.5)
Lymph Node, Bronchial, Fungus | 0 | 0 | 1

* Statistically significant pairwise difference from air control at p ≤ 0.05.

** Statistically significant pairwise difference from air control at p ≤ 0.01.

^#^ Statistically significant pairwise difference from heat-inactivated particle control at p ≤ 0.05.

^##^ Statistically significant pairwise difference from heat-inactivated particle control at p ≤ 0.01.

^a^ Statistical analysis performed by the one-sided Fisher’s exact test.

^b^ Number of animals examined microscopically.

^c^ Number of animals with lesion.

^d^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

In the larynx of males and females, the incidences of squamous metaplasia of the epiglottis were significantly increased in the viable A. fumigatus groups relative to the air control groups and the heat-inactivated particle control groups (Table 5). One female in the viable A. fumigatus group had an ulcer in the epithelium of the larynx, and another female in that group had hyperplasia of the squamous epithelium of the larynx (Table 5). Although not significantly increased, these lesions may have been related to exposure to viable A. fumigatus.

Microscopically, squamous metaplasia in the larynx was seen as replacement of the normal ciliated epithelium at the base of the epiglottis in level I sections by nonkeratinized squamous epithelium (Figure 6). The severity of squamous metaplasia was minimal in all groups where it occurred and affected <50% of the epithelium at the base of the epiglottis. The ulcer was characterized by a focal loss of the squamous epithelium overlying the arytenoid cartilage in a level II section of the larynx, and the squamous epithelium hyperplasia consisted of a thickening of the squamous epithelium overlying the arytenoid cartilage in level I.

Figure 6

Histopathology Images of Larynxes Following Inhalation of HEPA-filtered Air or Viable Aspergillus fumigatus Spores for Three Months (H&E)

Larynx from an air control female mouse (A) and a viable A. fumigatus-exposed female mouse (B) at the base of the epiglottis (40x magnification). Squamous metaplasia at the base of the epiglottis of the larynx was seen as replacement of the normal ciliated epithelium (A, air control) by nonkeratinized squamous epithelium (B, arrowheads).

The lungs of the male and female viable A. fumigatus-exposed mice were characterized by numerous nonneoplastic lesions compared to those of the air control mice and the heat-inactivated particle control mice (Table 6). Nonneoplastic lesions were also observed in the heat-inactivated particle control mice at a higher incidence than in the air control mice.

In the lungs, the incidences of artery hypertrophy, medial, were significantly increased in the viable A. fumigatus-exposed males and females relative to either the air control groups or the heat-inactivated particle control groups (Table 6). Mild to moderate artery hypertrophy, medial, was present in all male and female viable A. fumigatus-exposed mice and was absent in all air control and heat-inactivated particle control mice (Table 6). Artery hypertrophy, medial, was characterized histologically by circumferential thickening of the tunica media of small and medium arterioles and arteries by concentric layers of hypertrophied and hyperplastic smooth muscle cells (Figure 7). Lesion severity was graded according to the proportion of the pulmonary arteries affected as follows: minimal severity (1) was <10% of the arteries affected, mild (2) was 10%–40% of the arteries affected, moderate (3) was 41%–75% of the arteries affected, and marked (4) was >75% of the arteries affected.

Figure 7

Histopathology Images of Lungs Following Inhalation of HEPA-filtered Air or Viable Aspergillus fumigatus Spores for Three Months (H&E)

Lung sections from air control female mice (A, C, E) and viable A. fumigatus-exposed female mice (B, D, F). At low magnification (4x), arterioles and inflammation are prominent in the viable A. fumigatus-exposed mouse lung (B) compared to the air control mouse lung (A). Compare the normal arterioles (arrows) with thin vessel walls in the lung from an air control female (C) to the arterioles with medial hypertrophy (arrows) in the viable A. fumigatus-exposed female (D). In the viable A. fumigatus-exposed female, there is circumferential thickening of the tunica media of arteries (arrows) by concentric layers of hypertrophied and hyperplastic smooth muscle cells, typically with narrowing of the vascular lumen (D) at 20x magnification. The viable A. fumigatus-exposed female mouse shows chronic active inflammation, seen as perivascular infiltrates of lymphocytes and neutrophils with neutrophilic infiltrates extending into vessel walls and histiocytic infiltrates in surrounding alveoli (white asterisk) (D). Compared to normal bronchioles in an air control female mouse (E), bronchiole epithelium hyperplasia (black arrowheads) and goblet cell metaplasia (white arrows) were seen in bronchioles of viable A. fumigatus-exposed mice (F) (40x magnification).

The incidences of bronchiolar epithelium hyperplasia were significantly increased in the viable A. fumigatus-exposed males and females relative to either the air control groups or the heat-inactivated particle control groups (Table 6). Minimal bronchiolar epithelium hyperplasia was seen in 9/10 males and 8/10 females exposed to viable A. fumigatus, and in 1/10 heat-inactivated particle control females (Table 6). Bronchiolar epithelium hyperplasia consisted of crowded, plump, often piled (2–5 cell layers thick), cuboidal, ciliated epithelial cells lining terminal bronchioles with occasional small papillary projections and extension into adjacent alveolar septa (Figure 7). Bronchiolar epithelium hyperplasia was considered to be of minimal severity (1) as it involved <10% of the bronchioles in all instances.

The incidences of chronic active inflammation in the lungs were significantly increased in the viable A. fumigatus-exposed males and females relative to either the air control groups or the heat-inactivated particle control groups (Table 6). Mild to moderate chronic active inflammation in the lungs was present in all male and female mice exposed to viable A. fumigatus spores and was absent in all air control mice and all but one of the females in the heat-inactivated particle control groups (Table 6). Microscopically, chronic active inflammation was seen as predominantly perivascular infiltrates of lymphocytes and abundant neutrophils and alveolar macrophages (Figure 7). The perivascular infiltrates frequently extended into surrounding alveolar septa and spaces and occasionally into vessel walls. The associated alveolar macrophages usually exhibited pale to brightly eosinophilic cytoplasm, which sometimes contained intracytoplasmic cell debris and/or variably shaped eosinophilic material. Multinucleated giant cells were often present in small numbers. The severity of chronic active inflammation in the lung was graded based upon the extent of lung involvement as follows: minimal severity (1) was <10% of the lung affected, mild (2) was 10%–40% of the lung affected, moderate (3) was 41%–75% of the lung affected, and marked (4) was >75% of the lung affected. This chronic active inflammation likely corresponded with the increased numbers of circulating neutrophils observed in the viable A. fumigatus groups compared to the air control groups (Table 4).

Chronic inflammation was seen in the lungs of 3/10 males and 7/10 females in the heat-inactivated particle control groups. In females, this chronic inflammation was significantly increased in heat-inactivated particle control groups relative to the air control groups (Table 6). This inflammation differed in character and severity from the chronic active inflammation observed in all viable A. fumigatus-exposed males and females and the single heat-inactivated particle control female. Microscopically, chronic inflammation in the lung was minimal to mild in severity and consisted of infiltrates of lymphocytes that were often perivascular but frequently extended into surrounding alveoli, along with rare neutrophils and variable numbers of alveolar macrophages. The macrophages associated with the chronic inflammation in the heat-inactivated particle control mice were mononuclear and contained abundant, sometimes foamy, pale tan cytoplasm.

The incidences of bronchus-associated lymphoid tissue (BALT) lymphocyte hyperplasia in the lung were significantly increased in the viable A. fumigatus-exposed males and females relative to the air control groups, but not when compared with the heat-inactivated particle control groups (Table 6). Similarly, the incidences of BALT lymphocyte hyperplasia were significantly increased in the heat-inactivated particle control-exposed males and females relative to the air control groups (Table 6). Minimal to mild BALT lymphocyte hyperplasia was present in all males and females exposed to the viable A. fumigatus and in 7/10 males and 8/10 females in the heat-inactivated particle control groups—but in none of the air control mice (Table 6). BALT lymphocyte hyperplasia was characterized microscopically by an increase in the size and/or number of lymphoid aggregates of BALT compared to that observed in animals in the concurrent air control groups. Minimal severity was characterized by two or more small lymphoid aggregates in the lung, and mild was characterized by several larger, nodular lymphoid aggregates.

The incidences of goblet cell metaplasia in the lung were significantly increased in the viable A. fumigatus-exposed males and females relative to the air control groups and the heat-inactivated particle control groups (Table 6). Minimal to mild goblet cell metaplasia was present in all males and females exposed to viable A. fumigatus, as well as a single female in the heat-inactivated particle control group (Table 6). Goblet cell metaplasia affected most to all of the epithelium in an individual airway and was characterized by increased numbers of goblet cells in the epithelium lining the bronchi and/or bronchioles (Figure 7). Because this change often affected both bronchi and bronchioles in any given animal, a subsite was not used in the diagnosis. The severity of this lesion was graded based upon the proportion of airways affected as follows: minimal severity (1) was <10% of the airways affected, mild (2) was 10%–40% of the airways affected, moderate (3) was 41%–75% of the airways affected, and marked (4) was >75% of the airways affected.

Histopathological analysis of lymph nodes showed no visible lesions in the mediastinal, mesenteric, or mandibular lymph nodes (Appendix E). In the bronchial lymph node, the incidences of lymphocyte hyperplasia and plasma cell hyperplasia were significantly increased in the viable A. fumigatus-exposed males and females relative to either the air control groups or the heat-inactivated particle control groups (Table 7). Bronchial lymph node lymphocyte hyperplasia occurred in 6/9 male and 9/10 female viable A. fumigatus-exposed mice and 1/10 heat-inactivated particle control female mice (Table 7). Bronchial lymph node lymphocyte hyperplasia was seen microscopically as increased numbers of lymphocytes within any of the compartments of the lymph node (Figure 8). Although the follicles were almost always involved, increased lymphocytes usually were present in the other compartments, such as the paracortex and medullary cords. Lymphocyte hyperplasia was considered minimal when the follicles, medullary cords, and/or paracortical regions were expanded by mature, medium-sized lymphocytes. Mild lymphocyte hyperplasia included the additional feature of small germinal centers rimmed by a prominent, but narrow, band of small mature lymphocytes. Moderate and marked hyperplasia were not seen in this study. The lesions of lymphocyte hyperplasia and plasma cell hyperplasia were often, but not always, present in the same bronchial lymph node. Lymphocyte hyperplasia and plasma cell hyperplasia accounted for the macroscopic enlargement of the bronchial lymph nodes observed in some viable A. fumigatus-exposed female mice.

Figure 8

Histopathology Images of Lungs with Bronchial Lymph Nodes Following Inhalation of HEPA-filtered Air or Viable Aspergillus fumigatus Spores for Three Months (H&E)

Bronchial lymph node from an air control female mouse (A) and a viable A. fumigatus-exposed female mouse (B) showing enlargement of the bronchial lymph node (2x magnification). At high magnification (40x; C, black box inset in B), there is lymphocyte hyperplasia, which was generally seen as increased numbers of lymphocytes in multiple compartments, including the cortex, follicles, paracortex, and medullary cords. In the medullary cords at high magnification (40x; D, white box inset in B), there is plasma cell hyperplasia. The lesions of “hyperplasia, plasma cell” and “hyperplasia, lymphocyte” were often (as here), but not always, diagnosed in the same bronchial lymph node.

Bronchial lymph node plasma cell hyperplasia occurred in 5/9 male and 8/10 female viable A. fumigatus-exposed mice (Table 7). Bronchial lymph node plasma cell hyperplasia was characterized by increased numbers of plasma cells within the medullary cords, sinuses, and/or paracortical regions that exceeded the number present in the bronchial lymph nodes of animals in the concurrent air control groups (Figure 8). Plasma cell hyperplasia was considered minimal when the sinuses, medullary cords, and/or paracortical regions were expanded by small clusters of plasma cells. Mild plasma cell hyperplasia included the features of minimal severity with the additional feature of continuous clusters of 15–25 cells. Increasing expansion by plasma cells would be a feature of moderate and marked infiltrates.

Additionally, minimal granulomatous inflammation of the bronchial lymph node was observed in a single viable A. fumigatus-exposed male mouse, which may have been related to exposure (Table 7).

Fungal organisms were not observed in H&E-stained sections. The presence of fungal spores in histological sections of lung, BALT, bronchial lymph node, liver, spleen, gallbladder, heart, and aorta was evaluated using Grocott’s methenamine silver (GMS)-stained sections. There were no gross or histological lesions observed in the standard three sections of the nasal cavity taken in NTP studies; therefore, GMS staining was not conducted on any nose tissue sections. GMS-positive structures consistent with fungal organisms (conidia) were observed in GMS-stained sections of lung, BALT, and bronchial lymph node in some mice from the heat-inactivated particle control groups and the viable A. fumigatus groups (Table 6, Table 7; Figure 9). No fungal organisms were observed with either stain in the liver, spleen, aorta, or heart. In viable A. fumigatus-exposed groups, fungal organisms were observed in the lung in 1/10 males and 10/10 females and in the bronchial lymph node in 1/10 females (Table 6, Table 7). In the heat-inactivated particle control groups, fungal organisms were observed in the lung in 5/10 males, in the BALT of the lung in 4/10 males and 1/10 females, and in the bronchial lymph node in 2/9 males (Table 6, Table 7). The fungal organisms were consistent with conidia, were 2–3 µm in diameter, and were present in extremely small numbers (i.e., <10 spores/section). They were most often intracellular within alveolar macrophages or multinucleated giant cells, but occasional extracellular spores in alveolar spaces were observed (Figure 9). Very rarely did the conidia appear to be germinating (Figure 9B).

Figure 9

Images of Fungal Spores Observed within the Lungs of Mice Following Inhalation of Aspergillus fumigatus Spores for Three Months

Grocott’s methenamine silver-positive structures consistent with A. fumigatus conidia were rarely observed, but, when present, were seen free within alveoli or within alveolar macrophages (A; heat-inactivated particle control male lung, 40x). Rarely, the fungal organisms appeared to be germinating (B; arrow, viable A. fumigatus female lung, 40x). Very low numbers of conidia were seen in bronchus-associated lymphoid tissue (C; heat-inactivated particle control male, 40x).

## Genetic Toxicology

No increases in the frequencies of micronucleated polychromatic and normochromatic erythrocytes were observed in the peripheral blood of male or female B6C3F1/N mice exposed to either viable A. fumigatus or the heat-inactivated particle control spores relative to the air control mice (Table B-2). These negative results in the micronucleus test indicate an absence of exposure-induced chromosomal damage in progenitor erythrocytes in the bone marrow.