# Materials and Methods

## Procurement and Characterization

### Culture of Aspergillus fumigatus

Aspergillus fumigatus (NIH Strain B-5233) was acquired from the American Type Culture Collection (ATCC^®^ 13073™). The strain was grown in bulk according to the culture methods presented in Appendix A. Fungal stock suspensions used throughout the study were prepared in sterile water and mixed with an equal volume of autoclaved 50% glycerol. The A. fumigatus suspensions were then transferred and stored at −80°C in 0.5 mL aliquots containing 25% glycerol to ensure the stability of the A. fumigatus strain.

Individual stock suspension aliquots were used weekly to inoculate two malt extract agar (MEA) plates for the cultivation of A. fumigatus according to the methods presented in Appendix A. Following 7–10 days of culture, A. fumigatus spores were liberated from individual MEA culture plates at weekly intervals using 2 mL of sterile water. The spore suspension was used to inoculate 10 g of autoclaved brown rice contained in a sterile petri dish with 7.5 × 10^6^ A. fumigatus spores. A total of 15 petri dishes were inoculated each week. The rice culture plates were disturbed 1–2 times a day to prevent rice aggregation. Following 10–14 days of growth, the A. fumigatus-laden rice cultures were divided into two groups destined to become the heat-inactivated particle control and viable A. fumigatus test article. The A. fumigatus heat-inactivated spore exposure served as a biological particle control, as fungal spore germination has been identified in National Institute for Occupational Safety and Health (NIOSH) laboratory studies to be an important component associated with the pulmonary immune response to A. fumigatus.^18-20^ A. fumigatus cultures for the heat-inactivated particle control groups were transferred to quartz plates and autoclaved for 15 minutes at 121°C according to the method in Appendix A. The plates for both exposure groups were then transferred to the NIOSH Inhalation Facility and stored in a desiccator for 3–4 days prior to study animal exposures.

### Quality Assurance

Quality assurance and quality control of viable A. fumigatus consisted of testing cultures each week using internal transcribed spacer gene sequencing. This method allowed the amplification and detection of potentially contaminating mycobiota sources as described in Appendix A. The majority of identified fungal DNA belonged to A. fumigatus with no contaminating fungi detected in the viable test article and very little contaminating DNA detected in the heat-inactivated particle control. Cultures were also tested weekly to ensure reproducibility and production of nonviable A. fumigatus spores (Appendix A). Heat inactivation resulted in an average of 99.87% reduction in A. fumigatus spore viability throughout the course of the study (Table A-1).

## Test Article Generation and Exposure System

As a part of an ongoing partnership with the National Toxicology Program (NTP), NIOSH initiated a series of pilot studies to develop and characterize an exposure system capable of simulating natural indoor and occupational fungal exposure. From these studies, the opportunistic fungal pathogen, A. fumigatus, was selected as a model organism due to its widespread exposure potential in the biowaste industry, the production of respirable unicellular asexual spores, and the lack of available toxicity data. Previous animal models of fungal exposure have instilled or directly aspirated animals with protein extracts or spores washed in a buffered solution. Although these studies have provided initial insight into innate and adaptive pulmonary immune responses, they do not simulate fungal exposure in indoor, outdoor, or occupational environments. Unlike other microbial contaminants, fungi are viable organisms that grow as saprophytes in the environment and that produce a range of bioaerosols, including spores, hyphae, and submicron fragments.^3^ Fungal bioaerosols are usually dry with the outer cell wall components intact. Immersion of spores and hyphal fragments in buffered solution may modify the outer cell wall, solubilizes outer cell wall antigens, and in some cases, may result in spore metabolic activation and germination prior to exposure of the animals. Each of these parameters could modulate toxicological responses to fungal particles following instillation or aspiration.

To control for these potentially confounding variables, NIOSH developed a computer-controlled acoustical generation system (AGS) that allows the aerosolization of dry fungal conidia (spores) into a chamber with the aim of replicating natural environmental exposures. Figure 3A shows the AGS based on a modified acoustically powered particle (Pitt-3) generator. The Pitt-3 generator, originally described by Weyel et al.,^77^ was purchased from the University of Pittsburgh and evaluated under conditions recommended by Frazer et al.^78^ The system was then fitted with a computer controller, and a number of design modifications were made^79,80^ for use by NIOSH to study the health effects caused by the inhalation of a wide variety of occupationally relevant dusts. In 2009, the AGS was used as the foundation for a new and improved system for dispersing nanomaterials,^77^ which was subsequently modified for fungal spore aerosolization as described by Buskirk et al.^18^ Fungi are grown on rice, a natural substrate, which is then placed on a rubber membrane in the AGS and aerosolized using acoustical energy. This method of fungal spore aerosolization mimics natural fungal exposures in the environment and enables the production of a homogenous spore suspension within the chamber (Figure 3B, Figure 3C). The AGS is linked to a multi-animal nose-only exposure chamber (Figure 3A). NIOSH has used this chamber in previous animal model studies that assessed diisocyanate exposures. The exposure chamber consists of a vertical cylindrical tower with animal tubes that radially project outward from the tower (Figure 3A). As spores are aerosolized in the exposure chamber, the mass concentration of spores can be monitored in real time and used to estimate the number of spores deposited within the animal’s lung as described by Buskirk et al.^18^

To date, NIOSH has conducted several pilot studies that have characterized the aerosolization, deposition, and pulmonary immune responses to the heat-inactivated particle control and viable A. fumigatus. In these studies, reproducible growth of A. fumigatus on autoclaved rice was achieved, and test articles were generated by the AGS (Figure 3B, Figure 3C). Aerodynamic and microscopic analysis of the aerosolized A. fumigatus indicated the production of a respirable homogenous spore suspension (Figure 3B) with no ultrastructural changes (Figure 3C). Deposition studies then confirmed that A. fumigatus spores localized to the upper and lower respiratory airways of mice. The AGS and nose-only chamber were then used in proof-of-concept studies to determine an optimal dose for subsequent NIOSH and NTP studies evaluating dry A. fumigatus spores.^18^ The pilot studies used a modified local lymph node assay to evaluate potential sensitization following exposures of approximately 1 hour per day, two times per week for 4 weeks. At a pulmonary deposition of 1 × 10^6^ spores, viable A. fumigatus induced body weight loss >10% and induced sensitization demonstrated by a 10-fold change in lymphocyte proliferation compared to the air control group in the pilot study. At 1 × 10^4^ spores, the test article marginally induced sensitization at the requisite stimulation index of 10. Repeated exposures at 1 × 10^5^ spores induced significant sensitization without body weight loss. An estimated pulmonary deposition of 1 × 10^5^ spores was then selected as the optimal dose for all future NIOSH pulmonary immunology and NTP toxicology studies of A. fumigatus.

Aerosolized viable A. fumigatus and the heat-inactivated particle control were delivered to male and female B6C3F1/N mice housed in a multi-animal nose-only exposure chamber via the AGS (Figure 3A). Animals were exposed two times per week for 3 months via inhalation. In addition, an air control group received the same HEPA-filtered air that was being used to deliver viable A. fumigatus, and the heat-inactivated particle control group was exposed as previously described.^18^

Inhalation exposures were achieved by weighing and then placing the mice in a custom built nose-only multi-animal exposure carousel that was connected to the AGS (Figure 3A) as described in McKinney et al.^81^ Mice were placed in random pods for each exposure to minimize the effects of small concentration differences observed within individual ports. Although the nose-only carousel houses up to 24 pods (Figure 3A), only 20 pods (10 male and 10 female mice) were used during each exposure. Additional ports served as sample ports for the collection and analysis of test articles. During exposures, air control and exposure animals were placed on different exposure carousels located in the same inhalation exposure room.

The B6C3F1/N mice were exposed to viable A. fumigatus or the heat-inactivated particle control until the DataRAM software estimated that a total of approximately 1 × 10^5^ spores had been deposited within the lungs during the 1-hour exposure session. Figure 4 shows the estimated pulmonary deposition following each exposure for the duration of the study. The AGS successfully generated the aerosolized test article and was able to reproduce it over the course of this study (Figure 4). It is important to note that an inherent variability in the sporulation of the test article will always exist when working with biological organisms. In addition, heat inactivation via autoclaving can potentially result in some of the organism sticking to the rice, which will make the aerosolization of the heat-inactivated test articles more difficult compared to the viable test articles. The estimation software used a mouse-lung-deposition model developed by the NIOSH Inhalation Facility, which was based on deposition measurements from Raabe et al.^82^ During viable A. fumigatus or heat-inactivated particle control exposures, lung-deposition calculations were achieved using real-time DataRAM mass concentration measurements and a previously described scaling factor that estimated the number of spores deposited in the lungs of mice in real time.^18,19^ The integrated value of mass deposition per unit time was calculated throughout the exposures. The AGS automatically turned off when the desired total spore deposition had been delivered to the mice; however, the mice continued to receive HEPA-filtered humidified (approximately 40% RH) air supplied at a flow rate of 6 L/minute until 60 minutes had been reached. The desired spore concentration for the viable A. fumigatus was usually reached more quickly than for the heat-inactivated particle control spores, but no exposure was longer than 60 minutes. Each exposure corresponded to a 60-minute average mass concentration of approximately 10 mg/m^3^. Gravimetric filters were also collected during each exposure to continually monitor and adjust the DataRAM calibration. Air control mice received HEPA-filtered air supplied to the chamber at the same flow rate (6 L/minute) and time (60 minutes) as A. fumigatus-exposed mice. All environmental conditions were kept constant in each carousel between control and exposed (viable A. fumigatus and heat-inactivated particle control) animals.

Figure 4

Estimated Pulmonary Deposition of Aspergillus fumigatus Spores for Each Exposure over the Course of the Three-month Study

Values represent the number of spores estimated to deposit in the lung for viable A. fumigatus (solid circles) and heat-inactivated particle control (open circles) exposure groups.

## Animal Source

Male and female B6C3F1/N mice (n = 20/exposure group and 20 sentinel mice) were obtained via an NTP liaison from the NTP colony maintained at Taconic Biosciences, Inc. (Germantown, NY).

## Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Animals. The NIOSH Inhalation Facility is an environmentally controlled barrier facility that is fully accredited by AAALAC. Studies were approved by the NIOSH Animal Care and Use Committee and conducted in accordance with all NIOSH animal procedures and policies.

## Three-month Study

Mice were approximately 5–6 weeks old on receipt. The animals were weighed, distributed randomly into groups of approximately equal initial mean body weights, and assigned to viable A. fumigatus, heat-inactivated particle control, or air control groups. Mice were initially identified via tail marking, using a permanent marker and a consecutive numbering system. Animals that weighed more or less than 10% of the mean of the group were placed in the sentinel group (n = 20). At 4 weeks and at the end of the study, serologic analyses for bacterial and viral pathogens were performed on 10 male and 10 female sentinel mice using the protocol of the NIOSH Sentinel Animal Program (Appendix D). Before the study, the mice were acclimated to the NIOSH animal facility for a minimum of 15 days. Then, to reduce potential stress from exposures, the mice were acclimated to the housing units used for the exposures (nose-only carousel) for 1 week (two 1-hour acclimations) before the initial fungal exposure. Study mice were placed individually in the carousel housing units (pods), and humidified HEPA-filtered air was supplied to the chamber for 1 hour on 2 separate days during the week before the initial exposures. After acclimation was complete and before the exposures began, the mice were tattooed using a consecutive numbering system.

Male and female B6C3F1/N mice were randomly assigned to viable A. fumigatus, heat-inactivated particle control, and air control groups. Using a modified NTP protocol, groups of 10 male and 10 female mice were placed in the exposure units on the carousel on the same 2 days of the week for 26 exposures (3 months). Male and female mice were exposed for 1 hour per day to 10 mg/m^3^ (resulting lung dose = 1 × 10^5^) viable A. fumigatus spores, 10 mg/m^3^ (resulting lung dose = 1 × 10^5^) heat-inactivated A. fumigatus conidia (particle control), or HEPA-filtered air (air control) that was delivered through the AGS into the nose-only exposure chamber at a flow rate of 6 L/minute. This estimated dose was also used in companion studies that evaluated pulmonary immunological responses to A. fumigatus spores.^20,47^

Following acclimation and exposures, the animals were transferred from the individual carousel housing pods to a standard cage environment located in an adjoining room within the facility. Male and female mice were housed in HEPA-filtered ventilated polycarbonate cages on autoclaved hardwood chip bedding. Male B6C3F1/N mice were individually housed during acclimation and the life phases of the study due to social incompatibilities, whereas female mice were housed in groups of five. The ambient temperature of the animal facility was maintained between 67°F and 76°F, and the relative humidity ranged between 20% and 75% (Table 1). The light/dark cycle was maintained at 12-hour intervals. Mice were provided feed and autoclaved tap water ad libitum, except when housed in the pods during acclimation or exposures. Sentinel mice selected during the acclimation period were housed within the same room and were free of viral and bacterial pathogens (Appendix D).

Table 1 Experimental Design and Materials and Methods in the Three-month Inhalation Study of Aspergillus fumigatus Spores

Three-month Study
Study Laboratories
National Institute for Occupational Safety and Health (Morgantown, WV) Battelle (Columbus, OH)
Strain and Species
B6C3F1/N mice
Animal Source
Taconic Biosciences, Inc. (Germantown, NY)
Time Held before Studies
20 days
Average Age When Studies Began
8 weeks
Date of First Exposure
September 15, 2014
Duration of Exposure
3 months
Date of Last Exposure
December 9, 2014
Necropsy Date
December 10, 2014
Average Age at Necropsy
21 weeks
Size of Study Groups
10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
1 (male), 5 (females)
Method of Animal Identification
Tail tattoo
Diet
Irradiated NTP-2000 wafers (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed at least weekly
Water
Autoclaved tap water (Morgantown, WV municipal supply) provided in water bottles, available ad libitum
Cages
HEPA-filtered, ventilated polycarbonate cages, in filtered and ventilated racks (Lab Products Inc, Seaford, DE). Cages that housed three or more female mice were changed weekly. Cages that housed two mice or fewer (males) were changed every other week.
Bedding
Autoclaved hardwood chip bedding (Teklad Certified Sani-Chips^®^; Envigo, Madison, WI); irradiated crinkle cut craft paper provided for nesting/enrichment (The Andersons, Inc.; Maumee, OH), changed with cage changes.
Animal Room Environment
Temperature: 71.31°F ± 1.44°F (min: 67.42°F; max. 75.17°F) Relative Humidity: 45.76% ± 11.49% (min: 22.09%; max: 74.55%) Room fluorescent light: 12 hours/day Room air changes: 10–15/hour
Test Article
Aspergillus fumigatus (A. fumigatus) spores: untreated (viable) or heat-inactivated particle controls NIH Strain B-5233; Aspergillus fumigatus Fresenius, anamorph (ATCC^®^ 13073™)
Exposure Concentrations
Estimated lung depositions: Air control: 0 (HEPA-filtered air only) Heat-inactivated particle control: 1 × 10^5^ nonviable A. fumigatus spores (exposure chamber mass concentration: 10 mg/m^3^) Test article: 1 × 10^5^ viable A. fumigatus spores (exposure chamber mass concentration: 10 mg/m^3^)
Type and Frequency of Observation
Observed once daily on nonexposure days (morning) and twice daily on exposure days (morning/afternoon). Clinical findings were recorded at each observation and at study termination. Animals were weighed initially and then weekly until the end of the study.
Method of Euthanasia
Intraperitoneal injection of a lethal dose of sodium pentobarbital (100–300 mg/kg; Fatal Plus, Vortech Pharmaceuticals, Dearborn, MI) followed by exsanguination via cardiac puncture
Necropsy
Necropsies were performed on all study mice. Organs weighed were epididymis (left and right), heart, kidneys (left and right), liver, lungs, ovaries (left and right), testes (left and right), and thymus.
Hematology
Blood was collected from all surviving study mice via cardiac puncture at study termination. Hematological analyses included hematocrit, erythrocyte count, reticulocyte count, hemoglobin, mean cell volume, mean cell hemoglobin, mean cell hemoglobin concentration, platelet count, and leukocyte count and differential.
Histopathology
Complete histopathology was performed on all study mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, aorta, bone marrow, brain, esophagus, eye, femur, gallbladder, Harderian gland, heart, intestine (large and small), kidney, larynx, liver, lung, lymph nodes (bronchial, mandibular, mediastinal, mesenteric), mammary gland, nose, pancreas, pancreatic islets, parathyroid gland, pituitary gland, salivary glands, skin, spleen, stomach, thymus, thyroid gland, trachea, and urinary bladder. Other male tissues examined included the epididymis, preputial gland, prostate gland, seminal vesicle, and testes. Other female tissues examined included the cervix, clitoral gland, ovary, uterus, and vagina.

Study animals were weighed upon initial receipt, and body weights were recorded weekly until the end of the study. Clinical observations were recorded daily for the duration of the study, once a day (morning) on nonexposure days, and twice a day (morning/afternoon) on exposure days. Information about the study design, facilities, and animal maintenance are provided in Table 1. The report on feed composition is provided in Appendix C.

At the completion of the 3-month study, the mice were injected intraperitoneally with a lethal dose of sodium pentobarbital (100–300 mg/kg). Peripheral blood for hematology and micronuclei determination was obtained via cardiac puncture. Whole blood (a minimum of 600 µL) was collected in tubes containing potassium ethylenediaminetetraacetic acid, and 400 µL was immediately processed for hematology using a ProCyte Dx hematology analyzer (IDEXX Laboratories, Inc., Westbrook, ME). Table 1 lists the parameters measured. A minimum of 200 µL of blood was immediately refrigerated and shipped to Integrated Laboratory Systems, LLC (ILS; Research Triangle Park, NC) for micronuclei determination.

Necropsies were performed at the NIOSH site by Battelle staff (Columbus, OH) in random order on all animals surviving to terminal sacrifice. The organs weighed at terminal necropsy included the left and right epididymis, heart, left and right kidney, liver, lungs, left and right ovary, left and right testis, and thymus. Bilateral organs were weighed and recorded separately. At necropsy, the tissues in Table 1 were examined in situ for gross lesions, removed, and then fixed and preserved in 10% neutral buffered formalin (NBF). Exceptions included the eyes and testes (epididymis and vaginal tunics of testes), which were initially fixed in Davidson's solution and modified Davidson's solution, respectively, then transferred into 10% NBF. The collected and fixed tissues were then shipped overnight to the Battelle facility and further processed and trimmed, embedded in paraffin, sectioned at a thickness of 5 µm, and stained with hematoxylin and eosin (H&E). Histological sections of aorta, gallbladder, heart, liver, lung (all five lobes), bronchial lymph node, and spleen were stained with Grocott’s methenamine silver (GMS) stain for fungal elements. Battelle laboratory pathologists conducted a complete histopathological examination on all air control, heat-inactivated particle control, and viable A. fumigatus-exposed mice. Table 1 lists the tissues and organs that were examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to an NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologist were resolved by the NTP pathology peer-review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist, and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^83^ and Boorman et al.^84^

## Statistical Analysis

### Calculation and Analysis of Nonneoplastic Lesion Incidences

The incidences of nonneoplastic lesions are presented as numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. Fisher’s one-sided exact test,^85^ a procedure that uses the overall proportion of affected animals, was used to determine significance between all pairs of the three exposure groups.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed using a one-way analysis of variance with post-hoc Tukey HSD test for multiple comparisons between all pairs of the three exposure groups. Hematology data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison method of Dunn.^86^ Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^87^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

## Quality Assurance Methods

The 3-month study was conducted in compliance with U.S. Food and Drug Administration Good Laboratory Practice Regulations whenever possible.^88^ In addition, the 3-month study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Study Report. Audit procedures and findings are presented in the reports and are on file at the National Institute of Environmental Health Sciences. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Report.

## Genetic Toxicology

The genetic toxicity of A. fumigatus was assessed by testing the ability of an A. fumigatus extract to increase the frequency of micronucleated erythrocytes in mouse peripheral blood. The protocol for the micronucleus assay and the results are given in Appendix B.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database that would facilitate critical anticipation of a chemical’s carcinogenicity in experimental animals, using the results from several in vitro and in vivo short-term tests that measure functionally distinct genotoxicity endpoints. The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^89^ and the somatic mutation theory of cancer.^90,91^ Of note, however, is that not all cancers arise through genotoxic mechanisms.

### Peripheral Blood Micronucleus Test

Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^92,93^ The predictivity for carcinogenicity of a positive response in acute in vivo bone marrow chromosome aberration or micronucleus tests appears to be less than that in the Salmonella test.^94,95^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^96^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical. The protocol for these studies and the results are given in Appendix B.