# Introduction

Figure 1

Aspergillus fumigatus Fresenius

Botanical Name: Aspergillus fumigatus. Synonyms: Aspergillus fumigatus (A. fumigatus); NIH Strain B-5233 (a clinical strain isolated in a case of invasive aspergillosis from a patient with leukemia ); Aspergillus fumigatus Fresenius, anamorph (ATCC^®^ 13073™). The light microscopic image depicts asexual Aspergillus fumigatus reproductive structures composed of a septate hyphae, conidiophore, and chains of conidiospores.

Photo courtesy of CDC; CDC Public Health Image Library ID #300.

## Fungi, Indoor Environmental Quality, and Public Health

The fungal kingdom is a diverse lineage of eukaryotic microorganisms consisting of approximately 1.5 million species.^1^ Fungi grow in a wide variety of lifeforms and include unicellular yeasts, filamentous hyphae, or a combination of both life cycles (dimorphism) that include species with the ability to switch between yeast and filamentous forms on the basis of temperature and nutrient profiles. Fungi reproduce via meiotic or mitotic processes and produce spores or conidia that vary morphologically and can be aerosolized into the breathing zone of a person following abiotic or biotic colony disturbance. In addition to spores, small submicronic fragments of hyphae can also be released from the colony, and, in some cases, these bioaerosols can be released in greater concentrations than spores.^2-5^

In the environment, fungi predominate as saprophytes; as such, they have positive and negative effects on the environment, industry, and human health. Fungi and fungal-derived products have broad industrial utility ranging from the production of food (yeast, fermentation), detergents (enzymes), and pharmaceuticals (penicillin).^6^ The negative impacts that fungi have on society are more widely recognized by the public, however, especially after a cluster of infant pulmonary hemorrhage/hemosiderosis cases in the United States,^7,8^ as well as the effects on indoor environments resulting from natural disasters, including Hurricanes Katrina, Rita, Sandy, Harvey, Irma, and Maria. The growth of mold within the indoor built environment has led to public health and community concern over the potential pulmonary and neurological health effects associated with the inhalation of fungal spores, hyphae, and secondary metabolites such as mycotoxins and volatile organic compounds that may be released during fungal growth and colonization. Fungal secondary metabolites are frequently associated with sporulation and development and are produced late in the growth phase of the organism.^9^

Moisture infiltration in the indoor built environment can lead to mold growth; consequently, contamination of building materials has been the focus of numerous indoor air quality investigations over the last three decades. In 1994, epidemiological evidence of pulmonary hemorrhage/hemosiderosis in a cluster of Cleveland infants (n = 10)^7,8^ drew further attention to the negative impacts associated with fungal exposure in damp indoor environments. The investigation into the reported cases showed that infants with acute pulmonary hemorrhage/hemosiderosis were more likely to reside in water-damaged homes compared to non-damaged homes.^7^ The investigation additionally identified the toxigenic fungal species S. chartarum (synonym S. atra) to be in higher concentrations in case homes compared to control homes.^7^ A subsequent Centers for Disease Control and Prevention review of the Cleveland investigation^10^ identified that the associations in the initial epidemiological investigations were not supported. The initial findings had a significant effect on the community, however, and fostered the citation of the study in a range of government, academic, and public forums that ultimately led to litigation and even the closure of buildings.^10^

Since the Cleveland investigation, consensus reports have been published by the Institute of Medicine (IOM), Committee on Damp Indoor Spaces and Health,^11^ and the World Health Organization (WHO),^12^ evaluating the role of indoor dampness and fungal exposures on human health. The reports presented sufficient epidemiological evidence of associations between personal exposure to damp indoor environments or the presence of mold indoors with several respiratory symptoms.^11,12^ Recent meta-analyses have further confirmed the IOM and WHO consensus reports and identified additional associations between visible mold, mold odor, and allergy/asthma in damp indoor environments,^13-15^ although associations with individual fungal species and culturable fungi were limited.^16^ A 2016 cost estimate analysis has placed the economic burden of fungal exposure-related illness to be as high as $3.7 billion for allergic rhinitis and $15.1 billion for asthma morbidity.^17^ To date, the role of fungi and the physiological changes that follow exposure remain uncharacterized and in some cases completely misunderstood for indoor-contaminating fungal species. Numerous data gaps exist concerning the role of fungi in the areas of neurotoxicology, rheumatic diseases, reproduction, and cardiopulmonary disease. This lack of data has hindered understanding of the physiological consequences of fungal exposures and has resulted in no standardized methods or exposure limits for fungi.

To address some of these knowledge gaps, fungi were nominated to the National Toxicology Program (NTP) for investigation. In 2004, the NTP Board of Scientific Councilors and Executive Committee endorsed the study of fungi. The committee suggested studying fungal species commonly identified in indoor air, including Aspergillus, Penicillium, and Stachybotrys species. An expert review panel was convened in 2007 to discuss the study design for NTP subchronic toxicity studies. Several key areas that would have a direct bearing on study design were identified and considered, including colony growth conditions, life cycle, and biochemical makeup of the species. The panel recommended evaluating confluent fungal colonies derived from a single fungal species, as well as mixtures of fungal colonies co-cultured on building materials commonly used in the indoor environment. Variables related to the production, characterization, and reproducibility of the test material were also considered. The National Institute for Occupational Safety and Health (NIOSH) participated in the 2007 expert review and was identified as a partner to conduct the subchronic (13-week) fungal exposure studies due to their prior experience and expertise in microbial immunology and aerosol science.

As a part of an ongoing partnership with NTP, NIOSH initiated a series of pilot studies to develop and characterize an acoustical generation system (AGS) capable of simulating natural indoor and occupational fungal exposure. NIOSH has utilized the AGS and nose-only chamber in studies to characterize the pulmonary immune responses to dry viable and nonviable A. fumigatus conidia. In these studies, BALB/cJ mice were repeatedly exposed to 1 × 10^5^ A. fumigatus conidia via inhalation twice a week for 4 or 13 weeks. In the 4-week study, histopathological analysis of lung sections showed moderate to severe inflammation, mucus production, bronchiolar pneumonia, and tissue remodeling/fibrosis. Increased incidence of neutrophils and eosinophils were observed surrounding the larger airways, and giant cell formation was apparent in mice 24 hours following the final (eighth) exposure. Flow cytometry analysis showed total CD8+ T cells were increased in bronchoalveolar lavage fluid (BALF) at 24 hours, and approximately 33% of the CD8+ T cell numbers were CD8+IL-17+ T cells (Tc17), which peaked at 24 hours.^18^ Importantly, swollen conidia were observed at 4 hours, and by 24 hours, many conidia had begun to germinate. Emergence of hyphae from spores also correlated with an increase in Tc17 cell populations.^18,19^ This study was among the first to demonstrate in vivo A. fumigatus germination following spore exposures in an animal model.^18,19^

NIOSH also completed a pilot 13-week subchronic study to examine pulmonary immune endpoints using B6C3F1/N mice.^20^ In this study, mice were exposed twice a week for 13 weeks to dry viable A. fumigatus spores and compared to an air control group. Repeated exposures with viable spores revealed fungal dose-dependent pulmonary inflammation, cellular infiltration, goblet cell metaplasia, and peribronchial and perivascular collagen deposition. Flow cytometry of BALF showed CD4+ T helper (Th) cells expressing cytokines associated with an allergic phenotype [Th2; interleukin- (IL-) 5 and IL-13]. These cell populations were present in significantly increased numbers in the airways of animals dosed with viable A. fumigatus spores. The responses were accompanied by an increase in total serum immunoglobulin E (IgE) and development of immunoglobulin G (IgG) antibodies to A. fumigatus-specific proteins. The results of this study further supported the hypothesis that spore viability is a critical variable of fungal exposures that affected Th1/Th2 differentiation in mice. Compared with the 4-week repeated exposure study, these experiments demonstrated a shift toward a Th2-mediated response in animals that received 13 weeks of repeated exposures.

The overall goal in this series of studies was to characterize the hazards associated with exposure to A. fumigatus, a common fungal contaminant in indoor and occupational environments. The aim was to advance understanding of the toxicological and pulmonary immune responses associated with subchronic fungal exposures using a model that replicates human exposure conditions found in damp or water-damaged buildings. The data derived from these studies will provide further understanding of the species that can elicit adverse health effects. To address these experimental aims, NIOSH applied the same AGS and methodologies used in preliminary pulmonary immunological studies to characterize A. fumigatus toxicological endpoints following subchronic fungal spore exposures.

## Chemical and Physical Properties

The genus Aspergillus includes a diverse group of approximately 250 species within the Ascomycota order Eurotiales.^21^ A. fumigatus is environmentally ubiquitous and a common source of opportunistic fungal infections that were first described by Fresenius in 1863.^21^ The species is characterized by an anamorphic (asexual) life cycle (Figure 2) as well as a sexual phase (Neosartorya). The anamorphic phase is placed in the section Fumigati and is characterized by the production of chains of unicellular conidia (spores) that emerge from uniseriate phialides presented from conidiophores that consist of flask-shaped vesicles.^21,22^ A. fumigatus is abundant in indoor, outdoor, and occupational environments because it produces respirable-sized green echinulate globose-to-subglobose spores composed of a rodlet hydrophobic layer (2–3 µm spore diameter).^21-23^ The spores are continuously generated via a rapid sporulation process and are easily aerosolized into the environment following abiotic or biotic disturbance.^21-23^

Figure 2

A Representative Life Cycle of Fungi in the Order Eurotiales

## Production, Use, and Human Exposure

A. fumigatus is a ubiquitous saprophytic fungal species that has a worldwide distribution.^22,23^ It is found within the soil, where it is involved in the breakdown of plant-derived polysaccharides through the secretion of glycosyl hydrolases and proteases.^21-24^ A. fumigatus is thermotolerant and can grow and proliferate in self-heating compost piles and waste management plants.^21,23,25^ These growth conditions have become problematic in several occupational environments that produce compost. A. fumigatus has been identified as a harmful biological contaminant as well as an indicator organism within the composting industry.^26^ In occupational environments, highest concentrations of fungi, including A. fumigatus, have been measured in dusty working areas during shredding and processing activities.^27^ Airborne fungal concentrations are measured using multiple approaches, such as plating viable spores for determination of colony-forming units (CFU)/m^3^ or microscopic spore counting of viable and nonviable conidia (conidia/m^3^). Airborne A. fumigatus concentrations as high as 1 × 10^6^ CFU/m^3^ have been reported in occupational environments.^28,29^ Eleven secondary metabolites that were produced from cultured A. fumigatus strains collected in biowaste processing environments have been characterized.^30^ Other occupational environments where A. fumigatus has been detected in elevated concentrations include residual waste collection,^31^ the animal feed industry,^32^ grass seed production,^33^ baking,^34^ podiatry clinics,^35^ swine and poultry processing,^36^ ceramic production,^37^ professional cleaners,^38^ indoor workplaces,^39^ hospitals,^40^ and corn silage.^41^ Spores of A. fumigatus have also been detected in other indoor environments. Although the relative abundance and concentrations may not be as high as those identified in some occupational settings, investigators have noted that A. fumigatus is ubiquitous in the environment and exposure occurs daily. Human exposure has been estimated at 1–100 conidia/m^3^ in indoor environments.^22-24,42^ In damp indoor environments, exposure can be elevated due to the contamination of cellulose-based building materials.^43^ A secondary source of A. fumigatus could also be from indoor plants^44^; however, anthropogenic and outdoor transport are the likely sources of most exposures.

## Regulatory Status

To date, no exposure limits for A. fumigatus have been proposed by NIOSH or the American Conference of Governmental Industrial Hygienists. An evaluation of human, animal, and epidemiological datasets by Eduard^45^ of Norway’s National Institute of Occupational Health has identified a lowest-observed-effect level of 1 × 10^5^ spores/m^3^. In 2010, the Environment Agency of the United Kingdom provided guidance on the acceptable levels of microbial contaminants emitted from composting operators.^29^ Although not determined from dose-response relationships, airborne levels of A. fumigatus were set at 500 CFU/m^3^ within 250 meters of a composting facility.^29^ In Germany, the Federal Institute for Occupational Safety and Health set an occupational exposure limit of 50,000 CFU/m^3^ for mesophilic fungal contaminants that also include A. fumigatus.^29^

## Toxicity

Unlike low molecular weight chemicals that are traditionally studied by NTP, fungi are eukaryotic microorganisms. With fungi, the hyphae, fragments, spores, and reproductive propagules are all agents of personal inhalation exposure.^3^ In addition to nonviable particles, an individual can be exposed to viable spores that can metabolically activate following in vivo deposition. Spore germination follows and can result in the release of immunologically active proteins and secondary metabolites.^3,5,6,46^ The cell wall of A. fumigatus contains numerous components, some of which stimulate the host’s immune system, such as (1–3)-β-D glucan (or other high molecular weight proteins), and others that may suppress the host immune system, such as gliotoxin (or other secondary metabolites). These proteins and secondary metabolites, in combination with spore viability, result in a multifaceted pulmonary immune response involving a combination of innate and adaptive immune mechanisms.^18-20,47^

Although numerous studies have identified and characterized fungal spore exposures in indoor, outdoor, and occupational environments, the toxicity of individual fungal proteins, secondary metabolites, and mycotoxins remains less clear. Personal exposure to A. fumigatus spores can result in a variety of adverse health effects, but the most commonly reported include invasive aspergillosis in immunocompromised subjects^22^ and allergic bronchopulmonary aspergillosis.^48,49^ Other adverse respiratory conditions exacerbated by A. fumigatus include occupational rhinitis,^39^ occupational asthma,^50^ hypersensitivity pneumonitis,^34,50^ and organic dust toxic syndrome.^33,51^

A. fumigatus produces approximately 100 proteins that can bind immunoglobulin,^22^ as well as a broad diversity of secondary metabolites. Whole genome sequencing of A. fumigatus has resolved 58 allergens and 9 additional predicted allergens that include secreted proteinases, glucanases, and cellulases.^52,53^ The International Union of Immunological Societies currently recognizes 23 A. fumigatus allergens. Ribotoxin (Asp f 1) is one of the most broadly characterized A. fumigatus allergens that is expressed during spore germination and emergence of A. fumigatus hyphae.^46^ Exposure to Asp f 1 ranges from 7.6 to 29 ng/m^3^ in outdoor air samples.^46^ In addition to immunoglobulin binding proteins, A. fumigatus produces a variety of enzymes, including but not limited to, serine proteases, aspartic proteases, metalloproteinase, dipeptidyl peptidase, catalase, superoxide dismutase, and phospholipase.^42^

In addition to high molecular weight proteins, A. fumigatus produces toxic secondary metabolites capable of eliciting acute or chronic health effects.^54^ Whole genome sequencing of A. fumigatus has identified 39 predicted secondary metabolism gene clusters,^55-57^ although over 400 fungal mycotoxins or secondary metabolites have been characterized.^54^ The pioneering chemical characterization studies by Guido Fischer^30,58^ and Frisvad and Sampson^59^ provided preliminary insight into the species-specific secondary metabolite profiles derived from strains cultured from biowaste environments. In these studies, nine nonvolatile secondary metabolites were identified in culture and in conidial extracts and included gliotoxin, citrinin-like compound, fumagillin, fumigatin, fumiclavine A and C, fumitremorgin C, tryptoquivaline, trypacidin, and verruculogen.^30,59^

Secondary metabolites produced by A. fumigatus, including ferricrocin, DHN melanin, fusarinine C, helvolic acid, and gliotoxin, have roles in mediating virulence and toxic effects.^55^ Gliotoxin has been widely characterized for antimicrobial and immunosuppressive effects.^57,60^ Studies have shown gliotoxin to suppress cilia beat frequency, neutrophil function, T and B cell proliferation, protein synthesis, and phagocytosis, as well as inactivate alcohol dehydrogenase and cause epithelial damage.^54,57,60,61^ Toxicology studies have shown gliotoxin to be acutely toxic [as measured by median lethal dose (LD50)] to rabbits (LD50 = 45 mg/kg), mice (LD50 = 50 mg/kg), and rats (LD50 = 50–65 mg/kg).^62^ In vitro studies have shown gliotoxin to have an IC_50_ of 0.3 µM in L-929 and A549 cell lines and 1.2 µM and 0.6 µM in Neuro-2a and HepG2 cell lines, respectively.^63^ Waring and Beaver also reported that 0.1–3 µM gliotoxin resulted in DNA fragmentation in some immune cells and concentrations >10 µM induced apoptosis and cell death.^60^ Other A. fumigatus secondary metabolites, such as fumagillin and helvolic acid, are also immunosuppressive but only at higher concentrations than gliotoxin.^54^

Trypacidin, a secondary metabolite localized on A. fumigatus conidia, has antiprotozoal activities and is a potential virulence factor.^64^ In vitro studies have also shown trypacidin to reduce cell viability and to induce cell lysis at an IC_50_ of 7 µM, demonstrating toxicity to lung cells.^64^ Helvolic acid (syn. fumigacin) is an antibacterial nortriterpenoid/metabolite produced by A. fumigatus and has also been shown to produce liver, peritoneal, and superficial lesions following repeated intraperitoneal injections.^65,66^

Fumagillin is an additional A. fumigatus secondary metabolite that has been characterized to inhibit angiogenesis. Compared to gliotoxin, fumagillin is over 100-fold less cytotoxic to A549 cells but can inhibit endothelial cell proliferation and inhibit cilia beat frequency.^61,63^ Although oral administration of up to 2,000 mg/kg could be tolerated in rodent models,^65,66^ dermal exposure can be highly toxic and result in skin peeling from hands and feet as well as sensory disturbances.^65^ Fumagillin has also been shown to have genotoxic effects by adducting DNA,^61,63^ resulting in a decreased mitotic index and increased micronuclei in erythrocytes.^67,68^

Several secondary metabolites produced by A. fumigatus have specific central nervous system effects.^69^ Tremorgenic mycotoxins are bioactive alkaloids that include fumitremorgin, tryptoquivaline, and verruculogen.^70,71^ Along with gliotoxin, verruculogen has the highest known toxicity of all the A. fumigatus secondary metabolites and can cause tremors.^58^ However, the production of tremorgenic mycotoxins may be associated only with a growing mycelium and not with bioaerosols, suggesting that these secondary metabolites may not be an acute hazard in occupations such as the waste handling industry.^58^ Animal studies have shown fumitremorgin to be a potent neurotoxin: Concentrations as low as 0.15 mg/kg elicited mild tremor following intravenous injection, and convulsion was induced with 0.3 mg/kg.^72^ Fumitremorgin B and C administered to mice (1.0 mg/kg) and cockerels (25 mg/kg) were tremorgenic.^73^ In vitro studies have additionally shown verruculogen to alter the electrochemical properties of human nasal epithelial cells,^74^ and a dose of 2.4 mg/kg resulted in a lethality of 50%.^72^ To date, little is known about toxicological responses to tryptoquivaline, and few studies have evaluated this secondary metabolite in occupational environments.^72^

The results of these combined immunological and toxicological studies demonstrate that A. fumigatus is a complex eukaryotic microorganism that produces a broad array of high molecular weight proteins, secondary metabolites, and mycotoxins with known toxicological effects. Each of these components varies in concentration, depending on the stage of the A. fumigatus life cycle.

## Reproductive and Developmental Toxicity

Although several studies have evaluated reproductive and developmental toxicity for individual mycotoxins, NTP could not identify any studies following exposure to Aspergillus conidia.

## Carcinogenicity

Although several studies have evaluated the carcinogenicity of individual mycotoxins, NTP could not identify any long-term studies that evaluated carcinogenic potential following exposure to Aspergillus conidia.

## Genetic Toxicity

Little information has been published on the genotoxicity of Aspergillus-related chemicals, and none is available for Aspergillus conidia. Fumagillin, an antibiotic secreted by Aspergillus, has been tested in the form of fumagillin dicyclohexylamine salt for genotoxicity in vitro and in vivo. In vitro tests showed dose-related increases in structural chromosomal aberrations in human peripheral blood lymphocytes treated over a dose range of 0.34–9.20 µg/mL in a 1:1 water-sugar syrup vehicle.^68^ Over this same dose range, these authors also reported significant, dose-related increases in micronucleated cells. The absolute increases in micronucleated cells were small (ranging from 0.62% in the control cultures to 0.89% at the highest concentration tested), however, and unlikely to be of biological significance, in contrast with the significant increases seen in the chromosome aberration assay. The dicyclohexylamine salt may itself possess genotoxic activity, having been reported to induce chromosomal aberrations in vitro,^75^ thus confounding the interpretation of the genotoxicity test data reported for the fumagillin salt. In vivo, increases in micronuclei and chromosomal aberrations, along with cytostatic effects in bone marrow cells, were reported in BALB/c mice following administration of 25, 50, or 75 mg/kg fumagillin dicyclohexylamine salt in a water-sugar syrup once daily for 7 days via gavage.^76^

## Study Rationale

Fungi were nominated to NTP for comprehensive toxicity studies due to continued public health concern about mold exposures in damp indoor environments or following natural disasters. NIOSH, in collaboration with NTP, utilized an AGS (Figure 3) that has enabled the production of a homogenous bioaerosol for delivery of fungal particles to mice housed in a multi-animal exposure chamber. The design and fabrication of the chamber allows inhalation exposures to test articles that simulate natural human exposures. A. fumigatus was selected as the initial test article for this series of inhalation toxicity studies given prevalence of the species in the environment, importance as an opportunistic pathogen, and occupational relevance as a contaminant in the biowaste industry.

Figure 3

Illustration Showing the Acoustical Generator Nose-only Exposure System and Aspergillus fumigatus Particle Characterization

TEM = transmission electron microscope; SEM = scanning electron microscope. (A) HEPA-filtered supply air is directed into the acoustical generator, which vibrates at a designated frequency to form fungal spore aerosols from the fungus-coated rice grains. The fungal aerosol is directed into a nose-only chamber, and then the air is filtered before being sent into the exhaust system. A light-scattering instrument (DataRAM4; ThermoElectron Co., Franklin, MA) attached to the computer estimated the real-time aerosol mass concentration. This value was multiplied by a scale factor to determine the real-time number of spores deposited in the mouse lung based on the previously measured aerosol size distribution and a custom lung-deposition model. The software used that value to alter the amplitude of the speaker signal during exposures to obtain the desired chamber mass concentration. (B) The aerodynamic particle size distribution produced by the acoustical generator as measured with an aerodynamic particle sizer is shown (APS; TSI Inc., Shoreview, MN); 2–5 μm is the aerodynamic diameter of single or double aggregate Aspergillus fumigatus conidia. (C) Field emission SEM image is shown of A. fumigatus fungal conidia deposited on a polycarbonate filter sampled from the animal’s breathing zone in the nose-only chamber.