# Acknowledgments

The findings and the conclusions in this report are those of the authors and do not necessarily represent the official position of the National Institute for Occupational Safety and Health (NIOSH), Centers for Control and Prevention. This study was supported by internal NIOSH funds and in part by an interagency agreement between NIOSH and the National Institute of Environmental Health Sciences (NIEHS) as a collaborative National Toxicology Program research activity (AES 12007-001-00000-NIOSH reference 12-NS12-01).

This work was supported by the Intramural Research Program (ES103316, ES103318, and ES103319) at NIEHS, National Institutes of Health and performed for the National Toxicology Program, Public Health Service, U.S. Department of Health and Human Services under contracts HHSN273201800006C, HHSN273201600020C, HHSN273201600011C, GS00Q14OADU417 (Order No. HHSN273201600015U), HHSN273201500006C, HHSN273201500013C, HHSN273201400015C, HHSN273201300004C, HHSN273201300009C, HHSN316201200054W, N01-ES-55536.