# Appendix E Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TOX-100.

## E.1 Three-month Study – Mice

I01 – Animal Removal Summary

I02 – Animal Removals

I03 – Growth Curve

I03C – Growth Curve

I04 – Mean Body Weight Summary

I04G – Mean Body Weight Gain

I05 – Clinical Observations Summary

PA02 – Neoplastic Lesion Summary with Percent Incidence

PA03 – Non-Neoplastic Lesion Summary with Percent Incidence

PA05 – Incidence Rates of Neoplastic Lesions with Systemic Lesions Abridged

PA06 – Organ Weights Summary

PA10 – Statistical Analysis of Non-Neoplastic Lesions

PA14 – Individual Animal Pathology Data

PA18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grade

PA43 – Hematology Summary

PA46 – Summary of Gross Pathology

## E.2 Individual Animal Data

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Gross Pathology Data

Individual Animal Hematology Data

Individual Animal Histopathology Data

Individual Animal Organ Weight Data

Individual Animal Removal Reasons Data

## E.3 Genetic Toxicology

In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data