# Appendix D National Institute for Occupational Safety and Health Sentinel Animal Program

## D.1 Methods

The sentinel animal program at the National Institute for Occupational Safety and Health monitors for common rodent pathogens in each study room to ensure study mice are healthy and pathogen-free. Pathogens are monitored through the collection of blood and feces from sentinel mice housed in the study rooms.

For this 3-month subchronic inhalation toxicology study, mice weighing more or less than 10% of the mean weight of all male or female study mice were selected for the sentinel group (n = 20; 10/sex). Females were group-housed with five per cage. Male mice were single-housed. For each week the mice were on study, sentinel animals were exposed to dirty bedding from study animals. The 4-week sentinels were evaluated for viral antibodies and Helicobacter 24 hours following the second exposure in the fourth exposure week. The 3-month sentinels were evaluated only at study termination. All sentinels were euthanized at the end of the study and evaluated for abnormalities by gross necropsy.

Whole blood was collected via tail vein bleed for 4-week sentinels or via cardiac puncture postmortem for 3-month sentinels. Three to four drops of whole blood were placed onto an Opti-Spot card (IDEXX Laboratories, Inc., Westbrook, ME) for serology tests. These cards were submitted to IDEXX BioResearch for analysis using the Opti-HM serology profile. The profile included: Mycoplasma pulmonis, ectromelia virus (ECTV), epizootic diarrhea of infant mice virus (EDIM), lymphocytic choriomeningitis virus (LCMV), mouse hepatitis virus (MHV), minute virus of mice (MVM), mouse parvovirus (MPV), mouse norovirus (MNV), pneumonia virus of mice (PVM), reovirus type 3 (REO3), Sendai virus (SV), and Theiler’s murine encephalomyelitis virus (TMEV).

One fecal pellet from each sentinel mouse was collected with sterile forceps, and all pellets for each sample group were placed in a single sterile sample tube for analysis (maximum of 10 pellets/tube). Samples were submitted to IDEXX BioResearch for polymerase chain reaction (PCR) analysis using the Helicobacter profile. The profile included: Helicobacter bili, H. ganmani, H. hepaticus, H. mastomyrinus, H. rodentium, H. typhlonius, and Helicobacter spp.

Table D-1 Methods and Results for Sentinel Animal Testing in Mice

Three-month Study
Collection Time Points | Four-week Males | Four-week Females | Three-month Males | Three-month Females
n | 5 | 5 | 5 | 5
Method/Test
Serology Profile^a^
Ectromelia virus | – | – | – | –
Epizootic diarrhea of infant mice (mouse rotavirus) | – | – | – | –
Lymphocytic choriomeningitis virus | – | – | – | –
Mycoplasma pulmonis | – | – | – | –
Mouse hepatitis virus | – | – | – | –
Mouse norovirus | – | – | – | –
Mouse parvovirus | – | – | – | –
Minute virus of mice | – | – | – | –
Pneumonia virus of mice | – | – | – | –
Reovirus type 3 | – | – | – | –
Theiler’s murine encephalomyelitis virus | – | – | – | –
Sendai virus | – | – | – | –
PCR Evaluation^b^
Helicobacter | – | – | – | –

– = negative; PCR = polymerase chain reaction.

^a^ Serology profiles were conducted on whole blood samples of individual sentinel mice (n = 5/group).

^b^ PCR evaluations of Helicobacter species were conducted on pooled fecal samples for each group.

## D.2 Results

All test results were negative.