# Appendix C Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Mouse Ration

Table C-1 Ingredients of NTP-2000 Mouse Ration^a^

Ingredients | Percentage by Weight
Ground Whole Wheat | 23.00
Ground No. 2 Yellow Corn | 22.44
Wheat Middlings | 15.00
Oat Hulls | 8.50
Alfalfa Meal | 7.50
Solka Floc-40 | 5.50
Soy Protein Concentrate | 4.00
Fish Meal (60%) | 4.00
Soybean Oil | 3.00
Corn Oil | 3.00
Dried Brewer’s Yeast | 1.00
Calcium Carbonate | 0.90
Dicalcium Phosphate | 0.40
Salt | 0.30
DL Methionine | 0.20
Premixes | 1.26

^a^ Ingredient list is based on the formulation listed on the packaging.

Table C-2 Nutrient Composition of NTP-2000 Mouse Ration^a^

Nutrient | Amount
Crude Protein^b^ (% by Weight) | 14.60%
Crude Fat^b^ (% by Weight) | 8.40%
Crude Fiber^b^ (% by Weight) | 9.86%
Ash^b^ (% by Weight) | 5.09%
Amino Acids (% of Total Diet)
Arginine | 0.75%
Lysine | 0.65%
Methionine | 0.44%
Cystine | 0.21%
Tryptophan | 0.17%
Histidine | 0.32%
Leucine | 1.04%
Isoleucine | 0.58%
Phenylalanine | 0.59%
Tyrosine | 0.45%
Threonine | 0.52%
Valine | 0.66%
Minerals
Calcium | 0.99%
Phosphorus | 0.56%
Potassium | 0.69%
Sodium | 0.19%
Magnesium | 0.22%
Iron | 132.00 ppm
Zinc | 47.00 ppm
Manganese | 44.00 ppm
Copper | 10.00 ppm
Cobalt | 0.12 ppm
Iodine | 0.33 ppm
Vitamins
Vitamin A | 9.70 IU/g
Vitamin D_3_ | 1.00 IU/g
α-Tocopherol | 145.00 IU/g
Thiamine | 9.30 ppm
Riboflavin | 5.70 ppm
Niacin | 54.90 ppm
Pantothenic Acid | 19.00 ppm
Choline | 2,326.00 ppm
Pyrodoxine | 11.00 ppm
Folic Acid | 1.80 ppm
Biotin | 0.32 ppm
Vitamin B_12_ | 53.50 Mcg/kg
Vitamin K | 1.60 ppm

^a^ Nutrient content is based on the formulation listed on the packaging unless otherwise noted.

^b^ Nutrient content for protein, fat, fiber, and ash were calculated from the analysis of lot number 07-01-114 used in the study.

Table C-3 Contaminant Levels in NTP-2000 Mouse Ration^a^

Contaminant | Amount
Contaminants
Aflatoxins
B1 | <0.500 ppb
B2 | <0.500 ppb
G1 | <0.500 ppb
G2 | <0.500 ppb
Arsenic | 0.211 ppm
BHA | <1.0 ppm
BHT | <1.0 ppm
Cadmium | 0.054 ppm
Daidzein | <10.0 ppm
Daidzin | <10.0 ppm
Genistein | <10.0 ppm
Genistin | 10.7 ppm
Glycitein | <10.0 ppm
Glycitin | 11.0 ppm
Lead | 0.158 ppm
Mercury | <0.01 ppm
Nitrate Anion | 73.4 ppm
Nitrite Anion | <0.5 ppm
N-nitrosodibutylamine | <1.0 ppb
N-nitrosodiethylamine | <1.0 ppb
N-nitrosodimethylamine | 2.2 ppb
N-nitrosomorpholine | <1.0 ppb
N-nitrosopiperidine | <1.0 ppb
N-nitrosopyrrolidine | 6.9 ppb
Selenium | 0.196 ppm
Aerobic Plate Count | <10 CFU/g
Coliform | <3 MPN/g
Escherichia coli | <3 MPN/g
Salmonella | Negative
Pesticides
α-BHC | <0.0125 ppm
β-BHC | <0.0125 ppm
γ-BHC | <0.0125 ppm
δ-BHC | <0.0125 ppm
Acephate | <0.0400 ppm
Aldrin | <0.0125 ppm
Arochlor 1254 | <0.2000 ppm
Azinphos-methyl | <0.0400 ppm
Captafol | <0.0315 ppm
Captan | <0.0500 ppm
Chlorfenvinphos | <0.0400 ppm
Chlorothalonil | <0.0125 ppm
Cis-permethrin | <0.0375 ppm
Coumaphos | <0.0500 ppm
Cypermethrin | <0.0940 ppm
DCNA | <0.0185 ppm
DCPA | <0.0185 ppm
Demeton-S | <0.0250 ppm
Diazinon | <0.0200 ppm
Dichlofenthion | <0.0300 ppm
Dicofol | <0.0315 ppm
Dieldrin | <0.0125 ppm
Dimethoate | <0.0200 ppm
Disulfoton | <0.0250 ppm
Endosulfan I | <0.0125 ppm
Endosulfan II | <0.0185 ppm
Endosulfan Sulfate | <0.0185 ppm
Endrin | <0.0185 ppm
EPN | <0.0400 ppm
Et-chlorpyrifos | <0.0250 ppm
Ethion | <0.0200 ppm
Et-parathion | <0.0200 ppm
Fenitrothion | <0.0250 ppm
Folpet | <0.0315 ppm
Fonofos | <0.0250 ppm
HCB | <0.0065 ppm
Heptachlor | <0.0125 ppm
Heptachlor Epoxide | <0.0125 ppm
Malathion | 0.5850 ppm
Me-chlorpyrifos | 0.2640 ppm
Me-parathion | <0.0200 ppm
Me-pirimiphos | <0.0250 ppm
Methamidophos | <0.0150 ppm
Methidathion | <0.0300 ppm
Methoxychlor | <0.0315 ppm
Mevinphos | <0.0250 ppm
Mirex | <0.0125 ppm
Omethoate | <0.0350 ppm
Oxadiazon | <0.0375 ppm
p,p’-DDD | <0.0185 ppm
p,p’-DDE | <0.0125 ppm
p,p’-DDT | <0.0200 ppm
PCNB | <0.0100 ppm
Phosalone | <0.0400 ppm
Phosmet | <0.0350 ppm
Propetamphos | <0.0300 ppm
Propyzamide | <0.0250 ppm
Prothiophos | <0.0300 ppm
Ronnel | <0.0200 ppm
Tech Chlordane | <0.0500 ppm
Tecnazene | <0.0125 ppm
Telodrin | <0.0200 ppm
Tetradifon | <0.0185 ppm
Thimet | <0.0200 ppm
Toxaphene | <0.1000 ppm
Trans-permethrin | <0.0250 ppm
Trithion | <0.0300 ppm
Vapona | <0.0150 ppm
Vinclozolin | <0.0250 ppm

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DCNA = 2,6-dichloro-4-nitroaniline; DCPA = dimethyl tetrachloroterephthalate; EPN = ethyl p-nitrophenyl thionobenzenephosphate; HCB = hexachlorobenzene; DDD = dichlorodiphenyldichloroethane; DDE = dichlorodiphenyldichloroethylene; DDT = dichlorodiphenyltrichloroethane; PCNB = pentachloronitrobenzene.

^a^ NTP-2000 Rodent Diet, Wafer lot number 07-01-114 was irradiated.