# Appendix B Genetic Toxicology

## B.1 Micronucleus Assay

### B.1.1 Peripheral Blood Micronucleus Test Protocol

Peripheral blood samples were analyzed by Integrated Laboratory Systems, LLC (ILS; Research Triangle Park, NC) for determination of erythrocyte micronucleus frequencies. Briefly, EDTA-stabilized peripheral blood samples were shipped on ice packs immediately following terminal necropsy from the National Institute for Occupational Safety and Health to ILS. Before ILS received the samples, microcentrifuge tubes containing anticoagulant (heparin) were prepared and stored at 4°C, and 15 mL conical tubes containing fixative (methanol) were prepared and stored at −80°C ± 5°C.

Upon arrival, blood samples were fixed in ultracold methanol using a MicroFlowPLUS Kit (Litron Laboratories, Rochester, NY) according to the manufacturer’s instructions. Fixed samples were stored in a −80°C freezer until analysis. Thawed blood samples were analyzed for frequency of micronucleated immature erythrocytes (polychromatic erythrocytes or PCEs, reticulocytes) and mature erythrocytes (normochromatic erythrocytes or NCEs) using a flow cytometer^121^; both the mature and immature erythrocyte populations were analyzed separately by employing special cell surface markers to differentiate the two cell types. In mice, both the mature and immature erythrocyte populations can be evaluated for micronucleus frequency because the mouse spleen does not sequester and eliminate damaged erythrocytes. Damaged erythrocytes achieve steady state in the peripheral blood of mice following 4 weeks of continuous exposure. Approximately 20,000 immature erythroytes and 1 × 10^6^ mature erythrocytes were analyzed per animal for frequency of micronucleated cells, and the percentage of immature erythrocytes (% PCE) was calculated as a measure of bone marrow toxicity resulting from test article exposure.

For most NTP studies, the statistical methods for micronucleus assays employ a trend test and a Levene’s test for equal variances to determine which type of pairwise test (Williams or Dunn) is more appropriate. Due to the design of this study (with one exposed group and two control groups), no trend test is needed, and the use of the Williams test would be inappropriate due to its step-down nature. Therefore, the Dunn test was used for the three-way pairwise comparison of the treatment and exposure groups. The Dunn test has a built-in correction for multiple comparisons so that the overall false positive rate of the experiment can be maintained. Pairwise comparisons with the control groups are considered statistically significant at p ≤ 0.025.

Historical control data are used to evaluate the biological significance of any observed response. Both statistical significance and biological significance are considered when arriving at a call. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, the reproducibility of any effects observed (in acute studies), and the magnitudes of those effects.

### B.1.2 Results

No increases in the frequencies of micronucleated polychromatic and normochromatic erythrocytes were observed in the peripheral blood of male or female B6C3F1/N mice exposed to either viable A. fumigatus or the heat-inactivated particle control spores compared to the air control mice (Table B-1). In addition, no significant alteration in the % PCE was observed in these mice, suggesting no effects on hematopoiesis. These negative results in the micronucleus test indicate an absence of exposure-induced chromosomal damage in progenitor erythrocytes in the bone marrow of mice, along with an absence of generalized bone marrow toxicity.

Table B-1 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice in the Three-month Inhalation Study of Aspergillus fumigatus Spores^a^

| Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Air Control | 2.699 ± 0.219 | – | 1.463 ± 0.052 | – | 1.550 ± 0.063 | –
Heat-inactivated Particle Control | 2.390 ± 0.080 | 0.283 | 1.395 ± 0.028 | 0.483 | 1.623 ± 0.057 | 0.433
Viable A. fumigatus^d^ | 2.550 ± 0.154 | 0.818/0.716 | 1.379 ± 0.025 | 0.269/1.000 | 1.587 ± 0.049 | 0.594/1.000
Female
Air Control | 1.730 ± 0.080 | – | 0.931 ± 0.014 | – | 1.614 ± 0.100 | –
Heat-inactivated Particle Control | 1.960 ± 0.206 | 0.323 | 0.959 ± 0.032 | 1.000 | 1.883 ± 0.273 | 0.135
Viable A. fumigatus | 1.684 ± 0.108 | 1.000/0.343 | 0.903 ± 0.021 | 0.387/0.344 | 1.864 ± 0.122 | 0.206/1.000

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data are presented as mean ± standard error.

^c^ P values for all endpoints were calculated using the two-sided Dunn’s test, comparing all three groups simultaneously. For the PCEs (%) endpoints, the log-transformed PCE/NCE ratios were used.

^d^ P values for the viable A. fumigatus groups are presented as: p value (viable A. fumigatus compared to air control)/p value (viable A. fumigatus compared to heat-inactivated particle control).