# Appendix A Culture, Characterization, and Delivery of Aspergillus fumigatus

## A.1 Reconstitution, Culture, and Glycerol Stock Preparation of Aspergillus fumigatus

The Aspergillus fumigatus strain (NIH Strain B-5233) used in this study was acquired from the American Type Culture Collection (ATCC^®^ 13073™, lot 59030808, Manassas, VA) and stored at −80°C. The freeze-dried stock was reconstituted in 50 mL of sterile water according to the ATCC instructions. Once rehydrated, malt extract agar (MEA) culture plates were inoculated with 100 µL of the rehydrated fungus. MEA culture plates were incubated at 25°C for 10–14 days for optimal spore growth. A. fumigatus spores were harvested by liberating the spores in 2 mL of sterile water using an inoculating loop. The spore suspension was mixed with an equal volume of autoclaved 50% glycerol, and 0.5 mL aliquots of the suspension were prepared in cryogenic storage vials. Glycerol stock preparations were stored at −80°C.

## A.2 Preparation of the Test Article

Aliquoted frozen glycerol spore suspension was thawed, and 100 µL was used to inoculate two MEA culture plates. Plates were incubated at 25°C for 7–10 days. A. fumigatus spores were harvested from each plate by liberating the spores in 2 mL of sterile water using an inoculating loop. The concentration of spores in the spore suspension was determined by diluting the suspension 1:100 and manually counting the spores using a hemocytometer. The spore suspension was diluted to 2.5 × 10^6^ spores/mL using sterile water. Sterile petri dishes containing 10 g of autoclaved brown rice (15/week) were inoculated with 3 mL of the 2.5 × 10^6^ spore/mL suspension. The petri dishes were wrapped in parafilm and incubated at 25°C for 10–14 days. The plates were shaken vigorously 1–2 times each day of culture until the rice grains were coated in fungi to prevent aggregation of the rice grains. Prior to aerosolization, viable cultures were placed in a desiccator for 3–4 days.

## A.3 Heat Treatment of Aspergillus fumigatus Cultures for Creation of Nonviable Particle Control

After 10–14 days of culture, fungi-coated rice from two culture dishes were combined and then equally distributed to one sterile petri dish (viable A. fumigatus) and one sterile quartz plate (heat-inactivated particle control). This procedure was repeated for eight more plates for a total of four viable A. fumigatus and four heat-inactivated particle control plates. The quartz plates were autoclaved for 15 minutes at 121°C and allowed to cool. The fungi-coated rice grains were transferred from the quartz plates back to sterile petri dishes.

## A.4 Determination of the Reduction in Aspergillus fumigatus Spore Viability in the Heat-inactivated Particle Control

Spores were harvested from heat-inactivated particle control cultures and viable A. fumigatus spore cultures in sterile phosphate buffered saline (PBS), pH 7.4. Spore suspensions were further diluted and plated on MEA culture plates to allow for counting of individual fungal colonies. For heat-inactivated particle control cultures, 1:1,000, 1:10,000, and 1:50,000 dilutions were used. For viable A. fumigatus cultures, 1:100,000, 1:500,000, and 1:1,000,000 dilutions were used. After 48–96 hours of growth at 25°C, fungal colony-forming units (CFU) were counted. Those plates with 30–300 CFU were used to determine the number of viable A. fumigatus spores/mL PBS in the original stock solutions. These concentrations were used to determine the reduction in spore viability in the heat-inactivated particle control compared with the viable A. fumigatus. Reduction >98% was categorized as “nonviable.”

## A.5 Assessment of Fungal Contaminants in the Exposure Articles

Genomic DNA was extracted from the heat-inactivated particle control and viable A. fumigatus cultures each week for analysis of fungal contaminants. Spores were harvested in sterile, distilled, deionized water. Spores from 200 µL of the suspension were pelleted by centrifugation. Spores were then suspended in Roche Tissue Lysis buffer and transferred to tubes containing 0.3 µm glass beads. The tubes were processed in a bead mill homogenizer. The suspensions were centrifuged twice, and supernatants were transferred to new tubes in which 5 µL of CelLytic B Cell Lysis Reagent (Sigma Aldrich, St. Louis, MO) was added; tubes were incubated at 37°C for 30 minutes. Next, 40 µL proteinase K solution was added, and tubes were incubated at 70°C for 10 minutes. After the addition of 100 µL of isopropanol, extracted DNA was washed and eluted using the Roche High Pure PCR Template Preparation Kit (Roche, Indianapolis, IN). Internal transcribed spacer (ITS) regions of fungal ribosomal RNA were amplified using the Fun18Sf/ITS4R primer pair. Amplified DNA was purified, cloned into a pDRIVE vector, and transformed into chemically competent Escherichia coli. E. coli clones positive for the ITS amplicon insert were used to inoculate 96-well plates for generation of glycerol stocks. The glycerol stocks were sequenced with the T7 and SP6 primers using Sanger sequencing. Sequences were trimmed and assembled and then clustered into operational taxonomic units (OTUs)—groups of sequences with 97% or greater similarity. Representative sequences from each OTU were searched against the National Center for Biotechnology Information database. Sequences were then identified on the basis of identity with sequences banked in that database. Any sequence identified as a fungal species other than A. fumigatus or Aspergillus spp. were considered contaminants. The number of sequences analyzed depended on the number of viable spores in the sample. Very little DNA was obtained from heat-inactivated particle control samples due to the heat treatment. In Table A-1, the number of contaminant fungal sequences is shown relative to the number of sequences analyzed in the sample.

## A.6 Aerosolization of the Exposure Articles Using the Acoustical Generator System

Prior to aerosolization of the exposure articles, the viable A. fumigatus and heat-inactivated particle control cultures were placed in a desiccator for 3–4 days to remove excess moisture and allow for optimal aerosolization. Fungal-laden rice was placed on a rubber membrane housed on top of a speaker within the acoustical generator system (AGS). The AGS consisted of a modified Pitt-3 generator^77^ linked to a multi-animal nose-only exposure chamber with a vertical cylindrical tower of 24 ports that held animal pods radially projecting outward (Figure 3A). There were four levels of ports: ports 1–6 at the highest elevation, ports 7–12 at the next level, ports 13–18 at the next, and ports 19–24 at the lowest level. For this study, two AGS systems were used, one for the viable A. fumigatus exposures and one for the heat-inactivated particle control exposures. Air control mice were placed in an identical exposure chamber that was not attached to the AGS and received only HEPA-filtered air. Twenty animal pods were attached to each exposure chamber, 10 for male mice and 10 for female mice. Animals were randomly placed in the pods for each exposure to minimize the effects of potential small variations in spore concentrations at each port. The additional ports were used to (1) measure the mass concentration with a light-scattering device (DataRAM 4, ThermoElectron Co., Franklin, MA), (2) acquire gravimetric measurements used to adjust the calibration of the DataRAM, (3) determine particle size using an aerodynamic particle sizer (APS; TSI Inc., Shoreview, MN), and (4) collect samples on filters for field emission electron microscopy analysis (FESEM; Hitachi S-4800, Tokyo, Japan).

The fungus-laden rice was allowed to settle within the AGS prior to the start of exposures. Acoustical energy aerosolized fungal spores, which were then delivered into the exposure chamber at a flow rate of 6 liters per minute. Mass concentration was monitored in real time using the DataRAM software. That software shut down the AGS once the mice had been exposed to an estimated pulmonary deposition of 1 × 10^5^ spores, equating to approximately 10 mg/m^3^ fungal spores inhaled over 1 hour. Pulmonary deposition was calculated using a mouse lung-deposition model adapted from Raabe et al.^82^ The mice remained in the pods for a full 60 minutes and received HEPA-filtered air if the desired lung deposition was reached before the 60-minute exposure interval. Table A-2 and Table A-3 describe the measured concentrations of each exposure. Aerodynamic particle size data are shown in Table A-4, and Figure A-1 demonstrates spores within the respirable range of 2 to 3 µm. FESEM analysis showed that the aerosol primarily consisted of single spores or doublets (Figure A-2).

Table A-1 Weekly Evaluation of Aspergillus fumigatus Heat-inactivated Particle Controls and Viable A. fumigatus

| Heat-inactivated Particle Control | Viable A. fumigatus
Viability
Viable Spore Concentration^a^ | 1.18 × 10^4^ spores/mL (± 2.12 × 10^4^) | 1.49 × 10^7^ spores/mL (± 1.07 × 10^7^)
Reduction in Viability | 99.87% (± 0.33%) | –
Contamination^b^
Week 1 | 1/22 | 0/48
Week 2 | 0/24 | 0/48
Week 3 | 4/11 | 0/72
Week 4 | 0/11 | 0/70
Week 5 | 0/12 | 0/70
Week 6 | 2/12 | 0/71
Week 7 | 0/6 | 0/69
Week 8 | 4/6 | 0/70
Week 9 | 0/10 | 0/71
Week 10 | 0/7 | 0/72
Week 11 | 0/12 | 0/70
Week 12 | 0/12 | 0/71
Week 13 | 0/12 | 0/72

^a^ Spores were harvested from nonviable and viable cultures in phosphate buffered saline (PBS). These suspensions were plated at various dilutions. Colony-forming units were then counted to determine the spores per mL of PBS in each of the original, undiluted suspensions. Data presented as mean ± standard deviation.

^b^ Although no fungal contamination was visible within the cultures, DNA derived from other fungal species was detected in the heat-inactivated particle control but not in the viable Aspergillus fumigatus cultures on weeks 1, 3, 6, and 8. Sequence analysis revealed these species to include Leptosphaerulina chartarum, Davidiella spp., Sordariomycetes spp., Piptoporus beultinus, and Alternaria alternata.

Table A-2 Weekly Viable Aspergillus fumigatus Exposure Concentrations

Exposure Day | Chamber Concentration (DataRAM [mg/m^3^]) | Chamber Concentration (Filter [mg/m^3^]) | Filter Weight (mg) | Number of Spores Deposited in Lung
1 | 9.89 | 6.99 | 0.4335 | 1.004 × 10^5^
3 | 9.93 | 10.33 | 0.6405 | 1.006 × 10^5^
8 | 10.24 | 9.84 | 0.5906 | 1.005 × 10^5^
10 | 9.38 | 8.73 | 0.5778 | 1.006 × 10^5^
15 | 10.26 | 10.28 | 0.6169 | 1.006 × 10^5^
17 | 9.30 | 9.21 | 0.6092 | 1.005 × 10^5^
22 | 10.27 | 5.94 | 0.3562 | 1.005 × 10^5^
24 | 9.93 | 8.84 | 0.5482 | 1.005 × 10^5^
30 | 9.61 | 9.43 | 0.6041 | 1.005 × 10^5^
32 | 10.19 | 10.02 | 0.6014 | 1.005 × 10^5^
36 | 10.11 | 9.91 | 0.5943 | 1.006 × 10^5^
38 | 9.01 | 8.76 | 0.5983 | 1.006 × 10^5^
43 | 9.57 | 9.57 | 0.5700 | 1.005 × 10^5^
45 | 10.25 | 7.89 | 0.4733 | 1.005 × 10^5^
50 | 10.24 | 9.23 | 0.5538 | 1.004 × 10^5^
52 | 9.03 | 9.72 | 0.6640 | 1.006 × 10^5^
57 | 10.22 | 9.24 | 0.5543 | 1.004 × 10^5^
59 | 9.90 | 11.45 | 0.7100 | 1.004 × 10^5^
64 | 9.66 | 10.49 | 0.6722 | 1.004 × 10^5^
66 | 9.36 | 10.08 | 0.6669 | 1.006 × 10^5^
71 | 8.69 | 7.95 | 0.5599 | 1.004 × 10^5^
73 | 10.26 | 13.07 | 0.7843 | 1.004 × 10^5^
78 | 10.29 | 10.40 | 0.6237 | 1.007 × 10^5^
80 | 9.29 | 8.83 | 0.5843 | 1.005 × 10^5^
84 | 9.92 | 8.24 | 0.5109 | 1.004 × 10^5^
86 | 10.30 | 9.62 | 0.5770 | 1.005 × 10^5^
Mean^a^ | 9.81 ± 0.48 | 9.39 ± 1.39 | 0.588 ± 0.085 | 1.005 × 10^5^ ± 87.09

^a^ Data are presented as mean ± standard deviation of the measurements over the course of the study.

Table A-3 Weekly Aspergillus fumigatus Heat-inactivated Particle Control Exposure Concentrations

Exposure Day | Chamber Concentration (DataRAM [mg/m^3^]) | Chamber Concentration (Filter [mg/m^3^]) | Filter Weight (mg) | Number of Spores Deposited in Lung
1 | 10.26 | 8.79 | 0.5275 | 1.004 × 10^5^
3 | 10.24 | 8.44 | 0.5062 | 1.009 × 10^5^
8 | 10.30 | 9.81 | 0.5887 | 1.008 × 10^5^
10 | 10.24 | 9.50 | 0.5699 | 1.002 × 10^5^
15 | 9.69 | 8.85 | 0.5668 | 1.008 × 10^5^
17 | 8.76 | 9.20 | 0.6480 | 1.002 × 10^5^
22 | 5.62 | 4.86 | 0.2918 | 5.985 × 10^4^
24 | 10.00 | 6.45 | 0.3998 | 1.007 × 10^5^
30 | 10.31 | 12.80 | 0.7682 | 1.009 × 10^5^
32 | 9.94 | 10.72 | 0.6648 | 1.011 × 10^5^
36 | 10.39 | 12.88 | 0.7727 | 1.016 × 10^5^
38 | 10.07 | 12.37 | 0.7673 | 1.014 × 10^5^
43 | 9.78 | 10.31 | 0.6600 | 1.016 × 10^5^
45 | 10.03 | 9.83 | 0.6099 | 1.018 × 10^5^
50 | 10.35 | 9.75 | 0.5849 | 1.019 × 10^5^
52 | 9.42 | 8.79 | 0.5820 | 1.017 × 10^5^
57 | 10.28 | 10.75 | 0.6449 | 1.007 × 10^5^
59 | 10.31 | 8.20 | 0.4917 | 1.009 × 10^5^
64 | 10.45 | 10.95 | 0.6572 | 1.024 × 10^5^
66 | 10.40 | 11.20 | 0.6719 | 1.018 × 10^5^
71 | 9.38 | 8.02 | 0.5305 | 1.012 × 10^5^
73 | 10.39 | 8.55 | 0.5812 | 1.019 × 10^5^
78 | 10.42 | 13.80 | 0.8281 | 1.020 × 10^5^
80 | 10.48 | 16.24 | 0.9741 | 1.025 × 10^5^
84 | 10.49 | 15.71 | 0.9424 | 1.027 × 10^5^
86 | 10.45 | 14.34 | 0.8604 | 1.022 × 10^5^
Mean^a^ | 9.94 ± 0.97 | 10.43 ± 2.69 | 0.642 ± 0.156 | 9.978 × 10^5^ ± 8,173.36

^a^ Data are presented as mean ± standard deviation of the measurements over the course of the study.

Table A-4 Aerodynamic Particle Size Statistics for Aerosolized Aspergillus fumigatus Spores from Aerodynamic Particle Sizer Measurements^a^

| Number (Particle Size) | Surface (Particle Size) | Mass (Particle Size)
Viable A. fumigatus
Median (µm) | 2.25 | 2.32 | 2.35
Mean (µm) | 2.26 | 2.37 | 2.43
Geometric Mean (µm) | 2.23 | 2.34 | 2.40
Mode (µm) | 2.29 | 2.29 | 2.29
Geometric Standard Deviation | 1.19 | 1.16 | 1.17
Heat-inactivated Particle Control
Median (µm) | 2.31 | 2.38 | 2.44
Mean (µm) | 2.36 | 2.52 | 2.75
Geometric Mean (µm) | 2.34 | 2.46 | 2.60
Mode (µm) | 2.29 | 2.29 | 2.29
Geometric Standard Deviation | 1.15 | 1.21 | 1.33

^a^ The columns represent the three different methods of producing size distribution curves (as seen in Figure A-1). The aerodynamic particle sizer totals the particles in each particle size by number, by the surface area of the particles in each size bin, and by the mass of the particles in each size bin.

Figure A-1

Aerodynamic Particle Size Measurements Following Aerosolization of Aspergillus fumigatus Spores

The images depict the size distrution of particles measured with the aerodynamic particle sizer following aerosolization of (A) viable A. fumigatus spores and (B) the heat-inactivated particle control (nonviable A. fumigatus spores).

Figure A-2

Electron Microscropy Images of Aspergillus fumigatus Spores Aerosolized Using the Acoustical Generation System

Field emission electron microscopy images of spores collected on filters following acoutstical generation system aersolization of (A) viable A. fumigatus spores and (B) the heat-inactivated particle control (nonviable A. fumigatus spores). Spores in both exposure groups were aerosolized as single spores and doublets.