# Abstract

α-Pinene is a naturally occurring monoterpene produced by some plants (e.g., pine trees, cannabis, rosemary) and is used as a flavor and fragrance ingredient in addition to being the main constituent in turpentine. Exposure concentrations of α-pinene can reach 27 ppm (α-pinene) or 99 ppm (total terpenes, primarily α-pinene and Δ^3^-carene) in certain occupational settings, such as softwood lumber processing. Data are insufficient on the long-term effects associated with exposure to α-pinene or turpentine, and occupational exposures are likely to be chronic. Therefore, National Toxicology Program (NTP) carcinogenicity studies were conducted in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and B6C3F1/N mice to characterize hazard following chronic exposure to α-pinene. An inhalation route of exposure was selected to mimic the primary route of human exposure in occupational settings.

Based on findings in the urinary bladder, kidney, and male reproductive system in previous 3-month α-pinene inhalation studies in Fischer 344 (F344/N) rats and B6C3F1/N mice,^2^ 3-month evaluations were added for male Sprague Dawley rats, B6C3F1/N mice, and CD-1 mice to compare the responses in target tissues across species and strains and to evaluate reproductive function.

Early mortalities in the chronic study, attributed to mammary masses or nodules, prompted the addition of a follow-up 3-month investigative study in male and female Sprague Dawley rats to evaluate early biomarkers of carcinogenicity in mammary gland and collect definitive internal concentration data for α-pinene and α-pinene oxide in blood and mammary gland using headspace gas chromatography-mass spectrometry (HS-GC-MS) detection for α-pinene and GC-MS for α-pinene oxide. Mammary gland was collected for future analysis, and vaginal cytology and sperm parameters were also evaluated.

## Three-month Study in Rats

Male Sprague Dawley rats (n = 25/exposure group) were exposed to 0, 100, 200, or 400 ppm α-pinene via whole-body inhalation (6 hours plus the theoretical value for the time to achieve 90% of the target concentration after the beginning of vapor generation [T_90_] per day for 5 days per week) for 3 months for the reproductive assessment (see below) and analysis of limited tissues (kidney, urinary bladder). No exposure-related histopathological changes were noted in the kidney or urinary bladder of male rats in the 3-month study.

## Two-year Study in Rats

Male and female Sprague Dawley rats (n = 50/sex/exposure group) were exposed to 0, 50, 100, or 200 ppm α-pinene via whole-body inhalation (6 hours plus T_90_ per day for 5 days per week) for 2 years to investigate chronic toxicity and carcinogenicity. Survival of male rats in all exposed groups was comparable to that of control rats, whereas survival of exposed female rats was significantly decreased compared to control rats. Although there were significant decreases (≤10%) in body weights in male and female rats in the 100 and 200 ppm groups at different time points throughout the study, they were inconsistent throughout the study period and did not indicate overt toxicity. There were no clinical observations associated with α-pinene exposure in male rats, but female rats displayed an exposure-related higher incidence of vaginal discharge in all exposed groups.

In female rats, the incidences of mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined) were significantly increased in the 100 and 200 ppm groups. The incidences of adenocarcinoma; squamous cell carcinoma; squamous cell papilloma, squamous cell carcinoma, or adenoma or adenocarcinoma (combined); and stromal polyps in the uterus were significantly increased in the 200 ppm group. There were significant increases in the incidences of nonneoplastic lesions in the uterus, including atypical hyperplasia and stromal endometrium hyperplasia. Exposure-related significant increases in the incidences of hypercellularity in the bone marrow and increased extramedullary hematopoiesis in the spleen were also observed in female rats.

In male rats, there was a positive trend, and the incidence of papilloma in the urinary bladder was higher in the 200 ppm group relative to the control group. Increased incidences of nonneoplastic lesions in male rats included hypospermia in the epididymis, degeneration and degeneration or atrophy (combined) in the germinal epithelium of the testis, focal hyperplasia in the adrenal gland medulla, and bile duct hyperplasia in the liver.

α-Pinene and α-pinene oxide were present in blood and mammary gland.

## Three-month Studies in Mice

Male CD-1 mice (n = 25/exposure group) and B6C3F1/N mice (n = 10/exposure group) were exposed to 0, 100, 200, or 400 ppm α-pinene via whole-body inhalation (6 hours plus T_90_ per day for 5 days per week) for 3 months for the reproductive assessment (see below) and analysis of the urinary bladder. Male B6C3F1/N mice displayed exposure-related urinary bladder nonneoplastic lesions, but there were no findings in CD-1 mice.

## Two-year Study in Mice

Male and female B6C3F1/N mice (n = 50/sex/exposure group) were exposed to 0, 100, 200, or 400 ppm α-pinene via whole-body inhalation (6 hours plus T_90_ per day for 5 days per week) for 2 years to investigate chronic toxicity and carcinogenicity. α-Pinene exposure did not significantly affect survival of male or female mice. Male B6C3F1/N mice in the 400 ppm group had significantly decreased body weights beginning on approximately study day 80 and persisting until study termination, with a decrease of 16% compared to the control group on study day 703. Female B6C3F1/N mice did not display consistently different weights from control animals. Clinical observations were sporadic and not attributed to α-pinene exposure in male or female mice.

Male and female B6C3F1/N mice exhibited similar patterns of carcinogenicity in the Harderian gland, liver, and lung following exposure to α-pinene. The incidences of Harderian gland adenoma, adenocarcinoma, and adenoma or adenocarcinoma (combined) exhibited positive trends and were significantly increased in the 400, 400, and ≥200 ppm groups, respectively, in male mice, whereas the incidences of Harderian gland adenoma and adenoma or adenocarcinoma (combined) exhibited positive trends and were significantly increased at concentrations ≥200 ppm in female mice. In male and female mice, the incidences of hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined) exhibited positive trends and were significantly increased at concentrations of ≥200, 400, and ≥100 ppm α-pinene, respectively, in male mice, and ≥100, 400, and ≥100 ppm, respectively, in female mice. These neoplastic lesions in the liver were accompanied by an exposure-related significant increase in multinucleated hepatocyte, basophilic focus, and necrosis in male mice. There were positive trends in the incidences of alveolar/bronchiolar adenoma and adenoma or carcinoma (combined) in the lungs of male and female mice and alveolar/bronchiolar carcinoma in female mice. The incidences of alveolar/bronchiolar adenoma and adenoma or carcinoma (combined) were significantly increased at concentrations of 400 and ≥200 ppm α-pinene, respectively, in male mice, and the incidences of alveolar/bronchiolar adenoma, carcinoma, and adenoma or carcinoma (combined) were significantly increased at concentrations of ≥100, ≥200, and ≥100 ppm, respectively, in female mice. Significant increases in the incidence of alveolar/bronchiolar epithelium hyperplasia were observed in all exposed groups in both male and female mice.

In female mice, there were significant increases in the incidences of mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined) in the 400 ppm group. The incidences of granulosa cell tumor, benign or malignant (combined) and tubulostromal adenoma in the ovary in the 400 ppm group were also significantly increased. An increased incidence in tubulostromal hyperplasia accompanied the neoplastic lesions in the ovary.

There was a positive trend and a higher incidence of urinary bladder papilloma in the 400 ppm group of male mice. Significant increases in the incidences of urinary bladder nonneoplastic lesions were observed, including urothelium hyperplasia in both male and female mice and lymphocytic cellular infiltration and suppurative inflammation in male mice. In male mice, there was a positive trend and higher incidence of forestomach papilloma in the 200 and 400 ppm groups. This finding was not noted in females, although there was a positive trend and higher incidence of squamous cell carcinoma and a significant increase in the incidence of hyperplasia of the forestomach epithelium in the 400 ppm group.

There were significantly increased incidences of degeneration and degeneration or atrophy (combined) in the germinal epithelium of the testis and exfoliated germ cells in the duct of the epididymis in the 400 ppm group.

α-Pinene and α-pinene oxide were present in blood and mammary gland.

## Reproductive Performance in Rats and Mice

As described above, male Sprague Dawley rats (n = 25/exposure group), CD-1 mice (n = 25/exposure group), and B6C3F1/N mice (n = 10/exposure group) were exposed to 0, 100, 200, or 400 ppm α-pinene via whole-body inhalation (6 hours plus T_90_ per day for 5 days per week) for 3 months. Following exposure, male rats and CD-1 mice were mated with naïve females to evaluate reproductive performance. Epididymis and testis were weighed and evaluated histopathologically in all animals. Although collected, sperm parameters could not be evaluated because of artifacts (e.g., clumping of cells, too many sperm in sample).

Species differences in male reproductive tissue responses were noted with exposure-related effects observed in male rats and B6C3F1/N mice but not CD-1 mice. In male rats, absolute epididymis and testis weights were significantly decreased and nonneoplastic lesions in the testis were observed. While B6C3F1/N mice displayed significantly decreased absolute testis weights, no accompanying exposure-related histopathological lesions were found.

No exposure-related effects were seen in the number of females that were paired, mated, or became pregnant in rats or CD-1 mice. A negative trend was observed in the number of implantations per female in rats.

## Three-month Investigative Study in Rats

Male and female Sprague Dawley rats (n = 10/sex/exposure group) were exposed to 0, 50, 100, or 200 ppm α-pinene via whole-body inhalation (6 hours plus T_90_ per day for 5 days per week) for 3 months to measure internal concentrations of α-pinene and α-pinene oxide and to collect tissue for development and analysis of early biomarkers of mammary gland carcinogenesis. In addition, select male reproductive tissues were weighed and examined histopathologically and vaginal cytology and sperm parameters were evaluated.

Blood α-pinene concentration increased with the exposure concentration in both male and female rats. Blood α-pinene oxide concentration was generally higher than the α-pinene concentration but did not increase with exposure concentration in male or female rats. In general, female rats had higher concentrations of α-pinene and α-pinene oxide than male rats. Mammary gland α-pinene and α-pinene oxide concentrations were much higher than those observed in blood.

There was a marginal but significant decrease in proestrus cycle length in the 100 and 200 ppm groups compared to the control group.

## Conclusions

Under the conditions of these 2-year inhalation studies, there was some evidence of carcinogenic activity of α-pinene in male Hsd:Sprague Dawley^®^ SD^®^ rats based on the higher incidence of urinary bladder papilloma. There was clear evidence of carcinogenic activity of α-pinene in female Hsd:Sprague Dawley^®^ SD^®^ rats based on the increased incidences of mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined). Increased incidences of stromal polyp; adenocarcinoma; squamous cell carcinoma; and squamous cell papilloma, squamous cell carcinoma, adenoma, or adenocarcinoma (combined) in the uterus were also considered to be related to exposure.

There was clear evidence of carcinogenic activity of α-pinene in male B6C3F1/N mice based on the increased incidences of Harderian gland adenoma, adenocarcinoma, and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); and alveolar/bronchiolar adenoma and adenoma or carcinoma (combined). Higher incidences of urinary bladder papilloma and forestomach papilloma were also considered to be related to exposure. There was clear evidence of carcinogenic activity of α-pinene in female B6C3F1/N mice based on the increased incidences of Harderian gland adenoma and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); alveolar/bronchiolar adenoma, carcinoma, and adenoma or carcinoma (combined); and mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined). Increased incidences of granulosa cell tumor, benign, malignant (combined) and tubulostromal adenoma in the ovary and a higher incidence of squamous cell carcinoma in the forestomach were also considered to be related to exposure.

Exposure to α-pinene resulted in increased incidences of nonneoplastic lesions in the epididymis, testis, adrenal gland, and liver of male rats; bone marrow, spleen, and uterus of female rats; epididymis, liver, lung, testis, and urinary bladder of male mice; and lung, ovary, urinary bladder, and stomach of female mice.

Under the conditions of these 3-month reproductive assessments in Hsd:Sprague Dawley^®^ SD^®^ rats and CD-1 mice, reproductive function was not affected by exposure.

Synonyms acitene A; cyclic dexadiene; 2-pinene; 2,6,6-trimethylbicyclo[3.1.1]hept-2-ene

Summary of the Two-year Carcinogenesis Studies of α-Pinene

| Male Sprague Dawley Rats | Female Sprague Dawley Rats | Male B6C3F1/N Mice | Female B6C3F1/N Mice
Concentrations in Air | 0, 50, 100, or 200 ppm | 0, 50, 100, or 200 ppm | 0, 100, 200, or 400 ppm | 0, 100, 200, or 400 ppm
Survival Rates | 22/50, 19/50, 21/50, 14/50 | 27/50, 15/50, 13/50, 5/50 | 39/50, 30/50, 34/50, 31/50 | 33/50, 29/50, 24/40, 24/50
Body Weights | ↓ (200 ppm group: 10% less than the control group at study termination) | ↓ (200 ppm group: <10% lower than the control group from study day 71 to 449) | ↓ (400 ppm group: 15.7% less than the control group at study termination) | No effect
Nonneoplastic Effects | [underlined: Testis]: germinal epithelium, degeneration (includes bilateral) (12/50, 24/50, 20/50, 17/50); germinal epithelium, degeneration or atrophy (combined, includes bilateral) (13/50, 24/50, 20/50, 17/50) [underlined: Epididymis]: hypospermia (includes bilateral) (7/50, 3/50, 10/50, 14/50) [underlined: Adrenal gland]: medulla, hyperplasia, focal (includes bilateral) (9/50, 8/50, 12/50, 18/50) [underlined: Liver]: bile duct, hyperplasia (5/50, 25/50, 26/50, 19/50) | [underlined: Uterus]: hyperplasia, atypical (0/50, 0/49, 0/50, 3/49); endometrium, hyperplasia, stromal (0/50, 6/49, 3/50, 6/49) [underlined: Bone marrow]: hypercellularity (10/50, 22/50, 18/50, 24/48) [underlined: Spleen]: extramedullary hematopoiesis, increased (10/50, 28/49, 28/49, 34/50) | [underlined: Liver]: multinucleated hepatocyte (3/50, 11/50, 10/49, 23/50); basophilic focus (1/50, 2/50, 3/49, 7/50); necrosis (1/50, 3/50, 2/49, 7/50) [underlined: Lung]: alveolar/bronchiolar, epithelium, hyperplasia (2/50, 10/50, 20/50, 27/50) [underlined: Urinary bladder]: urothelium, hyperplasia (1/48, 7/43, 18/48, 15/45); infiltration cellular, lymphocyte (1/48, 2/43, 9/48, 9/45); inflammation, suppurative (0/48, 2/43, 0/48, 5/45) [underlined: Testis]: germinal epithelium, degeneration (includes bilateral) (14/50, 9/49, 15/50, 28/47); germinal epithelium, atrophy (includes bilateral) (2/50, 1/49, 3/50, 6/47); germinal epithelium, degeneration or atrophy (combined, includes bilateral) (14/50, 9/49, 16/50, 28/47) [underlined: Epididymis]: duct, exfoliated germ cell (includes bilateral) (2/50, 5/49, 2/50, 18/48) | [underlined: Lung]: alveolar/bronchiolar, epithelium, hyperplasia (0/50, 10/50, 6/39, 17/50) [underlined: Urinary bladder]: urothelium, hyperplasia (0/45, 5/43, 11/34, 20/46) [underlined: Ovary]: hyperplasia, tubulostromal (includes bilateral) (1/48, 18/49, 21/36, 28/46) [underlined: Stomach, forestomach]: epithelium, hyperplasia, focal (0/49, 0/49, 0/38, 5/49)
Neoplastic Effects | [underlined: Urinary bladder]: papilloma (0/50, 0/50, 0/50, 3/50) | [underlined: Mammary gland]: adenocarcinoma (5/49, 7/50, 11/50, 25/50); adenoma or adenocarcinoma (combined) (6/49, 7/50, 15/50, 25/50) [underlined: Uterus]: adenocarcinoma (1/50, 7/49, 3/50, 4/49); squamous cell carcinoma (0/50, 0/49, 1/50, 3/49); squamous cell papilloma, squamous cell carcinoma, adenoma or adenocarcinoma (combined) (1/50, 7/49, 4/50, 6/49); polyp, stromal (5/50, 2/49, 4/50, 8/49) | [underlined: Harderian gland]: adenoma (includes bilateral) (6/50, 9/50, 11/50, 16/50); adenocarcinoma (includes bilateral) (0/50, 1/50, 3/50, 7/50); adenoma or adenocarcinoma (combined) (6/50, 9/50, 14/50, 23/50) [underlined: Liver]: hepatocellular adenoma (includes multiple) (23/50, 26/50, 31/49, 33/50); hepatocellular carcinoma (includes multiple) (18/50, 26/50, 17/49, 36/50); hepatocellular adenoma or hepatocellular carcinoma (combined, includes multiple) (33/50, 40/50, 40/49, 46/50) [underlined: Lung]: alveolar/bronchiolar adenoma (includes multiple) (5/50, 8/50, 10/50, 18/50); alveolar/bronchiolar adenoma or alveolar/bronchiolar carcinoma (combined, includes multiple) (14/50, 14/50, 21/50, 26/50) [underlined: Urinary bladder]: papilloma (0/48, 0/43, 0/48, 3/45) [underlined: Stomach, forestomach]: papilloma (0/49, 0/49, 2/50, 3/48) | [underlined: Harderian gland]: adenoma (includes bilateral) (3/50, 6/49, 11/40, 16/50); adenocarcinoma (includes bilateral) (1/50, 2/49, 3/40, 6/50); adenoma or adenocarcinoma (combined) (4/50, 8/49, 13/40, 22/50) [underlined: Liver]: hepatocellular adenoma (includes multiple) (6/50, 15/50, 20/38, 28/50); hepatocellular carcinoma (includes multiple) (7/50, 14/50, 11/38, 20/50); hepatocellular adenoma or hepatocellular carcinoma (combined, includes multiple) (12/50, 27/50, 24/38, 39/50) [underlined: Lung]: alveolar/bronchiolar adenoma (includes multiple) (2/50, 8/50, 9/39, 17/50); alveolar/bronchiolar carcinoma (includes multiple) (1/50, 2/50, 6/39, 23/50); alveolar/bronchiolar adenoma or alveolar/bronchiolar carcinoma (combined, includes multiple) (3/50, 10/50, 15/39, 37/50) [underlined: Mammary gland]: adenocarcinoma (0/48, 0/46, 0/40, 5/48); adenoma or adenocarcinoma (combined) (0/48, 0/46, 1/40, 5/48) [underlined: Ovary]: granulosa cell tumor, benign, malignant (combined) (0/48, 3/49, 2/36, 5/46); tubulostromal adenoma (0/48, 0/49, 1/36, 7/46) [underlined: Stomach, forestomach:] squamous cell carcinoma (0/49, 0/49, 0/38, 2/49)
Equivocal Findings | None^a^ | None | None | None
Level of Evidence of Carcinogenic Activity | Some evidence | Clear evidence | Clear evidence | Clear evidence

^a^ None = no toxicologically relevant effects for this endpoint.