# Overview

Summary of National Toxicology Program Studies of α-Pinene

The International Union of the United Auto Workers originally nominated turpentine to the National Toxicology Program (NTP) for comprehensive assessment because of widespread exposure potential and a lack of chronic toxicity data. α-Pinene was selected for study because it is a major constituent of turpentine and has a wider exposure profile from its use as a fragrance and flavoring ingredient. An inhalation route was chosen to reflect both occupational and consumer product exposure.

NTP assessment of α-pinene was initiated with 2-week and 3-month studies in Fischer 344 (F344/N) rats and B6C3F1/N mice.^2^ In light of the findings of hyperplasia in the urinary bladder of male and female mice and the concern expressed in the original nomination for turpentine exposure and chronic nephrotoxicity in humans, the chronic toxicity and carcinogenicity of α-pinene were evaluated. Between the 3-month studies and the beginning of the 2-year studies, a programmatic decision was made to switch from F344/N rats to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats because of inherent health issues (e.g., high rates of testicular cancer and mononuclear cell leukemia) and decreased fecundity in the F344/N rat strain.^3,4^ The 3-month F344/N and B6C3F1/N studies observed significant decreases in sperm counts, and thus, reproductive evaluations were added to the chronic study to investigate whether this effect translated into a functional deficit in reproduction; however, B6C3F1/N mice cannot be bred to maintain the same genetic background because they are an F_1_ hybrid, so the CD-1 mouse strain was selected. A 3-month evaluation of B6C3F1/N mice was included to confirm urinary bladder findings and to conduct histopathological assessment of male reproductive tissues that could not be evaluated in the previous study.

During the chronic rat study, exposure-related early deaths in females were attributed to mammary masses or nodules. At the end of the chronic studies, preliminary data were collected on the internal concentrations of α-pinene and its purported active metabolite, α-pinene oxide. The early signs of mammary tumors in the chronic study prompted the addition of a follow-up investigative 3-month study in male and female Sprague Dawley rats to evaluate early biomarkers of carcinogenicity in the mammary gland using error-corrected duplex sequencing (data are not reported here and will be published separately) and to perform a definitive evaluation of internal concentrations of α-pinene and α-pinene oxide in the blood and mammary gland using validated methods. Whole-genome sequencing of the rat mammary tumors and mouse liver tumors demonstrated an exposure concentration-dependent increase in mutation burden. Surprisingly, in the mouse inhalation study, the mutation burden was higher in the liver tumors compared to the lung tumors, implicating a mutagenic intermediate formed in the liver, likely α-pinene oxide, and thereby supporting a mutagenic mode of carcinogenesis. In addition, exposure-related de novo mutation signatures were observed in each of the respective tumor targets (summary results of these data are provided in Appendix E). Further immunohistochemical studies using human breast cancer-relevant biomarkers are in progress to compare the α-pinene-induced rat mammary tumors with those arising spontaneously due to aging. Results from the evaluation of biomarkers of carcinogenicity will be published in peer-reviewed manuscripts.

Multiple translational research efforts are ongoing, aimed at investigating the relevance of animal toxicity and carcinogenicity findings to human exposure scenarios. As the first step in this process, α-pinene oxide was identified as a possible active metabolite of α-pinene. In vitro assays confirmed the production of α-pinene oxide in rats and humans, and furthermore, α-pinene oxide was found to be mutagenic in the Ames assay.^5^ The toxicokinetic (TK) behavior of α-pinene and α-pinene oxide was investigated in blood and mammary gland following whole-body inhalation exposure in adult male and female Sprague Dawley rats and B6C3F1/N mice. Rodent systemic exposure has been compared to human systemic exposure data.^6^

Further collaborations with the National Institute for Occupational Safety and Health are measuring α-pinene and other monoterpene concentrations in various workplaces with potential exposures.

All NTP α-pinene toxicity and carcinogenicity studies used an inhalation route of exposure. However, oral exposure is also relevant for humans given α-pinene’s use as a flavoring ingredient and its possible presence in pine bark extract dietary supplements. Because of a lack of information on the α-pinene content in these products, a survey of monoterpenes in commercially available pine bark supplements was undertaken. Findings from this study will be published in peer-reviewed manuscripts. Additional studies were conducted to investigate the TK behavior of α-pinene and α-pinene oxide following a 7-day oral exposure in male and female Sprague Dawley rats and B6C3F1/N mice and to bridge inhalation and oral exposures.^7^