# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-606

Report Series: NTP Technical Report Series

Report Series Number: 606

Official citation: National Toxicology Program (NTP). 2026. NTP technical report on the toxicology and carcinogenesis studies of α-pinene (CASRN 80-56-8) administered by inhalation to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats, B6C3F1/N mice, and CD-1 mice. Research Triangle Park, NC: National Toxicology Program. Technical Report 606.