# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of α-Pinene (CASRN 80-56-8) Administered by Inhalation to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats, B6C3F1/N Mice, and CD-1 Mice by letter in June 2025 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Peer review the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of α-Pinene (CASRN 80-56-8) Administered by Inhalation to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats, B6C3F1/N Mice, and CD-1 Mice.

NTP carefully considered reviewer comments when finalizing this report. The anonymized peer review comments are provided in Appendix F.

## Peer Reviewers

- Javed A. Bhalli, Ph.D., M.Phil
  Vice President and Site Head, Safety and Toxicology
  Frontage Laboratories, Inc.
  Chicago, Illinois, USA
- Daniel J. Conklin, Ph.D.
  Director, Exposure Studies Shared Resource, Omics & Exposure Facility Core
  Co-Director, Research Engagement and Training Coordination Core
  University of Louisville
  Louisville, Kentucky, USA
- Terry Gordon, Ph.D.
  Research Professor, Department of Medicine
  New York University School of Medicine
  New York City, New York, USA
- Wendy G. Halpern, D.V.M., Ph.D.
  Senior Fellow – Pathologist
  Genentech, Inc.
  San Francisco, California, USA
- Stephen S. Hecht, Ph.D.
  Professor, Department of Laboratory Medicine and Pathology
  Masonic Cancer Center, University of Minnesota
  Minneapolis, Minnesota, USA
- Lisa A. Miller, Ph.D.
  Professor, Department of Anatomy, Physiology, and Cell Biology
  University of California, Davis School of Veterinary Medicine
  Davis, California, USA
- Wanying Zhang, M.D.
  Laboratory Director, Clinical Consultant
  Variantyx, Inc.
  Fort Lauderdale, Florida, USA