# Collaborators and Contributors

## Collaborators

- Division of Translational Toxicology, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Cynthia V. Rider, Ph.D., Lead Toxicologist^1,9,10^
  Ronald A. Herbert, D.V.M., Ph.D., Lead Pathologist^1,3,5,9,10^
  Chad R. Blystone, Ph.D.^1,10^
  Mark F. Cesta, D.V.M., Ph.D.^5,10^
  Angela P. King-Herbert, D.V.M.^5,9,10^
  Barry S. McIntyre, Ph.D. (Retired)^1,9,10^
  Arun R. Pandiri, B.V.Sc. & A.H., Ph.D.^1,3,9,10^
  Georgia K. Roberts, Ph.D.^1,5,10^
  Kelly A. Shipkowski, Ph.D.^5,10^
  Suramya Waidyanatha, Ph.D.^1,5,9,10^
- Social & Scientific Systems, a DLH Holdings Corp Company, Research Triangle Park, North Carolina, USA
  Contracts GS-00F-173CA/75N96022F00055 and HHSN273201600011C
  Shawn F. Harris, M.S.^2,10^
- Integrated Laboratory Systems, LLC, an Inotiv Company, Research Triangle Park, North Carolina, USA
  Contract HHSN273201500013C
  Cynthia J. Willson, D.V.M., Ph.D.^3,10^
- ICF, Reston, Virginia, USA
  Contracts 75N96025C00003 and GS00Q14OADU417 (Order No. HHSN273201600015U)
  Jeanne Luh, Ph.D.^9,10^

## Contributors

- Division of Translational Toxicology, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Danica Andrews, B.S.^5^
  Milene L. Brownlow, Ph.D. (currently at NIH Center for Scientific Review)^12^
  Michelle C. Cora, D.V.M.^1^
  Helen C. Cunny, Ph.D.^5^
  June K. Dunnick, Ph.D.^1^
  Sue E. Fenton, Ph.D. (currently at North Carolina State University)^1^
  Jennifer M. Fostel, Ph.D.^2,5^
  Paul M. Foster, Ph.D. (Retired)^1^
  William M. Gwinn, Ph.D.^1^
  Michelle J. Hooth, Ph.D.^10^
  Grace E. Kissling, Ph.D. (Retired)^1^
  Jian-Liang Li, Ph.D.^2,3^
  Ruth M. Lunn, Dr.P.H.^3^
  Daniel L. Morgan, Ph.D. (Retired)^1^
  Veronica G. Robinson, M.S. (Retired)^5^
  Keith R. Shockley, Ph.D.^5^
  Robert C. Sills, D.V.M., Ph.D.^1,3^
  Stephanie L. Smith-Roe, Ph.D.^1^
  Jason P. Stanko, Ph.D.^5^
  Matthew D. Stout, Ph.D.^1,5^
  Thai-Vu T. Ton, B.S.^3^
  Nigel J. Walker, Ph.D.^10^
  Kristine L. Witt, M.S. (Retired)^9^
  Mary S. Wolfe, Ph.D. (Retired)^12^
- Battelle, Columbus, Ohio, USA
  Contract HHSN273201400015C
  Milton R. Hejtmancik, Ph.D., Principal Investigator^5,6^
  Barney R. Sparrow, Ph.D., Principal Investigator^5,6^
  Jessica Bailey, D.V.M.^3^
  Brian L. Burback, Ph.D.^5,6^
  P. Scott Clemons, Ph.D.^3^
  Amit Gupta, M.S.^3^
  Barry K. Hayden^3^
  Eve Mylchreest, Ph.D.^3^
  Mark Perry, M.S.^3^
  Jamie S. Richey, M.S.^5,6^
  Roger Renne, D.V.M.^3^
  Kemla Siddoway, B.S.^3^
  Anthony J. Skowronek, D.V.M., Ph.D.^3^
- AmplifyBio, West Jefferson, Ohio, USA
  Subcontract to HHSN273201400015C
  Karen E. Elsass, B.S.^3^
  Heather Toy, B.S.^3^
- RTI International, Research Triangle Park, North Carolina, USA
  Contracts HHSN273201400004C, HHSN273201400022C, HHSN273201100003C
  Reshan A. Fernando, Ph.D., Principal Investigator^5,6^
  James C. Blake, B.A. ^5,6^
  Timothy R. Fennell, Ph.D.^3^
  Jennifer Gilliam, B.S.^3^
  Melanie Silinski, Ph.D.^3^
- Taconic BioSciences, Inc., Germantown, New York, USA
  Contract HHSN273201600020C
  Jeffrey Lohmiller, D.V.M., Principal Investigator^5,6^
  Jami Southard, A.G.S.^3^
- Instem, Staffordshire, United Kingdom
  Contract HHSN273201300004C
  Mark Handley, Computing H.N.C., Program Manager^2,5,6^
  Pam Reese, B.S.^2^
  Martin Tyszka, M.S.^2^
- Charles River Laboratories, Inc., Durham, North Carolina, USA
  Contract HHSN273201500012C
  Vivian S. Chen, D.V.M., Ph.D.^3^
  Sheba R. Churchill, D.V.M.^10^
  Crystal L. Johnson, D.V.M.^3^
  Ashley Talley, D.V.M.^3^
- Pathology Working Group on Two-year Study in Mice (March 8, 2011), National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Ronald A. Herbert, D.V.M., Ph.D., National Institute of Environmental Health Sciences^3^
  Arun R. Pandiri, B.V.Sc. & A.H., Ph.D., National Institute of Environmental Health Sciences^3^
- Contract HHSN273201500012C
  Michael R. Elwell, D.V.M., Ph.D., Apex ToxPath, LLC.^3^
- Contract HHSN273201500014C
  Amy E. Brix, D.V.M., Ph.D., Experimental Pathology Laboratories, Inc.^3^
  Torrie A. Crabbs, D.V.M., Experimental Pathology Laboratories, Inc.^3^
- Contract HHSN273201500013C
  Kristen R. Hobbie, D.V.M., Ph.D., Integrated Laboratory Systems, LLC, an Inotiv Company^3^
  Cynthia J. Willson, D.V.M., Ph.D., Integrated Laboratory Systems, LLC, an Inotiv Company^3^
- Contract HHSN273201400015C
  Anthony J. Skowronek, D.V.M., Ph.D., Battelle^3^
- Pathology Working Group on Two-year Study in Rats (March 8–9, 2011), National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Ronald A. Herbert, D.V.M., Ph.D., National Institute of Environmental Health Sciences^3^
  Arun R. Pandiri, B.V.Sc. & A.H., Ph.D., National Institute of Environmental Health Sciences^3^
- Contract HHSN273201500014C
  Amy E. Brix, D.V.M., Ph.D., Experimental Pathology Laboratories, Inc.^3^
  Torrie A. Crabbs, D.V.M., Experimental Pathology Laboratories, Inc.^3^
- Contract HHSN273201500013C
  Kristen R. Hobbie, D.V.M., Ph.D., Integrated Laboratory Systems, LLC, an Inotiv Company^3^
  Cynthia J. Willson, D.V.M., Ph.D., Integrated Laboratory Systems, LLC, an Inotiv Company^3^
- Contract HHSN273201500012C
  Vivian S. Chen, D.V.M., Ph.D., Charles River Laboratories, Inc.^3^
  Michael R. Elwell, D.V.M., Ph.D., Apex ToxPath, LLC.^3^
- Contract HHSN273201400015C
  Anthony J. Skowronek, D.V.M., Ph.D., Battelle^3^
- Integrated Laboratory Systems, LLC, an Inotiv Company, Research Triangle Park, North Carolina, USA
  Contract HHSN273201500013C
  Georgette D. Hill, D.V.M, Ph.D.^3^
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Contracts 75N96024C00002 and HHSN273201800006C
  Emily Singletary, A.S., B.S., Manager^5,6^
  Michael J. Carden^3^
  Leslie C. Couch, B.S.^3^
  Lorri N. Ezedin, B.S.^3^
  Jami L. Heller, A.A.S., B.S.^3^
  Alexis Mihaltian, B.S.^3^
- Contract HHSN273201500014C
  Karen Y. Cimon, D.V.M., M.S.^10^
- Kelly Government Solutions, Research Triangle Park, North Carolina, USA
  Contract 75N95021D00012
  Ashley M. Brooks, Ph.D.^2,3^
  Jianying Li, M.S.^2,3^
- Princeton University, Princeton, New Jersey, USA
  Ella Gunady, B.S.^2,3^
- Wellcome Sanger Institute, Cambridge, United Kingdom
  David Adams, Ph.D.^1,2,3^
- ASRC Federal Data Solutions, Beltsville, Maryland, USA
  Contracts 75N96023A00001 and HHSN316201200054W
  Bhawana Bariar, Ph.D.^2^
  Julie Berke, B.S.^2^
  Phyllis B. Brown, B.S.^2^
  Karen S. Gilbert, B.S.^2^
  Courtney R. Goslowsky, B.S.^2^
  Marcus A. Jackson, B.S.^2^
  Kelsey J. Oeler, Ph.D.^2^
  Satya S. Uppuganti, M.S.^2^
- CSS Corporation, Research Triangle Park, North Carolina, USA
  Contract HHSN273201500006C
  Steven Brecher, Ph.D., Principal Investigator^5,6,11^
  Sudha Iyer, B.S.^11^
  Varghese S. Tharakan, D.V.M.^11^
- Social & Scientific Systems, a DLH Holdings Corp Company, Research Triangle Park, North Carolina, USA
  Contracts GS-00F-173CA/75N96022F00055 and HHSN273201600011C
  Katherine N. Allen, Ph.D., Principal Investigator^5,6^
  Laura J. Betz, M.S.^2^
  Angela Jeffers, B.S.^2^
  Guanhua Xie, Ph.D.^2^
- ICF, Reston, Virginia, USA
  Contracts 75N96025C00003 and GS00Q14OADU417 (Order No. HHSN273201600015U)
  David Burch, M.E.M., Principal Investigator^5,6^
  Kezia A. Addo, Ph.D.^10^
  Tamara Dawson^12^
  Katherine S. Duke, Ph.D.^10^
  Hannah J. Eglinton, B.A.^10^
  Lindsey M. Green, M.P.H.^12^
  Tara Hamilton, M.S.^10^
  Cary E. Haver, M.P.H.^5^
  Rachel C. McGill, B.S.^10^
  Kevin T. O’Donovan, B.A.^10^
  Jennifer I. Powers, M.A.P.^10^
  Lisa M. Prince, Ph.D.^10^
  Courtney Rosenthal, M.S.^10^
  Samantha J. Snow, Ph.D.^10^
  Swati Sriram, M.P.H.^10^
  J. Wren Tracy, M.H.S.^10^
  Nkoli Ukpabi, M.S.^10^
  Jessica A. Wignall, M.S.P.H.^5,6^
- Integrated Laboratory Systems, LLC, an Inotiv Company, Research Triangle Park, North Carolina, USA
  Subcontract to 75N96025C00003
  Whitney D. Arroyave, Ph.D.^3,5,6^
  Alton F. Peters, M.S.^3^

Collaborator and Contributor Roles and Definitions^a^

No. | Role | Definition
1 | Conceptualization | Ideas; formulation or evolution of overarching research goals and aims
2 | Data Curation, Formal Analysis, and Software | Management activities to annotate (produce metadata), scrub, and maintain research data (including software code, when it is necessary for interpreting the data) for initial use and later reuse or Application of statistical, mathematical, computational, or other formal techniques to analyze or synthesize study data or Programming and software development; design of computer programs; implementation of computer code and supporting algorithms; testing of existing code components
3 | Investigation | Conduct of the research/investigation process, specifically the performance of experiments or the collection of data/evidence
4 | Methodology | Development or design of methodology; creation of models
5 | Project Administration | Management and coordination responsibility for research planning and execution
6 | Resources for Study Conduct | Provision of study materials, reagents, patients, laboratory samples, animals, instrumentation, computing resources, or other analysis tools
7 | Validation | Verification, whether as a part of the activity or separately, of the overall replication/reproducibility of results/experiments and other research outputs
8 | Visualization | Preparation, creation, and/or presentation of the published work, specifically visualization/data presentation
9 | Writing: Original | Preparation, creation, and/or presentation of the published work, specifically the writing of the initial draft (including substantive translation)
10 | Writing: Review and Editing | Preparation, creation, and/or presentation of the published work by those from the original research group, specifically provision of substantive critical review, commentary, or revision—including pre- or post-publication stages
11 | Quality Assessment | Conduct of independent assessments of accuracy, consistency, and completeness of various aspects of research products and their components, including data; identification of areas in the conduct and documentation of studies that merit correction or improvement of the description of methodologies
12 | Peer Review and Production | Coordination and management of external peer review and publication, including identification of experts, conflict-of-interest screening, correspondence with reviewers, preparation of review documents, and publication activities

^a^ Developed using the Contributor Roles Taxonomy (CRediT) framework.^1^