# References

1 National Information Standards Organization (NISO). CRediT (Contributor Roles Taxonomy). Baltimore, MD: National Information Standards Organization; 2024. [Accessed: July 26, 2024]. https://credit.niso.org/
2 National Toxicology Program (NTP). NTP technical report on the toxicity studies of α-pinene (CAS No. 80-56-8) administered by inhalation to F344/N rats and B6C3F1/N mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2016. NTP Toxicity Report No. 81. 10.22427/NTP-TOX-81
3 King-Herbert A, Thayer K. NTP workshop: Animal models for the NTP rodent cancer bioassay: Stocks and strains—should we switch? Toxicol Pathol. 2006; 34(6):802–805. 10.1080/01926230600935938 17162538
4 King-Herbert AP, Sills RC, Bucher JR. Commentary: Update on animal models for NTP studies. Toxicol Pathol. 2010; 38(1):180–181. 10.1177/0192623309356450 20019353
5 Waidyanatha S, Black SR, Witt KL, Fennell TR, Swartz C, Recio L, Watson SL, Patel P, Fernando RA, Rider CV. The common indoor air pollutant α-pinene is metabolised to a genotoxic metabolite α-pinene oxide. Xenobiotica. 2022; 52(3):301–311. 10.1080/00498254.2022.2070047 35473450
6 Waidyanatha S, Hackett M, Black SR, Stout MD, Fennell TR, Silinski MR, Watson SL, Licause J, Robinson VG, Sparrow B, et al. Toxicokinetic evaluation of the common indoor air pollutant, α-pinene, and its potential reactive metabolite, α-pinene oxide, following inhalation exposure in rodents. Toxicol Appl Pharmacol. 2021;418:115496. 10.1016/j.taap.2021.115496 33744279
7 Waidyanatha S, Fennell TR, Black SR, Silinski MR, Knudsen GA, Fernando RA, Rider CV. Oral toxicokinetics of the indoor air pollutant, α-pinene, and its genotoxic metabolite, α-pinene oxide, in rodents and comparison to inhalation route of exposure. Toxicol Appl Pharmacol. 2026;513:117893. 10.1016/j.taap.2026.117893 42217586
8 National Center for Biotechnology Information (NCBI). PubChem compound summary for CID 6654, (+-)-alpha-pinene. Bethesda, MD: U.S. Department of Health and Human Services, National Institutes of Health, National Library of Medicine, National Center for Biotechnology Information; 2024. [Accessed: May 30, 2024]. https://pubchem.ncbi.nlm.nih.gov/compound/alpha-PINENE
9 U.S. Environmental Protection Agency (USEPA). CompTox Chemicals Dashboard: alpha-Pinene: 80-56-8 | DTXSID4026501: Properties. Washington, DC: U.S. Environmental Protection Agency; 2024. [Accessed: May 6, 2024]. https://comptox.epa.gov/dashboard/chemical/properties/DTXSID4026501
10 Bagchi A, Yu Y, Huang JH, Tsai CC, Hu WP, Wang CC. Evidence and evolution of Criegee intermediates, hydroperoxides and secondary organic aerosols formed via ozonolysis of α-pinene. Phys Chem Chem Phys. 2020; 22(12):6528–6537. 10.1039/C9CP06306D 32091071
11 Geron C, Rasmussen R, Arnts RR, Guenther A. A review and synthesis of monoterpene speciation from forests in the United States. Atmos Environ. 2000; 34(11):1761–1781. 10.1016/S1352-2310(99)00364-7
12 Gachkar L, Yadegari D, Rezaei MB, Taghizadeh M, Astaneh SA, Rasooli I. Chemical and biological characteristics of Cuminum cyminum and Rosmarinus officinalis essential oils. Food Chem. 2007; 102(3):898–904. 10.1016/j.foodchem.2006.06.035
13 Booth JK, Page JE, Bohlmann J. Terpene synthases from Cannabis sativa. PLoS One. 2017; 12(3):e0173911. 10.1371/journal.pone.0173911 28355238
14 Tisserand R, Young R. Essential oil composition. In: Essential Oil Safety: A Guide for Health Care Professionals. 2nd ed. Edinburgh, Scotland: Churchill Livingstone/Elsevier; 2014. p. 5-22. 10.1016/B978-0-443-06241-4.00002-3
15 Wibe A, Borg-Karlson AK, Persson M, Norin T, Mustaparta H. Enantiomeric composition of monoterpene hydrocarbons in some conifers and receptor neuron discrimination of α-pinene and limonene enantiomers in the pine weevil, Hylobius abietis. J Chem Ecol. 1998; 24(2):273–287. 10.1023/A:1022580308414
16 Phillips MA, Savage TJ, Croteau R. Monoterpene synthases of loblolly pine (Pinus taeda) produce pinene isomers and enantiomers. Arch Biochem Biophys. 1999; 372(1):197–204. 10.1006/abbi.1999.1467 10562434
17 Raeber J, Bajor B, Poetzsch M, Steuer C. Comprehensive analysis of chemical and enantiomeric stability of terpenes in Cannabis sativa L. flowers. Phytochem Anal. 2025; 36(1):205–217. 10.1002/pca.3432 39103248
18 Fuchs-Algrim J, Lorenz H, Zimmermann C, Günnewich N, Schwarzensteiner I, Kaiser PM, Tronnier H. Turpentine ointment in bacterial skin infections: A randomized, placebo-controlled, double-blind clinical trial. Complement Med Res. 2023; 30(1):56–62. 10.1159/000528220 36417842
19 Maimoona A, Naeem I, Saddiqe Z, Jameel K. A review on biological, nutraceutical and clinical aspects of French maritime pine bark extract. J Ethnopharmacol. 2011; 133(2):261–277. 10.1016/j.jep.2010.10.041 21044675
20 Adams TB, Gavin CL, McGowen MM, Waddell WJ, Cohen SM, Feron VJ, Marnett LJ, Munro IC, Portoghese PS, Rietjens IMCM, et al. The FEMA GRAS assessment of aliphatic and aromatic terpene hydrocarbons used as flavor ingredients. Food Chem Toxicol. 2011; 49(10):2471–2494. 10.1016/j.fct.2011.06.011 21726592
21 Nazaroff WW, Weschler CJ. Cleaning products and air fresheners: Exposure to primary and secondary air pollutants. Atmos Environ. 2004; 38(18):2841–2865. 10.1016/j.atmosenv.2004.02.040
22 Kwon KD, Jo WK, Lim HJ, Jeong WS. Characterization of emissions composition for selected household products available in Korea. J Hazard Mater. 2007; 148(1-2):192–198. 10.1016/j.jhazmat.2007.02.025 17376591
23 Rastogi SC, Heydorn S, Johansen JD, Basketter DA. Fragrance chemicals in domestic and occupational products. Contact Dermatitis. 2001; 45(4):221–225. 10.1034/j.1600-0536.2001.450406.x 11683833
24 de Carvalho CCCR, da Fonseca MMR. Biotransformation of terpenes. Biotechnol Adv. 2006; 24(2):134–142. 10.1016/j.biotechadv.2005.08.004 16169182
25 Demers PA, Teschke K, Davies HW, Kennedy SM, Leung V. Exposure to dust, resin acids, and monoterpenes in softwood lumber mills. AIHAJ. 2000; 61(4):521–528. 10.1080/15298660008984564 10976682
26 Fransman W, McLean D, Douwes J, Demers PA, Leung V, Pearce N. Respiratory symptoms and occupational exposures in New Zealand plywood mill workers. Ann Occup Hyg. 2003; 47(4):287–295. 10.1093/annhyg/meg046 12765869
27 Rosenberg C, Liukkonen T, Kallas-Tarpila T, Ruonakangas A, Ranta R, Nurminen M, Welling I, Jäppinen P. Monoterpene and wood dust exposures: Work-related symptoms among Finnish sawmill workers. Am J Ind Med. 2002; 41(1):38–53. 10.1002/ajim.10033 11757054
28 Hedenstierna G, Alexandersson R, Wimander K, Rosén G. Exposure to terpenes: Effects on pulmonary function. Int Arch Occup Environ Health. 1983; 51(3):191–198. 10.1007/BF00377751 6852927
29 Su FC, Friesen MC, Stefaniak AB, Henneberger PK, LeBouf RF, Stanton ML, Liang X, Humann M, Virji MA. Exposures to volatile organic compounds among healthcare workers: Modeling the effects of cleaning tasks and product use. Ann Work Expo Health. 2018; 62(7):852–870. 10.1093/annweh/wxy055 29931140
30 Jia C, Batterman S, Godwin C. VOCs in industrial, urban and suburban neighborhoods, part 1: Indoor and outdoor concentrations, variation, and risk drivers. Atmos Environ. 2008; 42(9):2083–2100. 10.1016/j.atmosenv.2007.11.055
31 Hodgson AT, Beal D, McIlvaine JER. Sources of formaldehyde, other aldehydes and terpenes in a new manufactured house. Indoor Air. 2002; 12(4):235–242. 10.1034/j.1600-0668.2002.01129.x 12532755
32 Moreno T, Pacitto A, Fernández A, Amato F, Marco E, Grimalt JO, Buonanno G, Querol X. Vehicle interior air quality conditions when travelling by taxi. Environ Res. 2019;172:529–542. 10.1016/j.envres.2019.02.042 30852456
33 Wolkoff P, Nielsen GD. Effects by inhalation of abundant fragrances in indoor air – An overview. Environ Int. 2017;101:96–107. 10.1016/j.envint.2017.01.013 28126407
34 American Conference of Governmental Industrial Hygienists (ACGIH). 2014 TLVs and BEIs: Based on the documentation of the threshold limit values for chemical substances and physical agents & biological exposure indices. Cincinnati, OH: American Conference of Governmental Industrial Hygienists; 2014.
35 Occupational Safety and Health Administration (OSHA). Occupational safety and health guideline for turpentine. Washington, DC: U.S. Department of Labor, Occupational Safety and Health Administration; 2013. [Accessed: January 4, 2024]. https://web.archive.org/web/20130216085929/http://www.osha.gov/SLTC/healthguidelines/turpentine/recognition.html
36 National Institute for Occupational Safety and Health (NIOSH). Recommended exposure level to turpentine-Air. U.S. Department of Health and Human Services, Public Health Service, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 1992.
37 Institut für Arbeitsschultz der Deutschen Gesetzlichen Unfallversicherung (IFA). GESTIS - International limit values: Substance list. Sankt Augustin, Germany: Institut für Arbeitsschultz der Deutschen Gesetzlichen Unfallversicherung; 2024. [Accessed: March 19, 2024]. https://ilv.ifa.dguv.de/substances
38 White RA, Agosin M. Metabolism of α-pinene by rat liver reconstituted cytochrome p-450 systems. In: Gustafsson JA, Carlstedt-Duke J, Mode A, Rafter J, editors. Biochemistry, Biophysics, and Regulation of Cytochrome P-450: Proceedings of the Third European Meeting on Cytochrome P-450, held in Saltsj̈obaden, Sweden, June 16-19, 1980. Amsterdam, The Netherlands: Elsevier/North-Holland Biomedical Press; 1980.
39 Falk AA, Hagberg MT, Lof AE, Wigaeus-Hjelm EM, Wang ZP. Uptake, distribution and elimination of alpha-pinene in man after exposure by inhalation. Scand J Work Environ Health. 1990; 16(5):372–378. 10.5271/sjweh.1771 2255878
40 Filipsson AF. Short term inhalation exposure to turpentine: Toxicokinetics and acute effects in men. Occup Environ Med. 1996; 53(2):100–105. 10.1136/oem.53.2.100 8777445
41 Eriksson K, Levin JO. Identification of cis- and trans-verbenol in human urine after occupational exposure to terpenes. Int Arch Occup Environ Health. 1990; 62(5):379–383. 10.1007/BF00381368 2228258
42 Eriksson K, Levin JO. Gas chromatographic-mass spectrometric identification of metabolites from alpha-pinene in human urine after occupational exposure to sawing fumes. J Chromatogr B Biomed Appl. 1996; 677(1):85–98. 10.1016/0378-4347(95)00435-1 8925106
43 U.S. Environmental Protection Agency (USEPA). Screening-level hazard characterization: Bicyclic terpene hydrocarbons category. Washington, DC: U.S. Environmental Protection Agency; 2010.
44 Wei Q, Harada K, Ohmori S, Minamoto K, Wei C, Ueda A. Toxicity study of the volatile constituents of myoga utilizing acute dermal irritation assays and the Guinea-Pig Maximization Test. J Occup Health. 2006; 48(6):480–486. 10.1539/joh.48.480 17179641
45 Wei QJ, Wei CN, Harada K, Minamoto K, Okamoto Y, Otsuka M, Ueda A. Evaluation of allergenicity of constituents of myoga using the murine local lymph node assay. Int J Immunopathol Pharmacol. 2010; 23(2):463–470. 10.1177/039463201002300208 20646341
46 Klecak G. The Freund's complete adjuvant test and the open epicutaneous test: A complementary test procedure for realistic assessment of allergenic potential. In: Andersen KE, Maibach HI, editors. Contact Allergy Predictive Tests in Guinea Pigs. Basel, Switzerland: Karger; 1985. p. 152-171. 10.1159/000411610
47 Johard U, Larsson K, Löf A, Eklund A. Controlled short-time terpene exposure induces an increase of the macrophages and the mast cells in bronchoalveolar lavage fluid. Am J Ind Med. 1993; 23(5):793–799. 10.1002/ajim.4700230512 8506856
48 Cachão P, Menezes Brandão F, Carmo M, Frazão S, Silva M. Allergy to oil of turpentine in Portugal. Contact Dermatitis. 1986; 14(4):205–208. 10.1111/j.1600-0536.1986.tb01225.x 3720296
49 Kauppinen TP, Partanen TJ, Hernberg SG, Nickels JI, Luukkonen RA, Hakulinen TR, Pukkala EI. Chemical exposures and respiratory cancer among Finnish woodworkers. Br J Ind Med. 1993; 50(2):143–148. 10.1136/oem.50.2.143 8435346
50 De Roos AJ, Olshan AF, Teschke K, Poole C, Savitz DA, Blatt J, Bondy ML, Pollock BH. Parental occupational exposures to chemicals and incidence of neuroblastoma in offspring. Am J Epidemiol. 2001; 154(2):106–114. 10.1093/aje/154.2.106 11447042
51 Chapman EM. Observations on the effect of paint on the kidneys with particular reference to the role of turpentine. J Ind Hyg Toxicol. 1941; 23(7):277–289.
52 Florin I, Rutberg L, Curvall M, Enzell CR. Screening of tobacco smoke constituents for mutagenicity using the Ames’ test. Toxicology. 1980; 15(3):219–232. 10.1016/0300-483X(80)90055-4 7008261
53 Connor TH, Theiss JC, Hanna HA, Monteith DK, Matney TS. Genotoxicity of organic-chemicals frequently found in the air of mobile homes. Toxicol Lett. 1985; 25(1):33–40. 10.1016/0378-4274(85)90097-9 3887653
54 Gomes-Carneiro MR, Viana MES, Felzenszwalb I, Paumgartten FJR. Evaluation of beta-myrcene, alpha-terpinene and (+)- and (-)-alpha-pinene in the Salmonella/microsome assay. Food Chem Toxicol. 2005; 43(2):247–252. 10.1016/j.fct.2004.09.011 15621337
55 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis studies of β-myrcene (CAS No. 123-35-3) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, National Toxicology Program; 2010. NTP Technical Report No. 557. NIH Publication No. 11-5898. [Accessed: February 12, 2024]. https://ntp.niehs.nih.gov/go/tr557abs
56 National Toxicology Program (NTP). Pine bark extract (PINEBARKEXT). Chemical Effects in Biological Systems (CEBS). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2024. 10.22427/NTP-DATA-DTXSID2031908
57 Organisation for Economic Co-operation and Development (OECD). Test No. 471: Bacterial reverse mutation test. (OECD guidelines for the testing of chemicals, section 4). Paris, France: OECD Publishing; 2020. 10.1787/9789264071247-en
58 Gminski R, Tang T, Mersch-Sundermann V. Cytotoxicity and genotoxicity in human lung epithelial A549 cells caused by airborne volatile organic compounds emitted from pine wood and oriented strand boards. Toxicol Lett. 2010; 196(1):33–41. 10.1016/j.toxlet.2010.03.015 20362040
59 Catanzaro I, Caradonna F, Barbata G, Saverini M, Mauro M, Sciandrello G. Genomic instability induced by α-pinene in Chinese hamster cell line. Mutagenesis. 2012; 27(4):463–469. 10.1093/mutage/ges005 22379123
60 Türkez H, Aydin E. In vitro assessment of cytogenetic and oxidative effects of α-pinene. Toxicol Ind Health. 2016; 32(1):168–176. 10.1177/0748233713498456 24081629
61 Kević Dešić S, Viljetić B, Wagner J. Assessment of the genotoxic and cytotoxic effects of turpentine in painters. Life (Basel). 2023; 13(2):530. 10.3390/life13020530 36836885
62 Fernando RA, Fennell TR, Watson SL, Silinski MAR, Blake JC, Robinson VG, Waidyanatha S. Development and validation of an analytical method for quantitation of alpha-pinene oxide in rodent blood and mammary glands by GC–MS. J Anal Toxicol. 2022; 46(3):270–276. 10.1093/jat/bkab007 33438723
63 Silinski MAR, Licause J, Uenoyama T, Blake JC, Fernando RA, Robinson VG, Waidyanatha S. Development and validation of an analytical method for quantitation of alpha-pinene in rodent blood and mammary gland by headspace GC–MS. J Anal Toxicol. 2022; 46(2):128–134. 10.1093/jat/bkaa195 33336684
64 National Toxicology Program (NTP). Specifications for the conduct of studies to evaluate the toxic and carcinogenic potential of chemical, biological and physical agents in laboratory animals for the National Toxicology Program (NTP). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, National Toxicology Program; 2011.
65 Sills RC, Cesta MF, Willson CJ, Brix AE, Berridge BR. National Toxicology Program position statement on informed (“nonblinded”) analysis in toxicologic pathology evaluation. Toxicol Pathol. 2019; 47(7):887–890. 10.1177/0192623319873974 31522628
66 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
67 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
68 Brix AE, Hardisty JF, McConnell EE. Combining neoplasms for evaluation of rodent carcinogenesis studies. In: Hsu CH, Stedeford T, editors. Cancer Risk Assessment: Chemical Carcinogenesis, Hazard Evaluation, and Risk Quantification. Hoboken, NJ: Wiley; 2010. p. 699-715. 10.1002/9780470622728.ch28
69 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481. 10.1080/01621459.1958.10501452
70 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975; 62(3):679–690. 10.1093/biomet/62.3.679
71 Cox DR. Regression models and life‐tables. J R Stat Soc Series B Stat Methodol. 1972; 34(2):187–202. 10.1111/j.2517-6161.1972.tb00899.x
72 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431. 10.2307/2531856 3390507
73 Piegorsch WW, Bailer AJ. Statistics for environmental biology and toxicology: Section 6.3.2. London, UK: Chapman and Hall; 1997.
74 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
75 Portier CJ, Hedges JC, Hoel DG. Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986; 46(9):4372–4378. 3731095
76 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. 10.2307/2532200 8241374
77 Nam JM. A simple approximation for calculating sample sizes for detecting linear trend in proportions. Biometrics. 1987; 43(3):701–705. 10.2307/2532006 3663825
78 Dixon WJ, Massey FJ. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw-Hill; 1957.
79 Tukey JW. Easy summaries--numerical and graphical. In: Exploratory Data Analysis. Reading, MA: Addison-Wesley; 1977. p. 27-56.
80 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
81 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
82 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
83 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
84 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
85 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
86 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. 10.1093/biomet/41.1-2.133
87 Kalbfleisch JD, Lawless JF. The analysis of panel data under a Markov assumption. J Am Stat Assoc. 1985; 80(392):863–871. 10.1080/01621459.1985.10478195
88 Haseman JK. Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992; 26(2):191–200. 10.1177/009286159202600210
89 Haseman JK. Data analysis: Statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995; 21(1):52–59. 10.1006/rtph.1995.1009 7784636
90 Haseman JK, Rao GN. Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992; 20(1):52–60. 10.1177/019262339202000107 1411131
91 U.S. Food and Drug Administration (FDA). 21 CFR Part 58. https://www.ecfr.gov/current/title-21/chapter-I/subchapter-A/part-58
92 National Toxicology Program (NTP). TR-606: Technical report pathology tables and curves. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2026. 10.22427/NTP-DATA-TR-606
93 Mercier B, Prost J, Prost M. The essential oil of turpentine and its major volatile fraction (alpha- and beta-pinenes): A review. Int J Occup Med Environ Health. 2009; 22(4):331–342. 20197260
94 Rivas da Silva AC, Lopes PM, Barros de Azevedo MM, Costa DCM, Alviano CS, Alviano DS. Biological activities of α-pinene and β-pinene enantiomers. Molecules. 2012; 17(6):6305–6316. 10.3390/molecules17066305 22634841
95 Rufino AT, Ribeiro M, Judas F, Salgueiro L, Lopes MC, Cavaleiro C, Mendes AF. Anti-inflammatory and chondroprotective activity of (+)-α-pinene: Structural and enantiomeric selectivity. J Nat Prod. 2014; 77(2):264–269. 10.1021/np400828x 24455984
96 Tisserand R, Young R. Essential oil profiles. In: Essential Oil Safety: A Guide for Health Care Professionals. 2nd ed. Edinburgh, Scotland: Churchill Livingstone/Elsevier; 2014. p. 187-482. 10.1016/B978-0-443-06241-4.00013-8
97 Ridder GM, Von Bargen EC, Alden CL, Parker RD. Increased hyaline droplet formation in male rats exposed to decalin is dependent on the presence of alpha 2u-globulin. Fundam Appl Toxicol. 1990; 15(4):732–743. 10.1016/0272-0590(90)90189-Q 1707839
98 Lam CM, Li Z, Theodorescu D, Li X. Mechanism of sex differences in bladder cancer: Evident and elusive sex-biasing factors. Bladder Cancer. 2022; 8(3):241–254. 10.3233/BLC-211658 36277328
99 Wellcome Sanger Institute. COSMIC: Mutational signatures (v3.4 - October 2023): SBS21, GRCh37, COSMIC v102. Cambridge, UK: Wellcome Sanger Institute; 2025. [Accessed: September 19, 2025]. https://cancer.sanger.ac.uk/signatures/sbs/sbs21/
100 Cline JM. Neoplasms of the reproductive tract: The role of hormone exposure. ILAR J. 2004; 45(2):179–188. 10.1093/ilar.45.2.179 15111737
101 Nandi S, Guzman RC, Yang J. Hormones and mammary carcinogenesis in mice, rats, and humans: A unifying hypothesis. Proc Natl Acad Sci USA. 1995; 92(9):3650–3657. 10.1073/pnas.92.9.3650 7731959
102 Hawkins RA, Drewitt D, Freedman B, Killin E, Jenner DA, Cameron EH. Plasma hormone levels and the incidence of carcinogen-induced mammary tumours in two strains of rat. Br J Cancer. 1976; 34(5):546–549. 10.1038/bjc.1976.209 826265
103 Harleman JH, Hargreaves A, Andersson H, Kirk S. A review of the incidence and coincidence of uterine and mammary tumors in Wistar and Sprague-Dawley rats based on the RITA database and the role of prolactin. Toxicol Pathol. 2012; 40(6):926–930. 10.1177/0192623312444621 22585942
104 Albert DM, Frayer WC, Black HE, Massicotte SJ, Sang DN, Soque J. The harderian gland: Its tumors and its relevance to humans. Trans Am Ophthalmol Soc. 1986;84:321–341. 3296405
105 Proctor DM, Gatto NM, Hong SJ, Allamneni KP. Mode-of-action framework for evaluating the relevance of rodent forestomach tumors in cancer risk assessment. Toxicol Sci. 2007; 98(2):313–326. 10.1093/toxsci/kfm075 17426108
106 Karlberg AT, Lepoittevin JP. One hundred years of allergic contact dermatitis due to oxidized terpenes: What we can learn from old research on turpentine allergy. Contact Dermatitis. 2021; 85(6):627–636. 10.1111/cod.13962 34453446
107 Kenkel S, Rolf C, Nieschlag E. Occupational risks for male fertility: An analysis of patients attending a tertiary referral centre. Int J Androl. 2001; 24(6):318–326. 10.1111/j.1365-2605.2001.00304.x 11737412
108 Ould Hamouda S, Perrin J, Achard V, Courbière B, Grillo JM, Sari-Minodier I. [Association between sperm abnormalities and occupational environment among male consulting for couple infertility]. J Gynecol Obstet Biol Reprod (Paris). 2016; 45(1):1–10. 10.1016/j.jgyn.2015.08.011 26387599
109 Melnick RL. Carcinogenicity and mechanistic insights on the behavior of epoxides and epoxide-forming chemicals. Ann N Y Acad Sci. 2002; 982(1):177–189. 10.1111/j.1749-6632.2002.tb04932.x 12562636
110 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis studies of citral (microencapsulated) (CAS No. 5392-40-5) in F344/N rats and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, National Toxicology Program; 2003. NTP Technical Report No. 505. NIH Publication No. 03-4439. [Accessed: February 12, 2024]. https://ntp.niehs.nih.gov/go/tr505abs
111 National Toxicology Program (NTP). NTP technical report on the carcinogenesis studies of food grade geranyl acetate (71% geranyl acetate, 29% citronellyl acetate) (CAS No. 105-87-3) in F344/N rats and B6C3F1 mice (gavage study). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, National Toxicology Program; 1987. NTP Technical Report No. 252. NIH Publication No. 88-2508. [Accessed: February 12, 2024]. https://ntp.niehs.nih.gov/go/tr252abs
112 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis studies of d-limonene (CAS No. 5989-27-5) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, National Toxicology Program; 1990. NTP Technical Report No. 347. NIH Publication No. 90-2802. [Accessed: February 12, 2024]. https://ntp.niehs.nih.gov/go/tr347abs
113 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis studies of α,β-thujone (CAS No. 76231-76-0) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, National Toxicology Program; 2011. NTP Technical Report No. 570. NIH Publication No. 12-5912. [Accessed: February 12, 2024]. https://ntp.niehs.nih.gov/go/tr570abs
114 Johnson KR, Ellis G, Toothill C. The sulfophosphovanillin reaction for serum lipids: A reappraisal. Clin Chem. 1977; 23(9):1669–1678. 10.1093/clinchem/23.9.1669 556319
115 Li H, Handsaker B, Wysoker A, Fennell T, Ruan J, Homer N, Marth G, Abecasis G, Durbin R. 1000 Genome Project Data Processing Subgroup. The Sequence Alignment/Map format and SAMtools. Bioinformatics. 2009; 25(16):2078–2079. 10.1093/bioinformatics/btp352 19505943
116 McKenna A, Hanna M, Banks E, Sivachenko A, Cibulskis K, Kernytsky A, Garimella K, Altshuler D, Gabriel S, Daly M, et al. The Genome Analysis Toolkit: A MapReduce framework for analyzing next-generation DNA sequencing data. Genome Res. 2010; 20(9):1297–1303. 10.1101/gr.107524.110 20644199
117 Van der Auwera GA, O’Connor BD. Genomics in the cloud: Using Docker, GATK, and WDL in Terra. Sebastopol, CA: O'Reilly Media; 2020.
118 Danecek P, Bonfield JK, Liddle J, Marshall J, Ohan V, Pollard MO, Whitwham A, Keane T, McCarthy SA, Davies RM, et al. Twelve years of SAMtools and BCFtools. Gigascience. 2021; 10(2):giab008. 10.1093/gigascience/giab008 33590861
119 Gileta AF, Fitzpatrick CJ, Chitre AS, St. Pierre CL, Joyce EV, Maguire RJ, McLeod AM, Gonzales NM, Williams AE, Morrow JD, et al. Genetic characterization of outbred Sprague Dawley rats and utility for genome-wide association studies. PLoS Genet. 2022; 18(5):e1010234. 10.1371/journal.pgen.1010234 35639796
120 Sherry ST, Ward M, Sirotkin K. dbSNP-database for single nucleotide polymorphisms and other classes of minor genetic variation. Genome Res. 1999; 9(8):677–679. 10.1101/gr.9.8.677 10447503
121 Bergstrom EN, Huang MN, Mahto U, Barnes M, Stratton MR, Rozen SG, Alexandrov LB. SigProfilerMatrixGenerator: A tool for visualizing and exploring patterns of small mutational events. BMC Genomics. 2019; 20(1):685. 10.1186/s12864-019-6041-2 31470794
122 Islam SMA, Díaz-Gay M, Wu Y, Barnes M, Vangara R, Bergstrom EN, He Y, Vella M, Wang J, Teague JW, et al. Uncovering novel mutational signatures by de novo extraction with SigProfilerExtractor. Cell Genom. 2022; 2(11):100179. 10.1016/j.xgen.2022.100179 36388765