# Conclusions

Under the conditions of these 2-year inhalation studies, there was some evidence of carcinogenic activity of α-pinene in male Hsd:Sprague Dawley^®^ SD^®^ rats based on the higher incidence of urinary bladder papilloma. There was clear evidence of carcinogenic activity of α-pinene in female Hsd:Sprague Dawley^®^ SD^®^ rats based on the increased incidences of mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined). Increased incidences of stromal polyp; adenocarcinoma; squamous cell carcinoma; and squamous cell papilloma, squamous cell carcinoma, adenoma, or adenocarcinoma (combined) in the uterus were also considered to be related to exposure.

There was clear evidence of carcinogenic activity of α-pinene in male B6C3F1/N mice based on the increased incidences of Harderian gland adenoma, adenocarcinoma, and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); and alveolar/bronchiolar adenoma and adenoma or carcinoma (combined). Higher incidences of urinary bladder papilloma and forestomach papilloma were also considered to be related to exposure. There was clear evidence of carcinogenic activity of α-pinene in female B6C3F1/N mice based on the increased incidences of Harderian gland adenoma and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); alveolar/bronchiolar adenoma, carcinoma, and adenoma or carcinoma (combined); and mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined). Increased incidences of granulosa cell tumor, benign, malignant (combined) and tubulostromal adenoma in the ovary and a higher incidence of squamous cell carcinoma in the forestomach were also considered to be related to exposure.

Exposure to α-pinene resulted in increased incidences of nonneoplastic lesions in the epididymis, testis, adrenal gland, and liver of male rats; bone marrow, spleen, and uterus of female rats; epididymis, liver, lung, testis, and urinary bladder of male mice; and lung, ovary, urinary bladder, and stomach of female mice.

Under the conditions of these 3-month reproductive assessments in Hsd:Sprague Dawley^®^ SD^®^ rats and CD-1 mice, reproductive function was not affected by exposure.