# Discussion

α-Pinene is a naturally occurring monoterpene produced by some plants (e.g., pine trees, rosemary, cannabis) that is commonly used as a fragrance and flavor ingredient and has been measured at exposure levels up to 27 ppm (α-pinene) or 99 ppm (total terpenes) in certain occupational settings, such as softwood lumber processing. α-Pinene is the main constituent of turpentine, which is distilled from the resin of pine trees and used as a paint thinner^61^ and in complementary medicine as a treatment for intestinal and skin ailments.^18,93^ Turpentine was originally nominated for National Toxicology Program (NTP) evaluation by the International Union of the United Auto Workers, but after review, α-pinene was selected because of its broader exposure potential and the decreasing use of turpentine as a general solvent in favor of cheaper petroleum-based products. The α-pinene used in the current studies was comprised of 68% (+) α-pinene and 32% (−) α-pinene. This is within the range of enantiomeric percentages observed in different plant species.^15-17^ While some studies show that the (+) α-pinene enantiomer is more biologically active than the (−) α-pinene enantiomer,^94,95^ it is unclear whether this difference in activity applies for the mechanism(s) of action responsible for the observed toxicological and carcinogenic findings in the studies reported herein.

In light of the widespread exposure potential, a lack of safety data on chronic exposure to α-pinene or turpentine, and signals of potential toxicity in the urinary system (kidney of rats and urinary bladder of mice) and male reproductive system during 3-month studies,^2^ 2-year inhalation carcinogenicity studies were conducted in male and female rats and mice. An evaluation of reproductive performance following inhalation exposure of male rats and mice was included to further investigate whether decreased sperm quality observed in the 3-month studies^2^ could affect reproductive function. An inhalation route of exposure was selected because of its relevance to human occupational exposures. The range of exposure concentrations evaluated in rats (0, 50, 100, or 200 ppm in the 2-year study and 0, 100, 200, or 400 ppm in the 3-month reproductive study) and mice (0, 100, 200, and 400 ppm) was higher than those recorded in European saw mills, where α-pinene was measured at 10–27 ppm^27^ and total terpenes were measured at 18–99 ppm.^28^ The high end of measured occupational exposures overlaps with current international exposure limits, wherein the international exposure limits range from 20 ppm for α-pinene up to 100 ppm for turpentine (corresponding to 44–94 ppm α-pinene, according to the α-pinene content in turpentine).^37,96^ Toxicokinetic (TK) data indicate that for a unit dose of α-pinene exposure, systemic exposure to α-pinene in humans is expected to be higher than that in rats (16–32 fold) and mice (41–51 fold) based on their respective area under the curve (AUC).^6^ Taken together, the exposure concentrations used in the studies reported here are within the range of human occupational exposure levels recorded in the lumber industry and current occupational exposure limits.

As noted above, the urinary system was identified as a target of α-pinene toxicity in previous 3-month inhalation studies.^2^ The urinary bladder transitional epithelium hyperplasia observed in the previous 3-month studies in male and female B6C3F1/N mice^2^ was replicated in the current 3-month study in B6C3F1/N male mice, wherein similar exposure-related significant increases in the incidence of hyperplasia (now termed urothelium hyperplasia) were observed. Significant increases in the incidences of cytoplasmic vacuolation, lymphocytic cellular infiltration, and single cell death were also observed in the urinary bladders of male B6C3F1/N mice in the current study. Unlike the B6C3F1/N mice, nonneoplastic lesions in the urinary bladder of CD-1 mice and Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were sporadic and not attributable to α-pinene exposure. Additionally, the kidney lesions observed in the previous 3-month studies in male Fischer 344 (F344/N) rats (i.e., granular casts, hyaline droplet accumulation) were not observed in the current 3-month studies in male Sprague Dawley rats. Male F344 and Sprague Dawley rats have been shown to exhibit similar responses to decalin through an α2u-globulin-mediated mechanism,^97^ ruling out species differences in α2u-globulin as an explanation for the lack of response in the kidney seen in male Sprague Dawley rats in the current study.

In the 2-year studies, both male rats and mice displayed a positive trend in the incidence of urinary bladder papilloma, with an incidence of three in each of the high exposure concentration groups (200 and 400 ppm in rats and mice, respectively). Although not statistically significant, the incidence of urinary bladder papilloma exceeded the historical control rates in both rats and mice. While male rats did not exhibit accompanying nonneoplastic lesions in the urinary bladder, male B6C3F1/N mice displayed an exposure-related significant increase in the incidence of urothelium hyperplasia (considered to be a precursor to papilloma) in all exposed groups and a significant increase in the incidence of lymphocytic cellular infiltration in the 200 and 400 ppm groups and suppurative inflammation in the 400 ppm group. The urinary bladder papillomas were considered to be related to exposure in both male rats and mice but did not rise to clear evidence, as the increase was seen in only the high exposure concentration and did not reach statistical significance. Incidences of papilloma were not observed in the urinary bladder of female rats or mice, but there was an exposure-related significant increase in urothelium hyperplasia in female mice in all exposed groups. While the current studies confirm that urinary bladder is a target following α-pinene exposure, sex, strain, and species differences were noted in sensitivity and the types of nonneoplastic lesions observed at this target site. In humans, men are more likely to develop urinary bladder cancer than women, but the mechanism for the sex difference has yet to be fully elucidated.^98^

In general, female rats in the chronic study appeared to be more sensitive to α-pinene exposure than male rats, and this result is consistent with the observed higher internal concentrations in female rat blood and mammary gland compared to male rats in the 3-month investigative study and higher systemic exposure (blood maximum concentration [C_max_] and AUC) observed in female rats compared to male rats following inhalation exposure in previous TK studies with Sprague Dawley rats.^6^ Female rats exposed to α-pinene displayed a significant increase in early mortality, which was attributed to mammary gland masses or nodules. Correspondingly, there was an exposure-related significant increase in the incidences of mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined) in the 100 and 200 ppm groups that exceeded historical control rates. While the incidence of adenoma was not significantly increased at any exposure concentration, the overall pattern of neoplasms was consistent with the expected progression of carcinogenesis: increasing malignancy with increasing exposure concentration. Early deaths attributed to mammary nodules or masses, an exposure-related increased incidence of adenocarcinomas that exceeded historical control rates, evidence of malignancy progression with exposure concentration, and consistency of findings across species contributed to the determination of clear evidence of carcinogenic activity. Whole-genome sequencing of fresh frozen rat mammary tumors revealed an exposure concentration-dependent increase in mutation burden and an exposure-specific mutation signature (single base substitution 21 [SBS21] Catalogue of Somatic Mutations in Cancer [COSMIC] signature) that is enriched for T>C transitions (Appendix E). SBS21 was seen in some human breast cancers and is related to DNA mismatch repair deficiency.^99^ Further evaluation of rat mammary gland from both the 2-year study and the 3-month investigative study is underway to identify early biomarkers of mutagenesis and carcinogenesis using error-corrected duplex sequencing technology.

An exposure-related significant increase in the incidence of uterine neoplasms was also observed in female rats. Significant increases were seen in the incidences of adenocarcinoma and squamous cell carcinoma and in the combined incidence of squamous cell papilloma, squamous cell carcinoma, or adenoma or adenocarcinoma. In addition, stromal polyps in the uterus were increased in the highest exposure group. Accompanying nonneoplastic lesions in the uterus included atypical hyperplasia and stromal endometrium hyperplasia. Increased incidences of hemorrhage and thrombus observed in the sections were considered to be secondary to the presence of uterine neoplasms. The uterine neoplasms were considered to be related to exposure in female rats but did not meet the criteria for clear evidence because there was not a consistent exposure-related increase and the incidences were relatively low. There were no preneoplastic lesions observed in either the mammary gland or uterus in female rats or mice from the previous 3-month studies, suggesting these findings would not have been predicted from shorter-term studies.^2^

Mammary and uterine neoplasms are known to be sensitive to hormones in both rats and humans.^100,101^ For example, mammary neoplasms can be induced in rats by prolonged exogenous estrogen exposure. Higher prolactin plasma concentrations at diestrus, but not estrogen or progesterone levels, were found to correspond to a higher mammary tumor-induction rate following exposure of two Sprague Dawley rat stocks to the carcinogen 7,12-dimethylbenzanthracene.^102^ Contrastingly, decreased prolactin levels in rats have been associated with increased uterine neoplasms.^103^ Hormone levels were not measured in the current study; however, future analysis of the effects of α-pinene on hormone concentrations could provide insight into their potential involvement in tumor development.

Additional nonneoplastic lesions observed in female rats included significant increases in the incidences of hypercellularity in the bone marrow and increased extramedullary hematopoiesis in the spleen. Nonneoplastic lesions observed in male rats included significant increases in the incidences of focal hyperplasia in the adrenal gland medulla, bile duct hyperplasia in the liver, hypospermia in the epididymis, and degeneration and degeneration or atrophy (combined) in the germinal epithelium of the testis.

Male and female B6C3F1/N mice in the chronic study displayed a similar pattern of carcinogenic responses in the Harderian gland, liver, and lung following chronic exposure to α-pinene. Unlike rats, male and female mice did not display a sex difference in systemic α-pinene concentrations following exposure,^6^ which is reflected in the similar carcinogenic response observed in male and female mice. In male mice, there were significant increases in the incidences of Harderian gland adenoma and adenocarcinoma in the 400 ppm group and adenoma or adenocarcinoma (combined) in the 200 and 400 ppm groups. In female mice, there were significant increases in the incidences of Harderian gland adenoma and adenoma or adenocarcinoma (combined) in the 200 and 400 ppm groups. A significant increase in Harderian gland hyperplasia was limited to male mice in the 100 ppm group. While the Harderian gland is not present in humans, it is a common target for multi-site chemical carcinogens in rodent studies.^104^

The incidences of hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined) were significantly increased in male and female mice, with the combination significantly increased at all exposure concentrations and exceeding historical control rates at the lowest exposure concentration of 100 ppm. In male mice, there were also significantly increased incidences of nonneoplastic lesions in the liver, including basophilic focus, multinucleated hepatocyte, and liver necrosis. Basophilic foci are considered a precursor to hepatocellular neoplasms.

The incidences of alveolar/bronchiolar adenoma and alveolar/bronchiolar adenoma or carcinoma (combined) in the lung were also significantly increased in male and female mice. Female mice demonstrated a slightly greater response, with adenoma and adenoma or carcinoma (combined) reaching statistical significance in all exposed groups and exceeding historical control rates, including at the lowest exposure concentration. A significant increase in alveolar/bronchiolar carcinoma was also observed in female mice in the 200 and 400 ppm groups. Male mice displayed significant increases in the incidence of adenoma at 400 ppm and adenoma or carcinoma (combined) at ≥200 ppm. A significant increase in alveolar/bronchiolar epithelium hyperplasia was observed at all exposure concentrations in both male and female mice.

Exposure-related increases in the incidences of neoplasms in the Harderian gland, liver, and lung that generally exceeded historical control rates, increased incidences of related nonneoplastic lesions, and consistency of findings across sex contributed to the determination of clear evidence of carcinogenic activity in male and female mice at each of these target tissues.

Female mice had significantly increased incidences of mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined) at the high exposure concentration, which exceeded historical control rates. The consistency of mammary neoplasms across species, as well as progressing malignancy with adenoma in the middle exposure concentration and adenocarcinoma at the high exposure concentration, contributed to a finding of clear evidence of carcinogenic activity in female mice. The significant increases in the incidences of granulosa cell tumor, benign or malignant (combined) and tubulostromal adenoma in the ovary in the 400 ppm group were related to exposure, but the response was not as strong as in the Harderian gland, liver, and lung. A significantly increased incidence in tubulostromal hyperplasia in the ovary at all exposure concentrations was observed. In male mice, there was a positive trend and higher incidence of forestomach papilloma in the 200 and 400 ppm groups. Although not statistically significant, the incidence of forestomach papilloma exceeded the historical control rate. This trend was not noted in females, although there was a positive trend and higher incidence of squamous cell carcinoma and a significant increase in the incidence of hyperplasia of the forestomach epithelium in the 400 ppm group. There was a consistency across sexes in forestomach lesions that fall along a continuum from hyperplasia to papilloma to carcinoma, along with incidences that exceeded those of the historical controls. Taken together, the positive trend and higher incidences in forestomach papilloma and carcinoma were considered to be related to exposure in male and female mice, respectively, in the 2-year studies. The rodent forestomach does not have a human homolog. However, review of the literature on human and animal carcinogens suggests that chemicals that act through genotoxic mechanisms and elicit tumors at multiple sites, including the forestomach, are likely to be human carcinogens.^105^ Additional nonneoplastic lesions observed in male mice included significant increases in the incidences of degeneration and degeneration or atrophy (combined) in the germinal epithelium of the testis and exfoliated germ cells in the epididymal ducts.

In the previous 3-month study, male F344/N rats exposed to 200 or 400 ppm α-pinene exhibited a significant decrease in the number of cauda sperm (19%).^2^ In the current 3-month investigative study in Sprague Dawley rats, the numbers of cauda sperm in the 50 and 200 ppm groups were lower (by 24% and 21%, respectively) compared to the control group, but no significant trend was observed, and the differences were not significant due to greater variability in this study versus the previous study. Although the absolute left testis and epididymis weights were significantly decreased in the 50 ppm group, there were no accompanying nonneoplastic lesions. A subtle change in estrous cyclicity limited to decreased time in proestrus was observed in female rats exposed to 100 or 200 ppm α-pinene for 3 months, which by itself was not sufficient to indicate reproductive toxicity but could warrant further evaluation. In the previous NTP 3-month study in F344/N rats, an increase in overall estrous cycle length was observed in the 400 ppm group, which was thought to be secondary to overt toxicity in female rats at that exposure concentration.^2^

The constellation of mild signals of reproductive toxicity associated with α-pinene exposure included significant decreases in sperm counts in the previous studies,^2^ as well as significant decreases in absolute epididymis and testis weights in male Sprague Dawley rats, significant decreases in absolute testis weights in male B6C3F1/N mice, a positive trend in the incidences of atrophy and degeneration or atrophy (combined) in the germinal epithelium in the testis of male rats, and a negative trend in the number of implantations in female rats in the current 3-month studies. However, no effects on reproductive outcomes were noted in the number of females that paired, mated, or became pregnant. In general, the relatively minor reproductive effects occurred at higher concentrations than the neoplastic effects. Additionally, there appeared to be some differences in species and strain sensitivity, with rats and B6C3F1/N mice being more sensitive than CD-1 mice to the effects of α-pinene exposure on male reproductive tissues. While there are some epidemiological studies linking occupational exposure in painters (with potential exposure to α-pinene via turpentine use^61,106^) to decreased semen quality,^107,108^ there are no direct measures of α-pinene or turpentine exposure in those studies. The mechanism of action for reproductive effects is not known, and further work would be needed to evaluate whether genotoxicity to germ cells could explain the reproductive effects. Evaluation of effects following developmental exposure to α-pinene is warranted.

The target sites identified in the current studies, including the mammary gland in rats and mice and the Harderian gland, liver, and lung in mice only, are consistent with the common target sites for carcinogenic epoxides and epoxide precursors including acrylonitrile, benzene, 1,3-butadiene, chloroprene, glycidol, isoprene, and vinyl fluoride.^109^ Evaluation of α-pinene using standard mutagenicity assays has consistently displayed negative results in the Ames assay^2,52-54^ and the in vivo peripheral blood micronucleus test.^2^ Given the structure of α-pinene, the epoxide α-pinene oxide was identified as a potential active metabolite and was found to be present in rats and mice exposed to α-pinene.^6^ Furthermore, we conducted a comparative in vitro investigation of the metabolism of α-pinene to α-pinene oxide in rat and human microsomes and hepatocytes.^5^ α-Pinene oxide was formed by both human and rat microsomes and hepatocytes.^5^ The formation of α-pinene oxide was found to be 2- to 4-fold higher in rats than in humans, whereas clearance of α-pinene oxide was similar in rat and human hepatocytes. Finally, unlike α-pinene, α-pinene oxide was positive for mutagenicity when evaluated in the Ames assay.^5^ Investigation into the lack of mutagenicity of α-pinene despite the presence of metabolic enzymes in rat liver S9 pointed to formation of inadequate levels of the genotoxic metabolite under the conditions of the assay.^5^ The human relevance of the genotoxic mechanism of α-pinene is further supported by a recent study that showed increased micronucleus formation in people occupationally exposed to turpentine.^61^

A significant increase in neoplastic lesions was observed in multiple tissues, sexes, and species at an exposure concentration of 100 ppm α-pinene, and a significant increase in nonneoplastic lesions was observed in the rat study at the low exposure concentration of 50 ppm. According to comparisons of human and rodent TK data, human systemic exposure would be 16- to 32-fold higher than rats and 41- to 51-fold higher than mice given the same unit dose (i.e., same exposure concentration).^6^ However, in vitro studies indicate that the likely active metabolite α-pinene oxide is formed at a higher level in rats than in humans (based on AUC comparison) and is cleared at a similar rate by rat and human hepatocytes.^5^ Whole-genome sequencing of mouse hepatocellular carcinomas demonstrated an exposure-related increase in the mutational burden when compared to the corresponding tumors arising spontaneously due to aging (Appendix E). The mutation burden in mouse hepatocellular carcinomas was higher than in mouse alveolar/bronchiolar carcinomas despite the fact that inhalation was the route of exposure. These data support a mutagenic mode of carcinogenesis, wherein α-pinene is metabolized to a reactive intermediate, α-pinene oxide, in the liver that induces a higher mutation burden compared to the lung. This interpretation is consistent with the findings of Waidyanatha et al.,^5^ wherein α-pinene oxide was shown to be the mutagenic metabolite. This type of work can further the understanding of the mechanism of genotoxicity and carcinogenicity involved and help to relate findings in rodent studies to human exposure conditions.

The toxicity and carcinogenicity studies described herein provide important hazard characterization information that will aid in regulatory decision making. However, several areas that could benefit from further research should be noted. First, the studies did not include exposure concentrations low enough to determine a no-observed-adverse-effect level. Second, because of concerns with occupational exposures, the studies were designed to focus on adult-only exposures. Therefore, it is not known if developmental exposures could lead to different effects or effects at lower exposure concentrations. In addition, a complete reproductive assessment was not performed; the assessment instead focused on whether exposure to male rats and mice would impact reproductive success. While an opportunistic evaluation of α-pinene and α-pinene oxide levels was conducted in blood and mammary glands from the 2-year study, the collection and analysis methods were not validated, and mammary gland samples were limited to one female rat in the highest exposure group. Therefore, internal concentration data from the 2-year studies should be viewed with caution. However, this was partially mitigated by collecting internal concentration data from the 3-month investigative study. Preliminary data from an analysis of mutation signatures in select tissues were also provided (Appendix E), but additional work is needed to evaluate the sensitivity of the analysis and account for possible artifacts. Finally, several of the intended endpoints (e.g., mammary whole mount, sperm evaluation from the reproductive studies) could not be evaluated or reported because of sample preparation issues.

Monoterpenes such as α-pinene are composed of two isoprene units. Structural similarity among monoterpenes has motivated read across efforts to fill in data gaps, as in the evaluation of aliphatic and aromatic monoterpene hydrocarbons for generally recognized as safe (GRAS) status by an expert panel of the Flavor and Extract Manufacturer’s Association.^20^ The expert panel reaffirmed the GRAS status of the substances, including α-pinene, β-pinene, camphene, d-limonene, and β-myrcene, among others, based on wide margins of safety between doses eliciting toxicity and human exposure levels and a lack of genotoxic and mutagenic potential.^20^ NTP studies have evaluated other monoterpenes for chronic toxicity and carcinogenicity, including citral,^110^ geranyl acetate,^111^ d-limonene,^112^ β-myrcene,^55^ and α,β-thujone.^113^ This group of structurally related compounds does not appear to share similar effect patterns. Key findings from chronic d-limonene exposure via gavage in F344/N rats and B6C3F1 mice were limited to α2μ-globulin-mediated nephropathy accompanied by tubular cell adenoma and carcinoma in the kidneys of male rats, with no neoplastic effects observed in female rats or male and female mice.^112^ Contrastingly, α,β-thujone exposure via gavage elicited seizures in F344/N rats and B6C3F1 mice at the high dose (50 mg/kg/day for rats and 25 mg/kg/day for mice) and was carcinogenic to male rats, as evidenced by neoplasms in the preputial gland. Robust findings of carcinogenicity in both sexes and species evaluated in the current α-pinene studies, along with the in vitro mutagenicity studies with α-pinene oxide, warrant re-evaluation of existing assumptions about the safety for this class of compounds.