# Results

## Data Availability

All study data were evaluated. Data relevant for evaluating toxicological findings are presented here. All study data are available in the National Toxicology Program (NTP) Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-606.^92^

## Rats

### Three-month Reproductive Study

All male rats survived to the end of the study. There were no exposure-related clinical observations, nor were there significant effects on body weight attributed to α-pinene exposure in male rats. A subset of 10 male rats was selected for histopathological evaluation of the kidney and urinary bladder. There were no exposure-related histopathological findings in the examined tissues (Appendix G).

### Two-year Study

Estimates of the 2-year survival probabilities for male and female rats are shown in Table 2 and in the Kaplan-Meier survival curves (Figure 2). Chronic exposure to α-pinene did not significantly affect the survival of male rats. However, survival of female rats was significantly decreased compared to the control group in all exposed groups. The decrease in survival was evident at approximately week 40 of exposure across all exposed groups. The most frequently noted cause of early death for female rats was mammary gland mass(es) or nodule(s) (Appendix G).

Table 2 Summary of Survival of Male and Female Rats in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 50 ppm | 100 ppm | 200 ppm
Male
Animals Initially in Study | 50 | 50 | 50 | 50
Euthanized Moribund | 10 | 13 | 11 | 15
Found Dead | 18 | 18 | 18 | 21
Animals Surviving to Study Termination | 22 | 19 | 21 | 14
Percent Probability of Survival at Study Termination^a^ | 44.0 | 38.0 | 42.0 | 28.0
Survival (Days)^b^ | 659.9 ± 16.0 | 663.5 ± 12.4 | 670.1 ± 10.5 | 630.7 ± 18.1
Survival Analysis^c^ | p = 0.111 | p = 0.982 | p = 0.982 | p = 0.350
Female
Animals Initially in Study | 50 | 50 | 50 | 50
Moribund | 15 | 16 | 22 | 28
Found Dead | 8 | 19 | 15 | 17
Animals Surviving to Study Termination | 27 | 15 | 13 | 5
Percent Probability of Survival at Study Termination | 56.0^d^ | 30.0 | 26.0 | 10.0
Survival (Days) | 668.3 ± 13.2 | 621.7 ± 16.9 | 589.8 ± 18.1 | 495.1 ± 21.4
Survival Analysis | p < 0.001 | p = 0.015 | p = 0.002 | p < 0.001

^a^ Kaplan-Meier determinations at study day 730 (male rats) or 731 (female rats), the first day of terminal euthanasia.

^b^ Mean of all deaths (uncensored, censored, and study termination) ± standard error.

^c^ The result of the Tarone trend test is in the 0 ppm chamber group column, and the results of the Cox log-rank pairwise comparisons with Hommel adjustment to the 0 ppm chamber group are in the exposed group columns.

^d^ Probability of survival accounts for one animal that was moribund or found dead on or after the first day of terminal euthanasia.

Figure 2

Kaplan-Meier Survival Curves for Male and Female Rats in the Two-year Inhalation Study of α-Pinene

Survival curves are shown for (A) males and (B) females.

Negative trends in body weights were observed in male and female rats, with decreases (≤10%) reaching statistical significance noted inconsistently throughout the study period in the 100 and 200 ppm groups compared to the control group (Table 3, Table 4; Figure 3). The body weights of the 200 ppm female rats were generally within 10% of the control group until study termination, at which point the body weights were within 12% of the control group and were not significant.

Table 3 Summary of Survival and Body Weights of Male Rats in the Two-year Inhalation Study of α-Pinene

Study Day^a^ | 0 ppm | | 50 ppm | | | 100 ppm | | | 200 ppm
Study Day^a^ | Wt. (g)^b,c^ | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 133.6 ± 2.3 | 50 | 134.8 ± 1.6 | 100.9 | 50 | 133.9 ± 2.2 | 100.2 | 50 | 135.9 ± 2.3 | 101.7 | 50
8 | 178.4 ± 2.5 | 50 | 177.5 ± 1.9 | 99.5 | 50 | 177.0 ± 2.5 | 99.2 | 50 | 176.7 ± 2.6 | 99.0 | 50
15 | 222.1 ± 2.8 | 50 | 221.0 ± 2.3 | 99.5 | 50 | 222.8 ± 2.8 | 100.3 | 50 | 221.2 ± 2.7 | 99.6 | 50
22 | 263.3 ± 3.0* | 50 | 261.0 ± 2.5 | 99.1 | 50 | 260.1 ± 3.1 | 98.8 | 50 | 255.7 ± 2.7 | 97.1 | 50
29 | 290.0 ± 3.4* | 50 | 285.1 ± 2.9 | 98.3 | 50 | 284.2 ± 3.5 | 98.0 | 50 | 278.8 ± 2.7* | 96.1 | 50
36 | 307.4 ± 3.7* | 50 | 302.6 ± 2.9 | 98.5 | 50 | 293.9 ± 3.5* | 95.6 | 50 | 299.2 ± 2.8 | 97.3 | 50
43 | 315.2 ± 4.0 | 50 | 321.1 ± 3.3 | 101.9 | 50 | 318.1 ± 4.0 | 100.9 | 50 | 315.2 ± 3.0 | 100.0 | 50
50 | 339.1 ± 4.2 | 50 | 336.8 ± 3.4 | 99.3 | 50 | 334.6 ± 4.3 | 98.7 | 50 | 329.8 ± 3.1 | 97.2 | 50
57 | 353.0 ± 4.4* | 50 | 349.3 ± 3.6 | 99.0 | 50 | 348.0 ± 4.6 | 98.6 | 50 | 340.3 ± 3.3 | 96.4 | 50
64 | 363.4 ± 4.6 | 50 | 358.5 ± 3.6 | 98.7 | 50 | 354.9 ± 4.7 | 97.7 | 50 | 353.1 ± 3.4 | 97.2 | 50
71 | 374.8 ± 4.6** | 50 | 369.1 ± 3.9 | 98.5 | 50 | 368.6 ± 4.8 | 98.4 | 50 | 353.7 ± 3.4** | 94.4 | 50
78 | 368.0 ± 5.0 | 50 | 373.5 ± 3.9 | 101.5 | 50 | 356.8 ± 5.1 | 96.9 | 50 | 366.5 ± 3.6 | 99.6 | 50
85 | 390.8 ± 5.0 | 50 | 387.6 ± 4.1 | 99.2 | 50 | 381.7 ± 5.0 | 97.6 | 50 | 375.4 ± 3.7* | 96.1 | 50
113 | 416.5 ± 5.5 | 50 | 410.7 ± 4.2 | 98.6 | 50 | 409.8 ± 5.3 | 98.4 | 50 | 399.8 ± 4.0* | 96.0 | 50
141 | 426.0 ± 6.2 | 50 | 427.5 ± 4.9 | 100.3 | 50 | 427.6 ± 5.7 | 100.4 | 50 | 417.3 ± 4.3 | 97.9 | 50
169 | 452.7 ± 6.4 | 49 | 442.0 ± 5.9 | 97.6 | 50 | 437.2 ± 5.6 | 96.6 | 50 | 432.5 ± 4.3* | 95.5 | 50
197 | 456.1 ± 6.4 | 49 | 450.2 ± 6.1 | 98.7 | 50 | 452.0 ± 6.1 | 99.1 | 50 | 441.7 ± 4.7 | 96.8 | 50
225 | 479.2 ± 6.7 | 49 | 470.2 ± 6.4 | 98.1 | 50 | 469.8 ± 6.2 | 98.0 | 50 | 466.4 ± 5.1 | 97.3 | 50
253 | 491.2 ± 6.8 | 49 | 482.1 ± 6.2 | 98.1 | 50 | 480.6 ± 6.7 | 97.8 | 50 | 477.4 ± 5.2 | 97.2 | 49
281 | 502.9 ± 7.1* | 49 | 495.6 ± 6.4 | 98.5 | 50 | 489.6 ± 6.6 | 97.4 | 50 | 481.9 ± 5.5 | 95.8 | 49
309 | 516.4 ± 7.3* | 49 | 509.8 ± 6.4 | 98.7 | 50 | 501.7 ± 6.8 | 97.2 | 50 | 495.5 ± 5.8 | 95.9 | 49
337 | 526.9 ± 7.5** | 48 | 522.1 ± 6.7 | 99.1 | 50 | 511.5 ± 7.1 | 97.1 | 50 | 498.8 ± 6.1** | 94.7 | 47
365 | 530.5 ± 7.5* | 48 | 525.0 ± 7.1 | 99.0 | 50 | 512.8 ± 7.3 | 96.7 | 50 | 508.2 ± 6.3 | 95.8 | 46
393 | 543.6 ± 7.7** | 48 | 538.2 ± 6.8 | 99.0 | 49 | 526.0 ± 7.3 | 96.8 | 50 | 516.1 ± 6.5** | 94.9 | 46
421 | 552.6 ± 9.0** | 48 | 550.7 ± 6.7 | 99.7 | 49 | 535.0 ± 7.7 | 96.8 | 50 | 520.5 ± 6.9** | 94.2 | 44
449 | 555.4 ± 8.5** | 48 | 560.0 ± 5.9 | 100.8 | 47 | 538.6 ± 7.7 | 97.0 | 49 | 526.4 ± 6.6** | 94.8 | 44
479 | 557.2 ± 8.0** | 47 | 559.5 ± 6.8 | 100.4 | 47 | 545.8 ± 7.5 | 98.0 | 48 | 528.8 ± 7.0** | 94.9 | 44
505 | 559.9 ± 8.0** | 47 | 569.4 ± 6.1 | 101.7 | 46 | 546.5 ± 7.5 | 97.6 | 48 | 532.1 ± 7.5* | 95.0 | 42
533 | 566.4 ± 8.7** | 45 | 575.2 ± 6.8 | 101.6 | 46 | 549.3 ± 7.9 | 97.0 | 47 | 534.2 ± 9.1** | 94.3 | 40
561 | 563.6 ± 8.3** | 45 | 581.8 ± 7.0 | 103.2 | 44 | 548.1 ± 8.2 | 97.2 | 45 | 540.5 ± 8.0 | 95.9 | 39
589 | 555.6 ± 8.5* | 42 | 578.8 ± 9.0 | 104.2 | 42 | 545.5 ± 7.3 | 98.2 | 44 | 537.5 ± 8.3 | 96.7 | 39
617 | 543.6 ± 11.3* | 37 | 578.1 ± 8.1* | 106.3 | 38 | 537.6 ± 8.8 | 98.9 | 40 | 535.0 ± 9.3 | 98.4 | 36
645 | 555.3 ± 10.1** | 33 | 576.6 ± 8.2 | 103.8 | 36 | 527.2 ± 11.3 | 94.9 | 35 | 518.7 ± 11.5* | 93.4 | 33
673 | 544.9 ± 12.9* | 32 | 567.0 ± 9.1 | 104.1 | 30 | 528.4 ± 11.1 | 97.0 | 28 | 511.5 ± 13.3 | 93.9 | 27
701 | 555.7 ± 12.8** | 28 | 553.1 ± 11.0 | 99.5 | 24 | 533.6 ± 10.5 | 96.0 | 25 | 499.8 ± 17.3** | 90.0 | 18

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Study day 1 is the day animals were placed on study.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Weights shown are mean ± standard error.

Table 4 Summary of Survival and Body Weights of Female Rats in the Two-year Inhalation Study of α-Pinene

Study Day^a^ | 0 ppm | | 50 ppm | | | 100 ppm | | | 200 ppm
Study Day^a^ | Wt (g)^b,c^ | No. of Survivors | Wt (g) | Wt (% of Controls) | No. of Survivors | Wt (g) | Wt (% of Controls) | No. of Survivors | Wt (g) | Wt (% of Controls) | No. of Survivors
1 | 120.5 ± 1.3 | 50 | 121.8 ± 1.1 | 101.1 | 50 | 122.1 ± 1.1 | 101.3 | 50 | 120.5 ± 1.1 | 100.0 | 50
8 | 144.9 ± 1.4 | 50 | 145.6 ± 1.3 | 100.5 | 50 | 146.1 ± 1.3 | 100.8 | 50 | 143.3 ± 1.2 | 98.9 | 50
15 | 166.1 ± 1.5 | 50 | 164.2 ± 1.7 | 98.8 | 50 | 165.5 ± 1.4 | 99.6 | 50 | 162.7 ± 1.5 | 97.9 | 49
22 | 183.3 ± 1.7* | 50 | 181.1 ± 1.8 | 98.8 | 50 | 182.0 ± 1.7 | 99.3 | 50 | 177.7 ± 1.8 | 97.0 | 49
29 | 194.9 ± 1.8* | 50 | 191.3 ± 2.0 | 98.2 | 50 | 192.3 ± 2.0 | 98.7 | 50 | 188.5 ± 2.1 | 96.7 | 49
36 | 204.8 ± 2.0 | 50 | 203.4 ± 2.2 | 99.3 | 50 | 204.0 ± 2.1 | 99.6 | 50 | 199.8 ± 2.2 | 97.5 | 49
43 | 210.7 ± 2.0 | 50 | 206.8 ± 2.4 | 98.2 | 50 | 207.6 ± 2.1 | 98.5 | 50 | 206.7 ± 2.3 | 98.1 | 49
50 | 219.2 ± 2.0 | 50 | 219.7 ± 2.5 | 100.2 | 50 | 218.7 ± 2.2 | 99.8 | 50 | 214.5 ± 2.5 | 97.9 | 49
57 | 224.5 ± 2.2 | 50 | 224.9 ± 2.6 | 100.2 | 50 | 225.5 ± 2.1 | 100.4 | 50 | 218.5 ± 2.6 | 97.3 | 49
64 | 230.7 ± 2.1 | 50 | 229.5 ± 2.6 | 99.5 | 50 | 229.0 ± 2.2 | 99.3 | 50 | 225.4 ± 2.6 | 97.7 | 49
71 | 236.2 ± 2.2** | 50 | 233.6 ± 2.6 | 98.9 | 50 | 234.6 ± 2.2 | 99.3 | 50 | 225.1 ± 2.6** | 95.3 | 49
78 | 239.2 ± 2.1** | 50 | 235.8 ± 2.6 | 98.6 | 50 | 232.9 ± 2.4 | 97.4 | 50 | 228.3 ± 2.7** | 95.4 | 49
85 | 244.2 ± 2.3** | 50 | 242.3 ± 2.6 | 99.2 | 50 | 241.3 ± 2.2 | 98.8 | 50 | 234.7 ± 2.9** | 96.1 | 49
113 | 256.1 ± 2.3** | 50 | 254.9 ± 2.9 | 99.5 | 50 | 253.1 ± 2.4 | 98.8 | 50 | 246.0 ± 2.8** | 96.0 | 49
141 | 267.9 ± 2.6** | 50 | 261.5 ± 3.0 | 97.6 | 50 | 259.8 ± 2.7 | 97.0 | 50 | 251.9 ± 3.4** | 94.0 | 49
169 | 272.8 ± 2.7** | 50 | 270.3 ± 3.1 | 99.1 | 50 | 265.7 ± 3.0 | 97.4 | 50 | 260.2 ± 3.2** | 95.4 | 49
197 | 274.8 ± 3.0** | 50 | 270.3 ± 3.1 | 98.4 | 50 | 271.4 ± 2.7 | 98.7 | 50 | 261.8 ± 3.3** | 95.3 | 49
225 | 285.8 ± 3.1** | 50 | 281.0 ± 3.1 | 98.3 | 49 | 277.6 ± 2.6 | 97.1 | 50 | 270.5 ± 3.6** | 94.6 | 49
253 | 290.2 ± 3.5** | 50 | 281.4 ± 3.0 | 97.0 | 49 | 281.1 ± 2.8 | 96.9 | 50 | 267.3 ± 3.4** | 92.1 | 48
281 | 285.6 ± 3.8* | 50 | 286.7 ± 3.3 | 100.4 | 49 | 282.9 ± 3.0 | 99.1 | 49 | 274.5 ± 4.0 | 96.1 | 46
309 | 299.9 ± 3.8** | 50 | 293.3 ± 3.4 | 97.8 | 49 | 289.1 ± 3.2* | 96.4 | 48 | 277.2 ± 4.0** | 92.4 | 46
337 | 304.2 ± 4.0** | 50 | 297.7 ± 3.6 | 97.8 | 49 | 290.8 ± 3.4* | 95.6 | 48 | 278.7 ± 3.8** | 91.6 | 45
365 | 307.6 ± 4.2** | 50 | 300.5 ± 3.9 | 97.7 | 49 | 293.9 ± 4.2* | 95.5 | 48 | 281.2 ± 4.5** | 91.4 | 41
393 | 316.0 ± 4.5** | 50 | 308.7 ± 4.3 | 97.7 | 47 | 301.6 ± 5.4* | 95.4 | 46 | 288.2 ± 4.8** | 91.2 | 37
421 | 320.8 ± 4.7** | 50 | 312.5 ± 4.5 | 97.4 | 47 | 308.2 ± 6.0 | 96.1 | 45 | 294.6 ± 5.6** | 91.8 | 36
449 | 324.0 ± 4.9** | 47 | 319.0 ± 4.7 | 98.5 | 45 | 308.4 ± 4.5* | 95.2 | 42 | 302.7 ± 7.4** | 93.4 | 33
479 | 330.3 ± 5.1** | 47 | 322.3 ± 5.7 | 97.6 | 45 | 314.2 ± 5.1 | 95.1 | 40 | 313.5 ± 9.6 | 94.9 | 28
505 | 334.0 ± 5.6** | 46 | 333.0 ± 8.8 | 99.7 | 43 | 321.6 ± 6.4 | 96.3 | 37 | 312.9 ± 9.1 | 93.7 | 22
533 | 340.2 ± 6.3 | 43 | 338.0 ± 11.1 | 99.4 | 38 | 339.7 ± 9.8 | 99.9 | 33 | 330.0 ± 12.5 | 97.0 | 18
561 | 341.7 ± 7.6 | 43 | 339.7 ± 5.2 | 99.4 | 33 | 352.1 ± 12.6 | 103.0 | 30 | 348.7 ± 16.9 | 102.0 | 18
589 | 345.7 ± 6.7 | 41 | 341.0 ± 6.3 | 98.6 | 31 | 351.8 ± 12.8 | 101.8 | 26 | 357.1 ± 23.0 | 103.3 | 16
617 | 342.9 ± 6.4 | 39 | 348.2 ± 6.5 | 101.5 | 30 | 349.0 ± 15.1 | 101.8 | 22 | 321.8 ± 15.3 | 93.8 | 11
645 | 344.6 ± 8.1 | 36 | 349.5 ± 10.9 | 101.4 | 26 | 342.4 ± 15.8 | 99.4 | 21 | 345.6 ± 28.5 | 100.3 | 9
673 | 349.7 ± 11.1 | 34 | 367.8 ± 17.2 | 105.2 | 25 | 347.1 ± 20.4 | 99.2 | 17 | 362.3 ± 49.7 | 103.6 | 7
701 | 350.6 ± 12.0 | 28 | 358.2 ± 17.9 | 102.2 | 19 | 368.7 ± 30.0 | 105.2 | 16 | 309.5 ± 20.9 | 88.3 | 5

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Study day 1 is the day animals were placed on study.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Weights shown are mean ± standard error.

Figure 3

Growth Curves for Male and Female Rats in the Two-year Inhalation Study of α-Pinene

Growth curves are shown for (A) males and (B) females.

In male rats, the clinical observations noted during the 2-year study were mostly sporadic and not exposure related, with the possible exception of a finding of thinness in 4, 7, 8, and 8 male rats in the 0, 50, 100, and 200 ppm groups, respectively. In female rats, clinical observations included brown and red vaginal discharge in 0, 2, 3, and 4 rats and 2, 12, 10, and 13 rats, respectively, and animals noted as pale in 3, 5, 11, and 15 rats in the 0, 50, 100, and 200 ppm groups, respectively (Appendix G).

#### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidence of neoplasms and/or nonneoplastic lesions of the mammary gland, uterus, urinary bladder, testis, epididymis, adrenal gland, bone marrow, liver, and spleen.

Mammary gland: In female rats, there was a positive trend and an exposure-related significant increase in the incidence of adenocarcinoma in the 100 and 200 ppm groups (Table 5). The incidence was outside the historical control range for all routes of exposure. The incidence of adenoma or adenocarcinoma (combined) was also significantly increased in the 100 and 200 ppm groups with a positive trend.

Table 5 Incidences of Neoplastic and Nonneoplastic Lesions of the Mammary Gland in Female Rats in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 50 ppm | 100 ppm | 200 ppm
n^a^ | 49 | 50 | 50 | 50
Duct, Hyperplasia^b^ | 0 | 0 | 2 (3.0)^c^ | 0
Adenoma^d^
Overall rate^e^ | 1/49 (2%) | 0/50 (0%) | 5/50 (10%) | 0/50 (0%)
Adjusted rate^f^ | 2.55% | 0% | 15.49% | 0%
Terminal rate^g^ | 1/26 (4%) | 0/15 (0%) | 1/13 (8%) | 0/5 (0%)
First incidence (days) | 731 (T) | –^h^ | 382 | –
Poly-3 test^i^ | p = 0.217 | p = 0.973 | p = 0.061 | p = 0.943
Adenocarcinoma^j^
Overall rate | 5/49 (10%) | 7/50 (14%) | 11/50 (22%) | 25/50 (50%)
Adjusted rate | 12.29% | 19.07% | 31.28% | 69.49%
Terminal rate | 1/26 (4%) | 1/15 (7%) | 3/13 (23%) | 2/5 (40%)
First incidence (days) | 512 | 449 | 264 | 250
Poly-3 test | p < 0.001 | p = 0.305 | p = 0.038 | p < 0.001
Adenoma or Adenocarcinoma (Combined)^k^
Overall rate | 6/49 (12%) | 7/50 (14%) | 15/50 (30%) | 25/50 (50%)
Adjusted rate | 14.75% | 19.07% | 40.46% | 69.49%
Terminal rate | 2/26 (8%) | 1/15 (7%) | 4/13 (31%) | 2/5 (40%)
First incidence (days) | 512 | 449 | 264 | 250
Poly-3 test | p < 0.001 | p = 0.419 | p = 0.008 | p < 0.001

(T) = terminal euthanasia.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion. For nonneoplastic lesions, each exposed group was compared to the 0 ppm chamber group using the Poly-3 test. No statistically significant findings were noted at p ≤ 0.05.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for 2-year inhalation studies (mean ± standard deviation): 7/150 (4.67% ± 3.06%); range: 2% to 8%; all routes: 22/590 (3.35% ± 3.02%); range: 0% to 9%.

^e^ Number of animals with neoplasm/number of animals necropsied.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at study termination.

^h^ Not applicable; no neoplasms in group.

^i^ Beneath the 0 ppm chamber group incidence is the p value associated with the trend test. Beneath the exposed group incidence is the p value corresponding to pairwise comparisons between the 0 ppm chamber group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. All trend and pairwise p values are reported as one-sided.

^j^ Historical control incidence for 2-year inhalation studies: 14/150 (9.33% ± 1.15%); range: 8% to 10%; all routes: 42/590 (6.83% ± 4.59%); range: 2% to 16%.

^k^ Historical control incidence for 2-year inhalation studies: 21/150 (14% ± 3.46%); range: 12% to 18%; all routes: 62/590 (9.98% ± 5.7%); range: 2% to 18%.

Figure 4A and Figure 4B illustrate the histologic architecture of normal mammary gland in control female rats. In comparison, mammary gland adenomas occurred as variably-sized, nodular, expansive masses that were well demarcated from the surrounding normal mammary parenchyma and distorted the underlying architecture (Figure 4C). They were composed of variably dilated, single and multiloculated, cystic, glandular-like spaces that were empty or contained variable amounts of flocculent to vacuolated, variably eosinophilic secretory material. The glandular spaces were usually lined by well-differentiated, cuboidal, and often vacuolated epithelial cells but often had focal to expanded areas of disorganized, proliferative epithelium extending from the basement membrane (Figure 4D). In some adenomas, this proliferative epithelium formed solid, expansive sheets with the cells arranged as papillary or tight alveolar to tubular-like structures. In these areas, the cells were uniform with minimal atypia. Mammary gland adenocarcinomas were irregularly nodular to expansive, frequently invasive masses that completely effaced the underlying architecture (Figure 4E). They were composed of densely crowded and/or stratified epithelial cuboidal to columnar cells that formed solid sheets, large and small acinar structures, ribbons, tubules, atypical anastomosing duct-like structures (partially lined by atypical hyperplastic epithelial cells), papillary structures, and tubulopapillary structures within a delicate background of well-vascularized fibrous stroma, with variably sized areas of necrosis, inflammation, and/or dissecting hemorrhage (Figure 4F). Constituent neoplastic epithelial cells exhibited round to oval nuclei with coarsely clumped heterochromatin, one to two prominent nucleoli, pale basophilic vacuolated cytoplasm, with variable nuclear-to-cytoplasmic ratios.

Figure 4

Representative Images of Control Mammary Gland and Adenoma and Adenocarcinoma in the Mammary Gland in Female Rats in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Normal mammary gland from a control female rat composed of clusters of glands or alveoli (arrows) and adipose (fat) cells (asterisks) (4×). (B) A higher magnification of the tissue in panel A. (C) Mammary gland adenoma (arrows) observed in a 100 ppm female rat occurred as a nodular mass composed mostly of dilated cystic glandular-like spaces with focal areas of a proliferative adenomatous-like epithelium (1×). (D) A higher magnification of the neoplasm in panel C showing focal areas of proliferative epithelium (arrows) within a dilated glandular-like space (20×). (E) Mammary gland adenocarcinomas were composed of neoplastic epithelial cells that formed variably sized acinar structures that effaced the normal glandular architecture, as observed in a 200 ppm female rat. Areas of necrosis (black asterisk) and hemorrhage (black arrow) were often present (2×). (F) A higher magnification of the neoplasm in panel E. Neoplastic cells were densely crowded and/or stratified epithelial cuboidal to columnar cells forming variably sized acini (white arrows) within a delicate background of well-vascularized fibrous stroma. Some acini were dilated and contained cellular debris and secretory material (white asterisk) (10×). H&E = hematoxylin and eosin stain.

Uterus: In female rats, the incidences of adenocarcinoma and squamous cell papilloma, squamous cell carcinoma, adenoma, or adenocarcinoma (combined) were significantly increased in the 50 and 200 ppm groups, whereas the incidence of squamous cell carcinoma was significantly increased in the 200 ppm group (Table 6). Both squamous cell papilloma, squamous cell carcinoma, adenoma, or adenocarcinoma (combined) and squamous cell carcinoma exhibited a positive trend.

Table 6 Incidences of Neoplastic and Nonneoplastic Lesions of the Uterus in Female Rats in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 50 ppm | 100 ppm | 200 ppm
n^a^ | 50 | 49 | 50 | 49
Hyperplasia, Atypical^b^ | 0** | 0 | 0 | 3* (3.0)^c^
Endometrium: Hyperplasia, Stromal | 0** | 6** (2.3) | 3 (2.7) | 6** (2.2)
Hemorrhage | 3** (3.7) | 7 (2.4) | 11** (3.4) | 11** (3.2)
Thrombus | 0** | 4* | 2 | 6**
Adenocarcinoma^d^
Overall rate^e^ | 1/50 (2%) | 7/49 (14%) | 3/50 (6%) | 4/49 (8%)
Adjusted rate^f^ | 2.48% | 19.62% | 9.98% | 19.7%
Terminal rate^g^ | 1/27 (4%) | 2/14 (14%) | 2/13 (13%) | 1/5 (20%)
First incidence (days) | 731 (T) | 442 | 648 | 606
Poly-3 test^h^ | p = 0.061 | p = 0.018 | p = 0.209 | p = 0.048
Squamous Cell Carcinoma^i^
Overall rate | 0/50 (0%) | 0/49 (0%) | 1/50 (2%) | 3/49 (6%)
Adjusted rate | 0% | 0% | 3.36% | 14.51%
Terminal rate | 0/27 (0%) | 0/14 (0%) | 1/13 (8%) | 0/5 (0%)
First incidence (days) | –^j^ | – | 731 (T) | 460
Poly-3 test | p = 0.008 | (e) | p = 0.441 | p = 0.043
Squamous Cell Papilloma, Squamous Cell Carcinoma, or Adenoma or Adenocarcinoma (Combined)^k^
Overall rate | 1/50 (2%) | 7/49 (14%) | 4/50 (8%) | 6/49 (12%)
Adjusted rate | 2.48% | 19.62% | 13.31% | 28.11%
Terminal rate | 1/27 (4%) | 2/14 (14%) | 3/13 (23%) | 1/5 (20%)
First incidence (days) | 731 (T) | 442 | 648 | 460
Poly-3 test | p = 0.010 | p = 0.018 | p = 0.103 | p = 0.007
Polyp, Stromal^l^
Overall rate | 5/50 (10%) | 2/49 (4%) | 4/50 (8%) | 8/49 (16%)
Adjusted rate | 12.14% | 6.06% | 12.73% | 34.94%
Terminal rate | 3/27 (11%) | 1/14 (7%) | 1/13 (8%) | 3/5 (60%)
First incidence (days) | 484 | 698 | 532 | 318
Poly-3 test | p = 0.022 | p = 0.899 | p = 0.610 | p = 0.038

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

(T) = terminal euthanasia; (e) = value of statistic could not be computed.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion. For nonneoplastic lesions, each exposed group was compared to the 0 ppm chamber group using the Poly-3 test.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for 2-year inhalation studies (mean ± standard deviation): 2/150 (1.33% ± 1.15%); range: 0% to 2%; all routes: 22/499 (4.42% ± 2.84%); range: 0% to 10%.

^e^ Number of animals with neoplasm/number of animals necropsied.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at study termination.

^h^ Beneath the 0 ppm chamber group incidence is the p value associated with the trend test. Beneath the exposed group incidence is the p value corresponding to pairwise comparisons between the 0 ppm chamber group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. All trend and pairwise p values are reported as one-sided.

^i^ Historical control incidence for 2-year inhalation studies: 1/150 (0.67% ± 1.15%); range: 0% to 2%; all routes: 6/499 (1.21% ± 1.7%); range: 0% to 4%.

^j^ Not applicable; no neoplasms in group.

^k^ Historical control incidence for 2-year inhalation studies: 3/150 (2% ± 2%); range: 0% to 4%; all routes: 31/499 (6.23% ± 4.11%); range: 0% to 14%.

^l^ Historical control incidence for 2-year inhalation studies: 13/150 (8.67% ± 6.11%); range: 2% to 14%; all routes: 51/499 (10.22% ± 4.93%); range: 2% to 18%.

Adenocarcinomas of the uterus were characterized by lobular masses that effaced the glandular endometrial epithelium and protruded into the uterine lumen (Figure 5A) and/or effaced the uterus. They were composed of haphazardly arranged tubules and anastomosing cords lined by neoplastic cuboidal to columnar epithelial cells (Figure 5B). Occasionally, masses comprised solid areas composed of sheets or packets of polygonal cells (carcinomas). Variation in the size and shape (pleomorphism) of neoplastic cells was moderate to marked. Mitoses were frequent. There were often areas of hemorrhage and necrosis.

Figure 5

Representative Images of Adenocarcinoma in the Uterus in a Female Rat in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Uterine adenocarcinoma was composed of a mass of neoplastic tubules (black arrow) that bulged into the uterine lumen of a 50 ppm female rat (1×). (B) A higher magnification of the neoplasm in panel A. Neoplastic tubules in the uterus were lined by crowded tall columnar epithelial cells (black arrow) (20×). H&E = hematoxylin and eosin stain.

Squamous cell carcinomas of the uterus were characterized by replacement of the glandular endometrial epithelium by variably thick layers of keratinized stratified squamous epithelium (Figure 6A, Figure 6B). There was often abundant keratin within the uterine lumen associated with the neoplastic epithelium (Figure 6A, Figure 6B). Neutrophilic inflammation was associated with the mass of keratin. Variation in the size and shape (pleomorphism) of neoplastic cells was mild. Mitoses were few.

Figure 6

Representative Images of Squamous Cell Carcinoma in the Uterus in a Female Rat in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Uterine squamous cell carcinoma was characterized by replacement of the endometrium with neoplastic keratinizing stratified squamous epithelium (black arrows) of a 100 ppm female rat. Keratin is indicated by a black asterisk (1×). (B) A higher magnification of the neoplasm in panel A. The neoplastic stratified squamous epithelium (black arrow) has replaced the glandular endometrial epithelium with a layer of keratin (black asterisk) (18×). H&E = hematoxylin and eosin stain.

There was a positive trend in the incidence of stromal uterine polyps, and the increase was significant in the 200 ppm group. Stromal polyps of the uterus were characterized by noninvasive polypoid masses that extended into the uterine lumen (Figure 7A). The predominant bulk of the polyps was composed of stromal spindle-shaped or stellate cells with few embedded endometrial glands (Figure 7B). The polyps were covered by cuboidal to columnar epithelium, which was continuous with the endometrial lining epithelium.

Figure 7

Representative Images of Stromal Polyp of the Uterus in a Female Rat in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Uterine stromal polyp was composed of polypoid masses that extended into the uterine lumen (black arrows) of a 50 ppm female rat. The stromal polyp was not invasive (1×). (B) A higher magnification of the neoplasm in panel A. The bulk of the stromal polyp was composed of spindle or stellate cells (yellow asterisk) with embedded endometrial glands (black arrow). The polyp was lined by cuboidal to columnar epithelium (green arrow) continuous with the endometrial lining (10×). H&E = hematoxylin and eosin stain.

There was a positive trend in the incidence of atypical hyperplasia with a significant increase in the 200 ppm group. The incidence of stromal endometrium hyperplasia was significantly increased in the 50 and 200 ppm groups with a positive trend.

Additional nonneoplastic lesions observed in the uterus included hemorrhage and thrombus wherein a positive trend was observed for each endpoint. A significant increase was observed in the incidence of hemorrhage in the 100 and 200 ppm groups and in the incidence of thrombus in the 50 and 200 ppm groups.

Urinary bladder: In male rats, there was a positive trend, and the incidence of papilloma was higher in the 200 ppm group relative to the control group (Table 7). Although not statistically significant, the incidence was greater than the historical control range for all routes of exposure. Papillomas in the urinary bladder were composed of exophytic, pedunculated masses lined by uniform urothelial cells and supported by fibrovascular stroma that projected into the lumen of the urinary bladder.

Table 7 Incidences of Neoplasms of the Urinary Bladder in Male Rats in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 50 ppm | 100 ppm | 200 ppm
n^a^ | 50 | 50 | 50 | 50
Papilloma^b^
Overall rate^c^ | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate^d^ | 0% | 0% | 0% | 8.32%
Terminal rate^e^ | 0/22 (0%) | 0/19 (0%) | 0/21 (0%) | 0/14 (0%)
First incidence (days) | –^f^ | – | – | 683
Poly-3 test^g^ | p = 0.010 | (e) | (e) | p = 0.101

(e) = value of statistic could not be computed.

^a^ Number of animals with tissue examined microscopically.

^b^ Historical control incidence for 2-year inhalation studies (mean ± standard deviation): 0/150 (0% ± 0%); range: 0% to 0%; all routes: 0/589 (0% ± 0%); range: 0% to 0%.

^c^ Number of animals with neoplasm/number of animals necropsied.

^d^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^e^ Observed incidence at study termination.

^f^ Not applicable; no neoplasms in group.

^g^ Beneath the 0 ppm chamber group incidence is the p value associated with the trend test. Beneath the exposed group incidence is the p value corresponding to pairwise comparisons between the 0 ppm chamber group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. All trend and pairwise p values are reported as one-sided.

Testis: The incidences of degeneration and degeneration or atrophy (combined) in the germinal epithelium of the testis were higher in all exposed groups with a significant increase in the 50 ppm group (Table 8). Degeneration of the germinal epithelium of the testis was characterized by tubular vacuolation, partial or segmental depletion of germ cells, degenerating (multinucleated or apoptotic) germ cells, and disordered arrangement of the germ cell layers.

Table 8 Incidences of Nonneoplastic Lesions of the Testis and Epididymis in Male Rats in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 50 ppm | 100 ppm | 200 ppm
Testis^a^ | 50 | 50 | 50 | 50
Germinal epithelium, degeneration (includes bilateral)^b^ | 12 (3.0)^c^ | 24* (2.4) | 20 (3.0) | 17 (2.8)
Germinal epithelium, degeneration or atrophy (combined, includes bilateral) | 13 (2.9) | 24* (2.4) | 20 (3.0) | 17 (2.8)
Epididymis | 50 | 50 | 50 | 50
Hypospermia (includes bilateral) | 7** (3.4) | 3 (3.3) | 10 (3.1) | 14* (3.1)

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion. Each exposed group was compared to the 0 ppm chamber group using the Poly-3 test.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Epididymis: There was a positive trend in the incidence of hypospermia that was significantly increased in male rats exposed to 200 ppm α-pinene (Table 8). Hypospermia of the epididymis was characterized by depletion of spermatids in the ductular lumen.

Adrenal gland: There was a positive trend, and the incidence of focal hyperplasia in the adrenal gland medulla was significantly increased in male rats exposed to 200 ppm α-pinene (Table 9). Focal hyperplasia of the adrenal gland medulla was characterized by a localized increase in the number of medullary cells with absent to minimal compression of the surrounding tissue (Figure 8A). The hyperplastic cells tended to be smaller and sometimes more basophilic than normal adrenal gland medullary epithelial cells (Figure 8B).

Table 9 Incidences of Select Nonneoplastic Lesions in Male and Female Rats in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 50 ppm | 100 ppm | 200 ppm
Male
Adrenal Gland^a^ | 50 | 50 | 50 | 50
Medulla, hyperplasia, focal (includes bilateral)^b^ | 9** (1.9)^c^ | 8 (2.0) | 12 (2.0) | 18* (2.3)
Liver | 50 | 50 | 50 | 50
Bile duct, hyperplasia | 5** (1.0) | 25** (1.1) | 26** (1.0) | 19** (1.1)
Female
Bone Marrow | 50 | 50 | 50 | 48
Hypercellularity | 10** (3.0) | 22** (3.1) | 18* (2.7) | 24** (3.3)
Spleen | 50 | 49 | 49 | 50
Extramedullary hematopoiesis, increased | 10** (3.2) | 28** (3.1) | 28** (2.8) | 34** (2.8)

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion. Each exposed group was compared to the 0 ppm chamber group using the Poly-3 test.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Figure 8

Representative Images of Focal Hyperplasia in the Adrenal Gland in a Male Rat in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Adrenal gland focal hyperplasia was characterized by a localized increase in the number of medullary cells with absent to minimal compression of the surrounding tissue (arrows), as observed in a 100 ppm male rat (3.5×). (B) A higher magnification of the tissue in panel A. The hyperplastic medullary epithelial cells tended to be smaller and sometimes more basophilic (arrows) than normal adrenal gland medullar epithelial cells (12.5×). H&E = hematoxylin and eosin stain.

Bone marrow: In female rats, the incidence of bone marrow hypercellularity was significantly increased in all exposed groups with a positive trend (Table 9). Compared to the bone marrow of control animals (Figure 9A, Figure 9B) hypercellularity of the bone marrow was characterized by an increase of hematopoietic cells relative to marrow fat in the exposed groups compared to concurrent control animals (Figure 9C, Figure 9D).

Figure 9

Representative Images of Control Bone Marrow and Hypercellularity in the Bone Marrow in a Female Rat in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Normal bone marrow from a control female rat (4×); note the ratio of fat cells (arrows) to hematopoietic tissue (asterisks). (B) A higher magnification of the tissue in panel A (20×). (C) Bone marrow hypercellularity was characterized by densely cellular marrow composed of increased numbers of hematopoietic cells (black arrows), as observed in a 200 ppm female rat (4×). (D) A higher magnification of the tissue in panel C. In hypercellular bone marrow, hematopoietic cells (asterisk) are increased compared to the marrow fat (white arrows) (20×). H&E = hematoxylin and eosin stain.

Liver: In male rats, the incidence of bile duct hyperplasia was significantly increased in all exposed groups with a positive trend (Table 9). Bile duct hyperplasia in the liver was minimal in severity and was characterized by an increased number of small bile ducts frequently arising in the portal region (Figure 10). The biliary epithelium was well differentiated, forming normal ducts.

Figure 10

Representative Image of Bile Duct Hyperplasia in the Liver in a Male Rat in the Two-year Inhalation Study of α-Pinene (H&E)

Liver bile duct hyperplasia was characterized by increased numbers of small bile ducts frequently arising in the portal region (arrows), as observed in a 200 ppm male rat. Biliary epithelium is well differentiated, forming normal ducts (8.5×). H&E = hematoxylin and eosin stain.

Spleen: In female rats, the incidence of increased extramedullary hematopoiesis was significantly increased in all exposed groups with a positive trend (Table 9). Increased extramedullary hematopoiesis was characterized by increased hematopoietic cell numbers in the splenic red pulp (Figure 11A, Figure 11B). An increase in the myeloid precursor cell population was observed more commonly than an increase in the erythroid precursor cell population. Normal distribution and a mixture of hematopoietic cell types were observed.

Figure 11

Representative Images of Increased Extramedullary Hematopoiesis in the Spleen in a Female Rat in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Increased extramedullary hematopoiesis was characterized by increased hematopoietic cell numbers in the splenic red pulp (white arrows) and white pulp (asterisk), as observed in a 50 ppm female rat (4×). (B) A higher magnification of the tissue in panel A. Extramedullary hematopoiesis was composed of increased numbers of erythroid (white arrow) and myeloid (black arrow) precursor cells (20×). H&E = hematoxylin and eosin stain.

Other tissues: In addition to the lesions described above, significant increases in nonneoplastic lesions were observed in the mesenteric lymph nodes and glandular stomach in male and female rats; the lung, pancreas, and skin in male rats; and the adrenal gland cortex, bronchial lymph node, kidney, ovary, and pars distalis of the pituitary gland in female rats (Appendix G). The biological and toxicological significance of these lesions is not known.

## Mice

### Three-month Study in B6C3F1/N Mice

All male mice survived to the end of the study. There were no exposure-related clinical observations, and there were no significant effects on body weight attributed to α-pinene exposure (Appendix G).

#### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidence of nonneoplastic lesions in the urinary bladder.

Urinary bladder: There was a positive trend, and the incidence of urothelium hyperplasia was significantly increased in male mice in the 200 and 400 ppm groups relative to the control group (Table 10). Urothelium hyperplasia of the urinary bladder was of minimal severity and was characterized by increased numbers of urothelial cells (particularly in the basal cell layer), increased cytoplasmic basophilia, and/or increased mucosal thickness (>5 cells thick) compared to the urothelium of control animals.

Table 10 Incidences of Nonneoplastic Lesions of the Urinary Bladder in Male B6C3F1/N Mice in the Three-month Inhalation Study of α-Pinene

| 0 ppm | 100 ppm | 200 ppm | 400 ppm
n^a^ | 10 | 10 | 10 | 10
Urothelium, Hyperplasia^b^ | 0** | 0 | 6** (1.0)^c^ | 10** (1.0)
Infiltration Cellular, Lymphocyte | 0** | 1 (1.0) | 9** (1.1) | 10** (1.0)
Cytoplasmic, Vacuolation | 0** | 9** (1.0) | 10** (1.1) | 10** (1.0)
Single Cell Death | 0** | 9** (1.0) | 9** (1.0) | 10** (1.0)

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion. Statistical analysis performed by the Cochran-Armitage (trend) or Fisher exact (pairwise) tests.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

The incidence of lymphocytic cellular infiltration was significantly increased in male mice in the 200 and 400 ppm groups with a positive trend (Table 10). Lymphocytic cellular infiltration in the urinary bladder was of minimal severity and was characterized by increased numbers of submucosal perivascular lymphocytes or less frequent clusters or nodular aggregates of lymphocytes within the submucosa.

There was a positive trend, and the incidence of cytoplasmic vacuolation in the urinary bladder was significantly increased in all exposed groups of male mice (Table 10). Cytoplasmic vacuolation in the urinary bladder was of minimal severity and was primarily observed in the superficial umbrella cells. These vacuoles were either empty or contained finely granular to flocculant eosinophilic material and occasionally pyknotic debris.

The incidence of single cell death in the urinary bladder was significantly increased in all exposed groups of male mice with a positive trend (Table 10). Single cell death in the urinary bladder was of minimal severity and was characterized by vacuoles within urothelial cells that contained pale pink flocculent material or were filled with either whole pyknotic cells or cellular debris (Figure 12).

Figure 12

Representative Images of Control Urothelium and Single Cell Death in the Urothelium of the Urinary Bladder in a Male B6C3F1/N Mouse in the Three-month Inhalation Study of α-Pinene (H&E)

(A) Urinary bladder from a control mouse showing normal urothelium (arrows) (20×). (B) Urinary bladder single cell death in the urothelium from a B6C3F1/N 200 ppm male mouse; compared to panel A, there are numerous vacuoles within the urothelial cells, several of which contain eosinophilic material or cell debris (arrows) (20×). H&E = hematoxylin and eosin stain.

### Three-month Reproductive Study in CD-1 Mice

All male mice survived to the end of the study. There were no exposure-related clinical observations, nor were there any effects on body weight attributed to α-pinene exposure in male mice (Appendix G). Ten male mice were selected for histopathological examination of the urinary bladder, and no exposure-related histopathological changes were observed (Appendix G).

### Two-year Study

Estimates of the 2-year survival probabilities for male and female mice are shown in Table 11 and in the Kaplan-Meier survival curves (Figure 13). Survival was not significantly decreased with α-pinene exposure. No clinical observations were associated with α-pinene exposure in male or female mice (Appendix G).

Table 11 Summary of Survival of Male and Female B6C3F1/N Mice in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 100 ppm | 200 ppm | 400 ppm
Male
Animals Initially in Study | 50 | 50 | 50 | 50
Euthanized Moribund | 3 | 5 | 5 | 5
Found Dead | 8 | 15 | 9 | 14
Accidental Deaths^a^ | 0 | 0 | 2 | 0
Animals Surviving to Study Termination | 39 | 30 | 34 | 31
Percent Probability of Survival at Study Termination^b^ | 78.0 | 60.0 | 70.9 | 62.0
Survival (Days)^c^ | 696.2 ± 11.3 | 673.3 ± 12.4 | 662.6 ± 20.5 | 675.3 ± 12.7
Survival Analysis^d^ | p = 0.260 | p = 0.194 | p = 0.558 | p = 0.258
Female
Animals Initially in Study | 50 | 50 | 40 | 50
Euthanized Moribund | 7 | 7 | 7 | 9
Found Dead | 10 | 14 | 9 | 17
Animals Surviving to Study Termination | 33 | 29 | 24 | 24
Percent Probability of Survival at Study Termination | 66.0 | 58.0 | 60.0 | 50.0^e^
Survival (Days) | 688.4 ± 11.9 | 675.4 ± 16.0 | 679.8 ± 16.2 | 671.8 ± 16.1
Survival Analysis | p = 0.184 | p = 0.738 | p = 0.738 | p = 0.581

^a^ Accidental deaths are considered censored removals for the survival probability calculations.

^b^ Kaplan-Meier determinations at study day 729 (male mice) or 731 (female mice), the first day of terminal euthanasia.

^c^ Mean of all deaths (uncensored, censored, and study termination) ± standard error.

^d^ The result of the Tarone trend test is in the 0 ppm chamber group column, and the results of the Cox log-rank pairwise comparisons with Hommel adjustment to the 0 ppm chamber group are in the exposed group columns.

^e^ Probability of survival accounts for one animal that was found dead on the first day of terminal euthanasia.

Figure 13

Kaplan-Meier Survival Curves for Male and Female B6C3F1/N Mice in the Two-year Inhalation Study of α-Pinene

Survival curves are shown for (A) males and (B) females.

On study day 92, 14 female mice in the 200 ppm group were found dead. The deaths were attributed to an accidental lack of feed over a 24-hour period. To partially mitigate the loss of animals in the 200 ppm group, four sentinel animals housed in the 200 ppm exposure chamber were reassigned to the chronic study on study day 94, resulting in a sample size of 40 for this group.

In male mice, there was a negative trend and significant decreases in body weight in the 400 ppm group beginning on approximately study day 80 and persisting until study termination (Table 12; Figure 14). Body weights were decreased by 16% compared to the control group on study day 703. In female mice, there were significant decreases in body weight that were sporadic and not attributed to α-pinene exposure (Table 13; Figure 14).

Table 12 Summary of Survival and Body Weights of Male B6C3F1/N Mice in the Two-year Inhalation Study of α-Pinene

Study Day^a^ | 0 ppm | | 100 ppm | | | 200 ppm | | | 400 ppm
Study Day^a^ | Wt. (g)^b,c^ | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 21.8 ± 0.1 | 50 | 21.8 ± 0.1 | 99.8 | 50 | 22.0 ± 0.1 | 100.7 | 50 | 21.8 ± 0.2 | 99.8 | 50
10 | 24.5 ± 0.1 | 50 | 24.9 ± 0.2 | 101.9 | 50 | 24.6 ± 0.2 | 100.4 | 50 | 24.5 ± 0.1 | 100.0 | 50
17 | 25.8 ± 0.1 | 50 | 26.0 ± 0.2 | 100.7 | 50 | 25.7 ± 0.2 | 99.6 | 50 | 25.6 ± 0.2 | 99.0 | 50
24 | 26.6 ± 0.1 | 50 | 26.7 ± 0.2 | 100.5 | 50 | 26.2 ± 0.1 | 98.3 | 50 | 26.6 ± 0.2 | 99.8 | 50
31 | 27.4 ± 0.2 | 50 | 27.8 ± 0.2 | 101.5 | 49^d^ | 27.2 ± 0.1 | 99.1 | 50 | 27.4 ± 0.2 | 99.8 | 50
38 | 28.1 ± 0.2 | 50 | 28.6 ± 0.2 | 101.7 | 50 | 27.8 ± 0.2 | 98.9 | 50 | 27.9 ± 0.2 | 99.3 | 50
45 | 28.8 ± 0.2* | 50 | 27.0 ± 0.3** | 93.8 | 50 | 29.2 ± 0.2 | 101.4 | 50 | 29.1 ± 0.2 | 100.8 | 50
52 | 28.6 ± 0.2 | 50 | 29.6 ± 0.3** | 103.7 | 50 | 29.1 ± 0.2 | 101.7 | 50 | 29.1 ± 0.2 | 101.8 | 50
59 | 29.9 ± 0.2 | 50 | 30.7 ± 0.3 | 102.4 | 50 | 30.1 ± 0.2 | 100.6 | 50 | 29.8 ± 0.3 | 99.5 | 50
66 | 30.8 ± 0.2 | 50 | 31.1 ± 0.3 | 101.1 | 50 | 30.5 ± 0.2 | 99.1 | 50 | 30.5 ± 0.3 | 99.2 | 50
73 | 30.8 ± 0.2 | 50 | 32.1 ± 0.3** | 104.1 | 50 | 30.6 ± 0.2 | 99.2 | 50 | 30.8 ± 0.3 | 99.9 | 50
80 | 31.6 ± 0.2** | 50 | 32.8 ± 0.3 | 103.8 | 50 | 31.6 ± 0.2 | 100.1 | 50 | 30.5 ± 0.3** | 96.6 | 50
87 | 32.2 ± 0.3** | 50 | 32.9 ± 0.3 | 102.0 | 50 | 31.8 ± 0.2 | 98.7 | 50 | 31.2 ± 0.3** | 96.7 | 50
94 | 32.8 ± 0.3** | 50 | 34.0 ± 0.4 | 103.7 | 50 | 32.7 ± 0.2 | 99.8 | 50 | 31.9 ± 0.3* | 97.3 | 50
115 | 34.6 ± 0.3** | 50 | 35.5 ± 0.4 | 102.5 | 50 | 34.7 ± 0.3 | 100.3 | 50 | 33.2 ± 0.4** | 96.0 | 50
143 | 37.5 ± 0.4** | 50 | 38.0 ± 0.5 | 101.5 | 50 | 35.7 ± 0.4** | 95.2 | 50 | 34.3 ± 0.5** | 91.5 | 50
171 | 39.2 ± 0.4** | 50 | 39.7 ± 0.5 | 101.3 | 50 | 37.7 ± 0.4* | 96.2 | 50 | 36.0 ± 0.5** | 91.8 | 50
199 | 41.4 ± 0.4** | 50 | 42.1 ± 0.6 | 101.8 | 50 | 40.0 ± 0.4 | 96.8 | 47 | 37.6 ± 0.5** | 91.0 | 50
227 | 43.7 ± 0.5** | 50 | 44.1 ± 0.5 | 100.8 | 50 | 42.1 ± 0.4* | 96.3 | 47 | 39.3 ± 0.5** | 89.9 | 50
256 | 45.2 ± 0.5** | 50 | 45.3 ± 0.5 | 100.3 | 50 | 42.9 ± 0.5** | 94.9 | 47 | 40.6 ± 0.6** | 89.9 | 50
283 | 44.6 ± 0.5** | 50 | 46.0 ± 0.6 | 103.1 | 50 | 44.2 ± 0.5 | 99.0 | 47 | 41.5 ± 0.6** | 93.1 | 50
311 | 46.8 ± 0.7** | 50 | 47.6 ± 0.6 | 101.6 | 50 | 45.1 ± 0.5 | 96.4 | 47 | 43.1 ± 0.6** | 92.2 | 50
339 | 48.3 ± 0.7** | 50 | 48.7 ± 0.7 | 100.9 | 50 | 46.5 ± 0.7 | 96.3 | 46 | 45.9 ± 0.6* | 95.0 | 50
367 | 49.2 ± 0.8** | 50 | 49.7 ± 0.6 | 101.1 | 49 | 48.0 ± 0.6 | 97.6 | 46 | 45.7 ± 0.7** | 92.9 | 50
395 | 50.0 ± 0.6** | 49 | 49.8 ± 0.7 | 99.5 | 49 | 47.9 ± 0.7* | 95.7 | 46 | 46.1 ± 0.7** | 92.2 | 49
423 | 50.9 ± 0.6** | 48 | 50.0 ± 0.8 | 98.3 | 49 | 48.5 ± 0.8* | 95.3 | 46 | 47.8 ± 0.7** | 94.0 | 48
451 | 51.8 ± 0.7** | 48 | 50.8 ± 0.7 | 98.2 | 48 | 50.0 ± 0.8 | 96.5 | 46 | 47.8 ± 0.7** | 92.2 | 48
479 | 52.2 ± 0.7** | 48 | 50.2 ± 0.8 | 96.2 | 48 | 50.5 ± 0.8 | 96.8 | 45 | 49.2 ± 0.8** | 94.3 | 47
507 | 51.7 ± 0.7** | 48 | 49.8 ± 1.0 | 96.4 | 47 | 49.7 ± 0.8 | 96.1 | 45 | 48.2 ± 0.8** | 93.3 | 47
535 | 51.3 ± 0.8** | 47 | 50.6 ± 1.0 | 98.6 | 46 | 51.0 ± 0.8 | 99.5 | 44 | 48.3 ± 0.9* | 94.1 | 46
563 | 51.6 ± 0.9** | 46 | 50.1 ± 1.0 | 97.1 | 44 | 49.8 ± 0.9 | 96.5 | 42 | 47.7 ± 0.9** | 92.5 | 43
591 | 51.0 ± 1.0** | 46 | 48.9 ± 1.1 | 96.0 | 43 | 49.8 ± 1.0 | 97.7 | 41 | 47.1 ± 1.0** | 92.5 | 42
619 | 50.7 ± 0.9** | 43 | 47.2 ± 1.2* | 93.1 | 37 | 47.9 ± 1.1* | 94.4 | 41 | 45.3 ± 1.0** | 89.3 | 39
647 | 51.1 ± 1.1** | 42 | 47.1 ± 1.3 | 92.2 | 35 | 48.6 ± 1.1 | 95.2 | 39 | 44.9 ± 1.1** | 87.9 | 37
675 | 50.6 ± 1.1** | 41 | 46.5 ± 1.4* | 91.9 | 33 | 47.1 ± 1.2* | 93.2 | 38 | 43.6 ± 1.2** | 86.2 | 34
703 | 50.2 ± 1.2** | 41 | 44.6 ± 1.6* | 88.8 | 31 | 46.5 ± 1.2* | 92.7 | 37 | 42.3 ± 1.2** | 84.3 | 33

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Study day 1 is the day animals were placed on study.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Weights shown are mean ± standard error.

^d^ One animal weight was excluded as an outlier and thus excluded from analysis on the indicated study day.

Figure 14

Growth Curves for Male and Female B6C3F1/N Mice in the Two-year Inhalation Study of α-Pinene

Growth curves are shown for (A) males and (B) females.

Table 13 Summary of Survival and Body Weights of Female B6C3F1/N Mice in the Two-year Inhalation Study of α-Pinene

Study Day^a^ | 0 ppm | | 100 ppm | | | 200 ppm | | | 400 ppm
Study Day^a^ | Wt. (g)^b,c^ | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 18.4 ± 0.1 | 50 | 18.2 ± 0.1 | 99.0 | 50 | 18.7 ± 0.1 | 101.7 | 36 | 17.9 ± 0.1* | 97.3 | 50
10 | 20.2 ± 0.1 | 50 | 20.4 ± 0.1 | 101.2 | 50 | 20.7 ± 0.2* | 102.6 | 36 | 20.4 ± 0.1 | 101.3 | 50
17 | 19.5 ± 0.1** | 50 | 22.1 ± 0.1** | 113.7 | 50 | 22.0 ± 0.2** | 112.9 | 36 | 21.9 ± 0.2** | 112.8 | 50
24 | 22.6 ± 0.1 | 49 | 22.4 ± 0.1 | 99.1 | 50 | 22.7 ± 0.2 | 100.5 | 36 | 22.9 ± 0.2 | 101.4 | 50
31 | 23.4 ± 0.2* | 50 | 23.8 ± 0.1 | 101.5 | 50 | 24.1 ± 0.2** | 103.0 | 36 | 23.8 ± 0.1 | 101.5 | 50
38 | 24.2 ± 0.1 | 50 | 24.4 ± 0.1 | 100.7 | 50 | 24.8 ± 0.2* | 102.5 | 36 | 24.1 ± 0.1 | 99.4 | 50
45 | 24.9 ± 0.2** | 50 | 24.1 ± 0.2 | 96.9 | 50 | 26.5 ± 0.2** | 106.6 | 36 | 25.7 ± 0.2** | 103.5 | 50
52 | 24.5 ± 0.2** | 50 | 25.8 ± 0.2** | 105.5 | 50 | 26.9 ± 0.2** | 110.2 | 36 | 25.8 ± 0.2** | 105.7 | 50
59 | 25.7 ± 0.2** | 50 | 27.0 ± 0.2** | 105.2 | 50 | 27.4 ± 0.2** | 106.7 | 36 | 26.3 ± 0.2** | 102.5 | 50
66 | 26.1 ± 0.2 | 50 | 27.3 ± 0.2** | 104.7 | 50 | 27.3 ± 0.3** | 104.6 | 36 | 26.3 ± 0.2 | 100.7 | 50
73 | 26.4 ± 0.2 | 50 | 27.8 ± 0.2** | 105.4 | 50 | 27.5 ± 0.2** | 104.0 | 36 | 26.7 ± 0.2 | 101.0 | 50
80 | 27.1 ± 0.2 | 50 | 28.2 ± 0.2** | 104.3 | 50 | 28.6 ± 0.3** | 105.8 | 36 | 27.3 ± 0.2 | 101.0 | 50
87 | 27.3 ± 0.2 | 50 | 28.3 ± 0.3** | 103.5 | 50 | 28.8 ± 0.3** | 105.6 | 36 | 27.2 ± 0.2 | 99.8 | 50
94 | 28.0 ± 0.2 | 50 | 29.3 ± 0.3** | 104.7 | 50 | 28.9 ± 0.3* | 103.5 | 40^d^ | 27.9 ± 0.2 | 99.8 | 50
115 | 29.4 ± 0.3 | 50 | 30.5 ± 0.3* | 103.5 | 50 | 30.8 ± 0.3** | 104.8 | 36 | 28.6 ± 0.3 | 97.2 | 50
143 | 31.9 ± 0.3** | 50 | 33.3 ± 0.4 | 104.6 | 50 | 32.7 ± 0.5 | 102.5 | 36 | 30.6 ± 0.4* | 96.1 | 50
171 | 34.4 ± 0.4** | 50 | 34.7 ± 0.5 | 100.8 | 50 | 34.9 ± 0.6 | 101.3 | 36 | 31.4 ± 0.5** | 91.3 | 50
199 | 34.5 ± 0.5* | 50 | 36.8 ± 0.5** | 106.7 | 50 | 36.6 ± 0.7* | 106.2 | 36 | 33.0 ± 0.5 | 95.7 | 50
227 | 36.7 ± 0.7 | 50 | 38.4 ± 0.6 | 104.8 | 50 | 38.5 ± 0.7 | 105.0 | 40 | 36.1 ± 0.7 | 98.5 | 50
256 | 39.9 ± 0.7 | 50 | 40.8 ± 0.7 | 102.4 | 50 | 39.8 ± 0.8 | 99.9 | 40 | 39.6 ± 0.7 | 99.2 | 49
283 | 38.0 ± 0.8* | 50 | 43.1 ± 0.8** | 113.3 | 49 | 42.6 ± 0.9** | 112.1 | 40 | 41.2 ± 0.8* | 108.5 | 49
311 | 42.8 ± 0.9 | 50 | 45.8 ± 0.9* | 107.0 | 48 | 44.1 ± 1.0 | 102.9 | 40 | 43.8 ± 0.9 | 102.3 | 48
339 | 44.3 ± 1.0 | 50 | 47.2 ± 0.9 | 106.5 | 48 | 47.8 ± 1.1* | 107.8 | 39 | 46.5 ± 1.0 | 104.9 | 48
367 | 46.7 ± 1.0 | 50 | 49.5 ± 0.9 | 106.0 | 48 | 50.1 ± 1.2 | 107.4 | 39 | 47.3 ± 1.0 | 101.3 | 48
395 | 48.1 ± 1.1 | 49 | 51.6 ± 1.0 | 107.2 | 47 | 52.6 ± 1.1* | 109.4 | 38 | 48.4 ± 1.1 | 100.7 | 48
423 | 50.6 ± 1.2 | 49 | 52.3 ± 1.0 | 103.4 | 47 | 53.4 ± 1.2 | 105.7 | 37 | 50.2 ± 1.1 | 99.3 | 47
451 | 52.5 ± 1.2 | 48 | 56.3 ± 1.0* | 107.2 | 46 | 55.9 ± 1.2 | 106.6 | 37 | 51.8 ± 1.1 | 98.7 | 47
479 | 54.0 ± 1.2 | 48 | 57.7 ± 1.1 | 106.9 | 46 | 57.3 ± 1.3 | 106.2 | 37 | 53.2 ± 1.0 | 98.5 | 46
507 | 53.6 ± 1.4 | 47 | 57.4 ± 1.1 | 107.1 | 45 | 57.6 ± 1.4 | 107.5 | 36 | 52.9 ± 1.0 | 98.7 | 45
535 | 54.7 ± 1.3 | 45 | 59.3 ± 1.2* | 108.3 | 44 | 58.6 ± 1.5 | 107.0 | 36 | 54.1 ± 1.0 | 98.9 | 44
563 | 55.5 ± 1.2 | 44 | 58.8 ± 1.2 | 106.0 | 43 | 57.1 ± 1.7 | 103.0 | 36 | 54.2 ± 1.1 | 97.7 | 44
591 | 56.1 ± 1.3 | 43 | 57.8 ± 1.3 | 103.0 | 43 | 58.4 ± 1.4 | 104.1 | 34 | 53.1 ± 1.2 | 94.6 | 43
619 | 53.7 ± 1.2 | 43 | 55.8 ± 1.4 | 103.8 | 42 | 56.2 ± 1.5 | 104.5 | 33 | 49.7 ± 1.3 | 92.4 | 43
647 | 52.9 ± 1.2 | 41 | 54.6 ± 1.5 | 103.3 | 41 | 55.3 ± 1.6 | 104.7 | 33 | 51.1 ± 1.3 | 96.8 | 38
675 | 51.5 ± 1.3 | 39 | 52.6 ± 1.5 | 102.2 | 38 | 53.4 ± 1.7 | 103.6 | 31 | 48.6 ± 1.4 | 94.5 | 38
703 | 51.4 ± 1.3 | 34 | 51.6 ± 1.8 | 100.2 | 34 | 52.1 ± 1.8 | 101.3 | 29 | 47.6 ± 1.4 | 92.5 | 31

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Study day 1 is the day animals were placed on study.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Weights shown are mean ± standard error.

^d^ Sentinel animals were not weighed on the same schedule as the chronic study animals; therefore, body weights for the four sentinel animals were not available until study day 94 (the day they were put on study). Sentinel animals were not weighed on study days 115, 143, 171, and 199.

#### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidence of neoplasms and/or nonneoplastic lesions of the Harderian gland, liver, lung, mammary gland, urinary bladder, ovary, stomach, testis, and epididymis.

Harderian gland: There were positive trends in the incidences of Harderian gland adenoma, adenocarcinoma, and adenoma or adenocarcinoma (combined) in male and female mice (Table 14). The incidence of Harderian gland adenoma was significantly increased in male mice in the 400 ppm group and in female mice exposed to 200 or 400 ppm α-pinene compared to their respective control groups. The incidence of Harderian gland adenocarcinoma was significantly increased in male mice in the 400 ppm group. The incidence of Harderian gland adenoma or adenocarcinoma (combined) was significantly increased in the 200 and 400 ppm groups for both male and female mice. In male mice, the incidence of hyperplasia was higher in all exposed groups and significantly increased in the 100 ppm group, whereas in female mice, the incidence of hyperplasia was higher in the 100 and 400 ppm groups.

Table 14 Incidences of Neoplastic and Nonneoplastic Lesions of the Harderian Gland in Male and Female B6C3F1/N Mice in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 100 ppm | 200 ppm | 400 ppm
Male
n^a^ | 50 | 50 | 50 | 50
Hyperplasia (Includes Bilateral)^b^ | 2 (4.0)^c^ | 8* (3.3) | 7 (2.9) | 6 (3.0)
Adenoma (Includes Bilateral)^d^
Overall rate^e^ | 6/50 (12%) | 9/50 (18%) | 11/50 (22%) | 16/50 (32%)
Adjusted rate^f^ | 13.32% | 21.47% | 25.91% | 36.24%
Terminal rate^g^ | 6/39 (15%) | 6/30 (20%) | 9/34 (26%) | 10/31 (32%)
First incidence (days) | 729 (T) | 599 | 576 | 541
Poly-3 test^h^ | p = 0.006 | p = 0.235 | p = 0.110 | p = 0.010
Adenocarcinoma (Includes Bilateral)^i^
Overall rate | 0/50 (0%) | 1/50 (2%) | 3/50 (6%) | 7/50 (14%)
Adjusted rate | 0% | 2.43% | 7.16% | 16.77%
Terminal rate | 0/39 (0%) | 1/30 (3%) | 3/34 (9%) | 6/31 (19%)
First incidence (days) | –^j^ | 729 (T) | 729 (T) | 708
Poly-3 test | p = 0.001 | p = 0.482 | p = 0.106 | p = 0.005
Adenoma or Adenocarcinoma (Combined)^k^
Overall rate | 6/50 (12%) | 9/50 (18%) | 14/50 (28%) | 23/50 (46%)
Adjusted rate | 13.32% | 21.47% | 32.98% | 52%
Terminal rate | 6/39 (15%) | 6/30 (20%) | 12/34 (35%) | 16/31 (52%)
First incidence (days) | 729 (T) | 599 | 576 | 541
Poly-3 test | p < 0.001 | p = 0.235 | p = 0.024 | p < 0.001
Female
n | 50 | 49 | 40 | 50
Hyperplasia (Includes Bilateral) | 3 (3.3) | 6 (2.8) | 3 (2.3) | 8 (2.9)
Adenoma (Includes Bilateral)^l^
Overall rate | 3/50 (6%) | 6/49 (12%) | 11/40 (28%) | 16/50 (32%)
Adjusted rate | 6.91% | 14.38% | 31.72% | 36.4%
Terminal rate | 3/33 (9%) | 3/28 (11%) | 9/24 (38%) | 9/24 (38%)
First incidence (days) | 731 (T) | 640 | 581 | 459
Poly-3 test | p < 0.001 | p = 0.221 | p = 0.004 | p = 0.001
Adenocarcinoma (Includes Bilateral)^m^
Overall rate | 1/50 (2%) | 2/49 (4%) | 3/40 (8%) | 6/50 (12%)
Adjusted rate | 2.3% | 4.85% | 8.8% | 14.01%
Terminal rate | 1/33 (3%) | 1/28 (4%) | 3/24 (13%) | 2/24 (8%)
First incidence (days) | 731 (T) | 730 | 731 (T) | 628
Poly-3 test | p = 0.022 | p = 0.482 | p = 0.222 | p = 0.053
Adenoma or Adenocarcinoma (Combined)^n^
Overall rate | 4/50 (8%) | 8/49 (16%) | 13/40 (33%) | 22/50 (44%)
Adjusted rate | 9.21% | 19.17% | 37.48% | 48.74%
Terminal rate | 4/33 (12%) | 4/28 (14%) | 11/24 (46%) | 11/24 (46%)
First incidence (days) | 731 (T) | 640 | 581 | 459
Poly-3 test | p < 0.001 | p = 0.156 | p = 0.002 | p < 0.001

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group.

* Statistically significant at p ≤ 0.05.

(T) = terminal euthanasia.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion. For nonneoplastic lesions, each exposed group was compared to the 0 ppm chamber group using the Poly-3 test.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for 2-year inhalation studies (mean ± standard deviation): 14/150 (9.33% ± 3.06%); range: 6% to 12%; all routes: 33/440 (7.58% ± 4.22%); range: 0% to 12%.

^e^ Number of animals with neoplasm/number of animals necropsied.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at study termination.

^h^ Beneath the 0 ppm chamber group incidence is the p value associated with the trend test. Beneath the exposed group incidence is the p value corresponding to pairwise comparisons between the 0 ppm chamber group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. All trend and pairwise p values are reported as one-sided.

^i^ Historical control incidence for 2-year inhalation studies: 4/150 (2.67% ± 3.06%); range: 0% to 6%; all routes: 13/440 (2.92% ± 1.81%); range: 0% to 6%.

^j^ Not applicable; no neoplasms in group.

^k^ Historical control incidence for 2-year inhalation studies: 18/150 (12% ± 0%); range: 12% to 12%; all routes: 46/440 (10.5% ± 3.82%); range: 4% to 16%.

^l^ Historical control incidence for 2-year inhalation studies: 10/150 (6.67% ± 3.06%); range: 4% to 10%; all routes: 25/490 (5.16% ± 2.65%); range: 2% to 10%.

^m^ Historical control incidence for 2-year inhalation studies: 1/150 (0.67% ± 1.15%); range: 0% to 2%; all routes: 4/490 (0.89% ± 1.45%); range: 0% to 4%.

^n^ Historical control incidence for 2-year inhalation studies: 11/150 (7.33% ± 3.06%); range: 4% to 10%; all routes: 29/490 (6.05% ± 3.58%); range: 2% to 12%.

Harderian gland adenomas were well demarcated, compressive masses composed of neoplastic acinar cells that formed multiple, papillary structures supported by a thin fibrovascular stroma, occasionally bordered by a fibrous capsule (Figure 15A). Neoplastic acinar cells lining papillary structures were generally one cell layer thick and had basal round nuclei and finely vacuolated basophilic cytoplasm (Figure 15B and Figure 15C).

Figure 15

Representative Images of Adenoma in the Harderian Gland in a Female Mouse in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Harderian gland adenoma in a 400 ppm female mouse (arrows). The tumor has effaced the normal architecture (arrows) (2×). (B) A higher magnification of the Harderian gland adenoma in panel A. There is minimal compression of the surrounding normal Harderian gland at the margins (arrows) (4×). (C) A higher magnification of the Harderian gland adenoma in panel B. The cells lining the papillary projections are for the most part single layered, with basal nuclei and finely vacuolated cytoplasm (20×). H&E = hematoxylin and eosin stain.

Harderian gland adenocarcinomas were poorly demarcated, infiltrative masses that variably expanded and effaced the Harderian gland (Figure 16A; Figure 16B). Neoplastic acinar cells formed multiple, disarrayed papillary structures supported by fibrovascular stroma and/or grew in solid sheets. Neoplastic cells lining papillary structures were similar to those in the adenomas, but those in the solid sheets were disorganized and lacked the finely vacuolated cytoplasm. The neoplastic cells were pleomorphic, mitoses were increased, and areas of tissue invasion were often present (Figure 16C).

Figure 16

Representative Images of Adenocarcinoma in the Harderian Gland in Male and Female Mice in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Harderian gland adenocarcinoma in a 400 ppm female mouse. The tumor is large and has completely replaced the normal gland. There are areas of papillary growth (asterisks) and solid growth (arrow) (2×). (B) A higher magnification of the tissue in panel A. Clusters of neoplastic cells are invading the connective tissue at the edge of the tumor (arrows) (10×). (C) A Harderian gland adenocarcinoma in a 400 ppm male mouse. This high-magnification image reveals marked cellular pleomorphism. A mitotic figure is also present (arrow). Typically, adenocarcinomas display more cellular atypia than adenomas, but confirmatory features of malignancy include invasion and metastasis (20×). H&E = hematoxylin and eosin stain.

Harderian gland hyperplasia was characterized by focal to multifocal regions in which there were increased numbers of crowded acinar epithelial cells with slight tinctorial differences when compared to the surrounding parenchyma (Figure 17). Occasionally, papillary infolding of hyperplastic acinar cells was evident. Regions of Harderian gland hyperplasia were well demarcated and noncompressive.

Figure 17

Representative Image of Focal Hyperplasia in the Harderian Gland in a Male Mouse in the Two-year Inhalation Study of α-Pinene (H&E)

Harderian gland focal hyperplasia (circled area) is distinguished from the normal Harderian gland architecture by disorganization and increased cellularity with cells that are larger and/or stain more darkly, as observed in a 200 ppm male mouse. There is some papillary infolding (arrow), but unlike a neoplasm of the Harderian gland, there is no compression of the surrounding, unaffected glandular tissue (10×). H&E = hematoxylin and eosin stain.

Liver: There was a positive trend and exposure-related significant increase in the incidence of hepatocellular adenoma in male and female mice (Table 15). The incidence of hepatocellular adenoma was significantly increased in male mice exposed to 200 or 400 ppm α-pinene and in all exposed groups of female mice compared to the control group. The incidence of multiple hepatocellular adenomas was higher in male and female mice exposed to 200 or 400 ppm. There was a positive trend, and the incidence of hepatocellular carcinoma was significantly increased in the 400 ppm group for both male and female mice. The incidence of multiple hepatocellular carcinomas was higher in all male and female mice exposed to 400 ppm. The incidence of hepatocellular adenoma or hepatocellular carcinoma (combined) was significantly increased in all exposed groups of male and female mice with a positive trend.

Table 15 Incidences of Neoplastic and Nonneoplastic Lesions of the Liver in Male and Female B6C3F1/N Mice in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 100 ppm | 200 ppm | 400 ppm
Male
n^a^ | 50 | 50 | 49 | 50
Multinucleated Hepatocyte^b^ | 3** (1.0)^c^ | 11* (1.3) | 10* (1.3) | 23** (1.4)
Basophilic Focus | 1** | 2 | 3 | 7*
Necrosis | 1* (2.0) | 3 (2.7) | 2 (2.0) | 7* (2.9)
Hepatocellular Adenoma, Multiple^d^ | 8 | 17 | 21 | 20
Hepatocellular Adenoma (Includes Multiple)^e^
Overall rate^f^ | 23/50 (46%) | 26/50 (52%) | 31/49 (63%) | 33/50 (66%)
Adjusted rate^g^ | 49.6% | 59.92% | 72.9% | 75.51%
Terminal rate^h^ | 19/39 (49%) | 21/30 (70%) | 27/34 (79%) | 26/31 (84%)
First incidence (days) | 557 | 432 | 638 | 550
Poly-3 test^i^ | p = 0.003 | p = 0.216 | p = 0.017 | p = 0.007
Hepatocellular Carcinoma, Multiple | 4 | 10 | 8 | 17
Hepatocellular Carcinoma (Includes Multiple)^j^
Overall rate | 18/50 (36%) | 26/50 (52%) | 17/49 (35%) | 36/50 (72%)
Adjusted rate | 38.34% | 57.12% | 37.89% | 77.15%
Terminal rate | 14/39 (36%) | 16/30 (53%) | 11/34 (32%) | 24/31 (77%)
First incidence (days) | 420 | 365 | 472 | 383
Poly-3 test | p < 0.001 | p = 0.051 | p = 0.602 | p < 0.001
Hepatocellular Adenoma or Hepatocellular Carcinoma (Combined, Includes Multiple)^k^
Overall rate | 33/50 (66%) | 40/50 (80%) | 40/49 (82%) | 46/50 (92%)
Adjusted rate | 68.38% | 85.17% | 87.88% | 96.33%
Terminal rate | 25/39 (64%) | 27/30 (90%) | 30/34 (88%) | 31/31 (100%)
First incidence (days) | 420 | 365 | 472 | 383
Poly-3 test | p < 0.001 | p = 0.038 | p = 0.018 | p < 0.001
Female
n | 50 | 50 | 38 | 50
Hepatocellular Adenoma, Multiple | 1 | 4 | 9 | 22
Hepatocellular Adenoma (Includes Multiple)^l^
Overall rate | 6/50 (12%) | 15/50 (30%) | 20/38 (53%) | 28/50 (56%)
Adjusted rate | 13.61% | 34.95% | 57.82% | 64.91%
Terminal rate | 5/33 (15%) | 13/29 (45%) | 16/24 (67%) | 17/24 (71%)
First incidence (days) | 508 | 518 | 603 | 639
Poly-3 test | p < 0.001 | p = 0.016 | p < 0.001 | p < 0.001
Hepatocellular Carcinoma, Multiple | 0 | 3 | 2 | 7
Hepatocellular Carcinoma (Includes Multiple)^m^
Overall rate | 7/50 (14%) | 14/50 (28%) | 11/38 (29%) | 20/50 (40%)
Adjusted rate | 16% | 32.73% | 31.55% | 46.68%
Terminal rate | 5/33 (15%) | 11/29 (38%) | 7/24 (29%) | 11/24 (46%)
First incidence (days) | 673 | 650 | 581 | 587
Poly-3 test | p = 0.002 | p = 0.056 | p = 0.084 | p = 0.001
Hepatocellular Adenoma or Hepatocellular Carcinoma (Combined, Includes Multiple)^n^
Overall rate | 12/50 (24%) | 27/50 (54%) | 24/38 (63%) | 39/50 (78%)
Adjusted rate | 27.02% | 62.19% | 68.27% | 88.4%
Terminal rate | 9/33 (27%) | 22/29 (76%) | 18/24 (75%) | 24/24 (100%)
First incidence (days) | 508 | 518 | 581 | 587
Poly-3 test | p < 0.001 | p < 0.001 | p < 0.001 | p < 0.001

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion. For nonneoplastic lesions, each exposed group was compared to the 0 ppm chamber group using the Poly-3 test.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ No statistical analyses were performed on multiplicity data.

^e^ Historical control incidence for 2-year inhalation studies (mean ± standard deviation): 61/150 (40.67% ± 12.86%); range: 26% to 50%; all routes: 207/440 (45.97% ± 9.46%); range: 26% to 58%.

^f^ Number of animals with neoplasm/number of animals necropsied.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Observed incidence at study termination.

^i^ Beneath the 0 ppm chamber group incidence is the p value associated with the trend test. Beneath the exposed group incidence is the p value corresponding to pairwise comparisons between the 0 ppm chamber group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. All trend and pairwise p values are reported as one-sided.

^j^ Historical control incidence for 2-year inhalation studies: 39/150 (26% ± 10%); range: 16% to 36%; all routes: 105/440 (23.14% ± 9.2%); range: 10% to 36%.

^k^ Historical control incidence for 2-year inhalation studies: 88/150 (58.67% ± 8.08%); range: 50% to 66%; all routes: 270/440 (60.06% ± 9.11%); range: 46% to 74%.

^l^ Historical control incidence for 2-year inhalation studies: 22/150 (14.67% ± 8.33%); range: 8% to 24%; all routes: 87/489 (17.48% ± 5.67%); range: 8% to 24%.

^m^ Historical control incidence for 2-year inhalation studies: 20/150 (13.33% ± 1.15%); range: 12% to 14%; all routes: 39/489 (7.89% ± 4.54%); range: 2% to 14%.

^n^ Historical control incidence for 2-year inhalation studies: 39/150 (26% ± 9.17%); range: 18% to 36%; all routes: 117/489 (23.57% ± 6.15%); range: 16% to 36%.

Hepatocellular adenomas were well-demarcated, compressive masses composed of hepatocytes arranged in disorganized cords (1–2 hepatocytes thick) with increased mitotic activity, occasional necrosis, variable cytoplasmic vacuolation, and minimal pleomorphism. Neoplastic hepatocytes often resembled normal hepatocytes apart from a disorganized growth pattern. Hepatocellular adenomas occasionally bulged from the capsular surface, had distinct transitions from neoplastic tissue to adjacent normal tissue, and lacked lobular structures with portal triads (Figure 18A, Figure 18B, Figure 18C).

Figure 18

Representative Images of Hepatocellular Adenoma in the Liver in a Male Mouse in the Two-year Inhalation Study of α-Pinene (H&E)

Liver hepatocellular adenoma in a 200 ppm male mouse. (A) The adenoma is projecting above the surface of the liver (2×). (B) A higher magnification of the tissue in panel A. This hepatocellular adenoma is causing compression of the surrounding liver parenchyma (arrows). The normal architecture of the liver is effaced within the adenoma—with hepatic lobules and portal triads not evident (4×). (C) A higher magnification of the tissue in panel A. There is a distinct transition between the cells of the hepatocellular adenoma and the surrounding liver (arrows). The cells of the hepatocellular adenoma do not display much pleomorphism (10×). H&E = hematoxylin and eosin stain.

Hepatocellular carcinomas were generally larger, poorly demarcated expansile masses that occasionally effaced entire liver sections (Figure 19A, Figure 19B). Neoplastic hepatocytes were polygonal with poorly defined cell margins and had round nuclei with coarsely clumped chromatin and variable amounts of occasionally vacuolated eosinophilic cytoplasm. Neoplastic hepatocytes demonstrated significant pleomorphism and grew in acinar and/or trabecular patterns (trabeculae ≥3 cells thick), often forming islands of neoplastic hepatocytes separated by irregular dilated spaces.

Figure 19

Representative Images of Hepatocellular Carcinoma in the Liver in a Male Mouse in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Liver hepatocellular carcinomas (e.g., the example shown from a 200 ppm male mouse) can become quite large and involve the entire liver section (1×). (B) A higher magnification of the hepatocellular carcinoma from panel A reveals the classic thickened trabeculae (arrows) that represent the most common growth pattern of hepatocellular carcinomas (20×). H&E = hematoxylin and eosin stain.

The incidence of multinucleated hepatocytes was significantly increased in all exposed groups of male mice with a positive trend (Table 15). Multinucleated hepatocytes were of minimal severity and enlarged, polyhedral, or rhomboid in shape; contained 6–12 round to oval nuclei; and were randomly distributed within nontumor hepatic parenchyma (Figure 20).

Figure 20

Representative Image of Multinucleated Hepatocytes in the Liver in a Male Mouse in the Two-year Inhalation Study of α-Pinene (H&E)

Liver multinucleated hepatocytes in a 400 ppm male mouse (arrows). While it is not uncommon for the livers of older mice to have binucleated hepatocytes, these multinucleated hepatocytes had >3, and sometimes >10, nuclei (20×). H&E = hematoxylin and eosin stain.

Additional nonneoplastic lesions observed in the liver of male mice included basophilic focus and necrosis, which occurred with positive trends (Table 15). For both basophilic focus and necrosis, there was a significant increase in incidence in the 400 ppm group. Basophilic foci were generally round or oval and ranged in size from approximately 1 to 3 mm diameter. Hepatocytes had basophilic cytoplasm and variably sized vesicular nuclei that had prominent nucleoli. Necrosis consisted of focal to focally extensive areas of coagulative necrosis, occurring within and/or adjacent to hepatocellular carcinomas often associated with minimal to mild acute to chronic active inflammation.

Lung: There was a positive trend, and the incidence of alveolar/bronchiolar adenoma was significantly increased in male mice exposed to 400 ppm α-pinene and in all exposed groups of female mice; the incidence of multiple alveolar/bronchiolar adenoma was higher in male and female mice exposed to 400 ppm α-pinene (Table 16). The incidence of alveolar/bronchiolar carcinoma was significantly increased in female mice exposed to 200 and 400 ppm α-pinene and exhibited a positive trend; the incidence of multiple alveolar/bronchiolar carcinoma was higher in female mice exposed to 400 ppm α-pinene. The incidence of alveolar/bronchiolar adenoma or alveolar/bronchiolar carcinoma (combined) was significantly increased in the 200 and 400 ppm groups in male mice and in all exposed groups in female mice with a positive trend.

Table 16 Incidences of Neoplastic and Nonneoplastic Lesions of the Lung in Male and Female B6C3F1/N Mice in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 100 ppm | 200 ppm | 400 ppm
Male
n^a^ | 50 | 50 | 50 | 50
Alveolar/Bronchiolar, Epithelium, Hyperplasia^b^ | 2** (4.0)^c^ | 10** (2.2) | 20** (2.3) | 27** (2.6)
Alveolar/Bronchiolar Adenoma, Multiple^d^ | 1 | 1 | 3 | 5
Alveolar/Bronchiolar Adenoma (Includes Multiple)^e^
Overall rate^f^ | 5/50 (10%) | 8/50 (16%) | 10/50 (20%) | 18/50 (36%)
Adjusted rate^g^ | 10.96% | 19.14% | 23.84% | 42.28%
Terminal rate^h^ | 4/39 (10%) | 7/30 (23%) | 9/34 (26%) | 16/31 (52%)
First incidence (days) | 557 | 554 | 716 | 542
Poly-3 test^i^ | p < 0.001 | p = 0.220 | p = 0.093 | p < 0.001
Alveolar/Bronchiolar Carcinoma, Multiple | 1 | 1 | 3 | 4
Alveolar/Bronchiolar Carcinoma (Includes Multiple)^j^
Overall rate | 9/50 (18%) | 6/50 (12%) | 14/50 (28%) | 13/50 (26%)
Adjusted rate | 19.97% | 13.89% | 33.42% | 30.63%
Terminal rate | 9/39 (23%) | 3/30 (10%) | 14/34 (41%) | 11/31 (35%)
First incidence (days) | 729 (T) | 432 | 729 (T) | 563
Poly-3 test | p = 0.060 | p = 0.851 | p = 0.118 | p = 0.182
Alveolar/Bronchiolar Adenoma or Alveolar/Bronchiolar Carcinoma (Combined, Includes Multiple)^k^
Overall rate | 14/50 (28%) | 14/50 (28%) | 21/50 (42%) | 26/50 (52%)
Adjusted rate | 30.69% | 32% | 50.07% | 59.98%
Terminal rate | 13/39 (33%) | 10/30 (33%) | 20/34 (59%) | 22/31 (71%)
First incidence (days) | 557 | 432 | 716 | 542
Poly-3 test | p = 0.001 | p = 0.538 | p = 0.048 | p = 0.003
Female
n | 50 | 50 | 39 | 50
Alveolar/Bronchiolar, Epithelium, Hyperplasia | 0** | 10** (2.1) | 6** (1.8) | 17** (3.1)
Alveolar/Bronchiolar Adenoma, Multiple | 0 | 1 | 3 | 7
Alveolar/Bronchiolar Adenoma (Includes Multiple)^l^
Overall rate | 2/50 (4%) | 8/50 (16%) | 9/39 (23%) | 17/50 (34%)
Adjusted rate | 4.53% | 18.93% | 26.42% | 40.19%
Terminal rate | 1/33 (3%) | 7/29 (24%) | 8/24 (33%) | 13/24 (54%)
First incidence (days) | 450 | 730 | 697 | 628
Poly-3 test | p < 0.001 | p = 0.037 | p = 0.006 | p < 0.001
Alveolar/Bronchiolar Carcinoma, Multiple | 0 | 0 | 0 | 15
Alveolar/Bronchiolar Carcinoma (Includes Multiple)^m^
Overall rate | 1/50 (2%) | 2/50 (4%) | 6/39 (15%) | 23/50 (46%)
Adjusted rate | 2.29% | 4.62% | 16.93% | 52.53%
Terminal rate | 0/33 (0%) | 0/29 (0%) | 2/24 (8%) | 12/24 (50%)
First incidence (days) | 657 | 380 | 563 | 519
Poly-3 test | p < 0.001 | p = 0.497 | p = 0.027 | p < 0.001
Alveolar/Bronchiolar Adenoma or Alveolar/Bronchiolar Carcinoma (Combined, Includes Multiple)^n^
Overall rate | 3/50 (6%) | 10/50 (20%) | 15/39 (38%) | 37/50 (74%)
Adjusted rate | 6.75% | 23.09% | 42.18% | 83.26%
Terminal rate | 1/33 (3%) | 7/29 (24%) | 10/24 (42%) | 22/24 (92%)
First incidence (days) | 450 | 380 | 563 | 519
Poly-3 test | p < 0.001 | p = 0.029 | p < 0.001 | p < 0.001

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

(T) = terminal euthanasia.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion. For nonneoplastic lesions, each exposed group was compared to the 0 ppm chamber group using the Poly-3 test.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ No statistical analyses were performed on multiplicity data.

^e^ Historical control incidence for 2-year inhalation studies (mean ± standard deviation): 20/150 (13.33% ± 7.57%); range: 8% to 22%; all routes: 63/440 (14.31% ± 4.71%); range: 8% to 22%.

^f^ Number of animals with neoplasm/number of animals necropsied.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Observed incidence at study termination.

^i^ Beneath the 0 ppm chamber group incidence is the p value associated with the trend test. Beneath the exposed group incidence is the p value corresponding to pairwise comparisons between the 0 ppm chamber group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. All trend and pairwise p values are reported as one-sided.

^j^ Historical control incidence for 2-year inhalation studies: 21/150 (14% ± 3.46%); range: 12% to 18%; all routes: 42/440 (9.06% ± 6.01%); range: 2% to 18%.

^k^ Historical control incidence for 2-year inhalation studies: 41/150 (27.33% ± 7.02%); range: 20% to 34%; all routes: 101/440 (22.69% ± 6.29%); range: 14% to 34%.

^l^ Historical control incidence for 2-year inhalation studies: 10/150 (6.67% ± 3.06%); range: 4% to 10%; all routes: 21/490 (4.37% ± 2.81%); range: 0% to 10%.

^m^ Historical control incidence for 2-year inhalation studies: 4/150 (2.67% ± 3.06%); range: 0% to 6%; all routes: 15/490 (3.04% ± 2.24%); range: 0% to 6%.

^n^ Historical control incidence for 2-year inhalation studies: 14/150 (9.33% ± 3.06%); range: 6% to 12%; all routes: 36/490 (7.41% ± 2.61%); range: 4% to 12%.

Alveolar/bronchiolar adenomas were well-demarcated neoplasms composed of cuboidal to columnar epithelial cells with solid or papillary growth patterns, scant fibrovascular stroma, and little to no mitotic activity (Figure 21). Alveolar/bronchiolar adenomas compressed the adjacent pulmonary parenchyma and demonstrated loss of the normal alveolar/bronchiolar architecture.

Figure 21

Representative Image of Alveolar/Bronchiolar Adenoma in the Lung of a Female Mouse in the Two-year Inhalation Study of α-Pinene (H&E)

The lung alveolar/bronchiolar adenoma is a well-circumscribed lesion, with some compression of the surrounding parenchyma (4×). Representative lesion depicted is from a 400 ppm female mouse. H&E = hematoxylin and eosin stain.

Alveolar/bronchiolar carcinomas tended to be larger than adenomas, involving much of the lung lobe, sometimes creating gross distortion of the tissue (Figure 22A). Alveolar/bronchiolar carcinomas were further distinguished from adenomas by stratification or piling up of cells, the presence of multiple growth patterns within the same neoplasm, cellular pleomorphism, increased mitotic activity, and/or the presence of extrapulmonary metastases (Figure 22B, Figure 22C). Occasionally, alveolar/bronchiolar carcinomas exhibited squamous differentiation.

Figure 22

Representative Images of Alveolar/Bronchiolar Carcinoma in the Lung of a Female Mouse in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Lung alveolar/bronchiolar carcinomas (e.g., the example shown from a 400 ppm female mouse) tended to be larger than alveolar/bronchiolar adenomas. This carcinoma has replaced much of the lung lobe and caused gross distortion of the normal lung lobe shape (1×). (B) A higher magnification of the alveolar/bronchiolar carcinoma in panel A shows areas of stratification or piling up of the cells (arrows); this was consistent with a malignant growth pattern (20×). (C) A higher magnification of panel A. The cells of alveolar/bronchiolar carcinomas displayed marked pleomorphism, and mitotic figures (arrows) were more common than in alveolar/bronchiolar adenomas (40×). H&E = hematoxylin and eosin stain.

The incidence of alveolar/bronchiolar epithelium hyperplasia was significantly increased in all exposed groups of male and female mice with a positive trend (Table 16). In female mice, the average severity grade increased with increasing exposure concentration. Hyperplasia of the alveolar/bronchiolar epithelium was a focal or multifocal lesion that did not disrupt the alveolar architecture and demonstrated little or no compression of the adjacent pulmonary parenchyma. Alveolar/bronchiolar epithelial hyperplasia exhibited the following growth patterns: extension of cuboidal to low columnar bronchiolar-type epithelium into peribronchiolar alveoli (bronchiolization), proliferation of terminal bronchiolar epithelium resulting in formation of short papillary fronds that projected into bronchiolar lumina, and/or hyperplasia of cuboidal type II pneumocytes (Figure 23A, Figure 23B) with occasional binucleation.

Figure 23

Representative Images of Alveolar/Bronchiolar Epithelium Hyperplasia in the Lung of a Male Mouse in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Lung alveolar/bronchiolar epithelial hyperplasia often occurred as focal, poorly demarcated areas where type II pneumocytes (Type 2 cells) had replaced the type I pneumocytes (Club cells) that normally line the alveolar septae (circled area), as observed in a 200 ppm male mouse. In contrast to adenomas, the normal alveolar pattern of the lung was still visible within hyperplastic lesions (10×). (B) A higher magnification of the area of hyperplasia of the alveolar/bronchiolar epithelium from panel A shows the cuboidal type II pneumocytes that have replaced the normally flat type I pneumocyte (40×). H&E = hematoxylin and eosin stain.

Mammary gland: In female mice, there was a positive trend, and the incidence of mammary gland adenocarcinoma was significantly increased in the 400 ppm group and exceeded the historical control rate (Table 17). The incidence of adenoma or adenocarcinoma (combined) was also significantly increased in the 400 ppm group with a positive trend.

Table 17 Incidences of Neoplasms of the Mammary Gland in Female B6C3F1/N Mice in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 100 ppm | 200 ppm | 400 ppm
n^a^ | 48 | 46 | 40 | 48
Adenoma^b,c^ | 0 | 0 | 1 | 0
Adenocarcinoma^d^
Overall rate^e^ | 0/48 (0%) | 0/46 (0%) | 0/40 (0%) | 5/48 (10%)
Adjusted rate^f^ | 0% | 0% | 0% | 12.52%
Terminal rate^g^ | 0/32 (0%) | 0/27 (0%) | 0/24 (0%) | 4/24 (17%)
First incidence (days) | –^h^ | – | – | 683
Poly-3 test^i^ | p < 0.001 | (e) | (e) | p = 0.026
Adenoma or Adenocarcinoma (Combined)^j^
Overall rate | 0/48 (0%) | 0/46 (0%) | 1/40 (3%) | 5/48 (10%)
Adjusted rate | 0% | 0% | 2.93% | 12.52%
Terminal rate | 0/32 (0%) | 0/27 (0%) | 1/24 (4%) | 4/24 (17%)
First incidence (days) | – | – | 731 (T) | 683
Poly-3 test | p = 0.001 | (e) | p = 0.458 | p = 0.026

(e) = value of statistic could not be computed; (T) = terminal euthanasia.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Historical control incidence for 2-year inhalation studies (mean ± standard deviation): 0/150 (0% ± 0%); range: 0% to 0%; all routes: 3/490 (0.67% ± 1.41%); range: 0% to 4%.

^d^ Historical control incidence for 2-year inhalation studies (mean ± standard deviation): 0/150 (0% ± 0%); range: 0% to 0%; all routes: 1/490 (0.22% ± 0.67%); range: 0% to 2%.

^e^ Number of animals with neoplasm/number of animals necropsied.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at study termination.

^h^ Not applicable; no neoplasms in group.

^i^ Beneath the 0 ppm chamber group incidence is the p value associated with the trend test. Beneath the exposed group incidence is the p value corresponding to pairwise comparisons between the 0 ppm chamber group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. All trend and pairwise p values are reported as one-sided.

^j^ Historical control incidence for 2-year inhalation studies (mean ± standard deviation): 0/150 (0% ± 0%); range: 0% to 0%; all routes: 4/490 (0.89% ± 1.45%); range: 0% to 4%.

Mammary gland adenocarcinomas were poorly demarcated, expansile masses composed of neoplastic glandular epithelial cells arranged as variably sized and shaped tubulo-acini and/or solid structures within a fibrous to fibrovascular stroma (Figure 24A). Disorganized neoplastic glandular epithelial cells were highly pleomorphic with poorly delineated cell margins, had euchromatic oval nuclei and moderate amounts of eosinophilic cytoplasm, and demonstrated increased mitotic activity. There were often areas of neoplastic capsular invasion and/or necrosis (Figure 24B).

Figure 24

Representative Images of Adenocarcinoma in the Mammary Gland in Female Mice in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Mammary gland adenocarcinomas like the one in this image from a 400 ppm female mouse tended to be large, densely cellular tumors (1×). (B) A higher magnification of a mammary gland adenocarcinoma in a different 400 ppm female mouse than panel A shows clusters of disorganized epithelial cells. An area of necrosis is visible on the right side of the image (asterisk) (10×). H&E = hematoxylin and eosin stain.

Urinary bladder: In male mice, there was a positive trend and higher incidence of urinary bladder papilloma in the 400 ppm group (Table 18). Although not statistically significant, the incidence exceeded the historical control rate for all routes of exposure. Urinary papillomas were exophytic, pedunculated masses that extended from the urinary bladder mucosa into the urinary bladder lumen. They were composed of uniform urothelial cells arranged in papillary fronds supported by a core of fibrovascular stroma (Figure 25).

Table 18 Incidences of Neoplastic and Nonneoplastic Lesions of the Urinary Bladder in Male and Female B6C3F1/N Mice in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 100 ppm | 200 ppm | 400 ppm
Male
n^a^ | 48 | 43 | 48 | 45
Urothelium, Hyperplasia^b^ | 1** (4.0)^c^ | 7* (1.0) | 18** (1.6) | 15** (1.5)
Infiltration Cellular, Lymphocyte | 1** (1.0) | 2 (1.0) | 9** (1.1) | 9** (1.4)
Inflammation, Suppurative | 0** | 2 (2.0) | 0 | 5* (1.6)
Papilloma^d^
Overall rate^e^ | 0/48 (0%) | 0/43 (0%) | 0/48 (0%) | 3/45 (7%)
Adjusted rate^f^ | 0% | 0% | 0% | 7.67%
Terminal rate^g^ | 0/39 (0%) | 0/30 (0%) | 0/34 (0%) | 1/31 (3%)
First incidence (days) | –^h^ | – | – | 603
Poly-3 test^i^ | p = 0.010 | (e) | (e) | p = 0.098
Female
n | 45 | 43 | 34 | 46
Urothelium, Hyperplasia | 0** | 5* (1.4) | 11** (1.0) | 20** (1.4)

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

(e) = value of statistic could not be computed.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion. For nonneoplastic lesions, each exposed group was compared to the 0 ppm chamber group using the Poly-3 test.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for 2-year inhalation studies (mean ± standard deviation): 0/148 (0% ± 0%); range: 0% to 0%; all routes: 0/434 (0% ± 0%); range: 0% to 0%.

^e^ Number of animals with neoplasm/number of animals necropsied.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at study termination.

^h^ Not applicable; no neoplasms in group.

^i^ Beneath the 0 ppm chamber group incidence is the p value associated with the trend test. Beneath the exposed group incidence is the p value corresponding to pairwise comparisons between the 0 ppm chamber group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. All trend and pairwise p values are reported as one-sided.

Figure 25

Representative Image of Papilloma in the Urinary Bladder of a Male Mouse in the Two-year Inhalation Study of α-Pinene (H&E)

Urinary bladder papilloma in this 400 ppm male mouse is visible at low magnification. It arises from the urothelium and consists of papillary projections off a central fibrovascular stalk (arrow). The adjacent urothelium is hyperplastic (2×). H&E = hematoxylin and eosin stain.

The incidence of urinary bladder urothelium hyperplasia was significantly increased in all exposed groups of male and female mice with a positive trend (Table 18). Urothelium hyperplasia of the urinary bladder was characterized by increased numbers of urothelial cells (particularly in the basal cell layer), increased cytoplasmic basophilia, and/or increased mucosal thickness (>5 cells thick) compared to the urothelium of control animals (Figure 26).

Figure 26

Representative Images of Control Urothelium and Diffuse Hyperplasia in the Bladder of a Male Mouse in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Urinary bladder in a control male mouse showing normal urothelium (arrows) (10×). (B) Urinary bladder diffuse hyperplasia of the urothelium in a 400 ppm male mouse. Compared to the bladder from the 0 ppm animal, there are more layers of epithelial cells, and the basal layer of cells is more crowded (thin arrows). This animal also has a focal infiltration of lymphocytes (thick arrow) in the submucosa (10×). H&E = hematoxylin and eosin stain.

The incidence of lymphocytic cellular infiltration in the urinary bladder was significantly increased in male mice exposed to 200 or 400 ppm α-pinene and exhibited a positive trend (Table 18). Lymphocytic cellular infiltration in the urinary bladder was characterized by increased numbers of submucosal perivascular lymphocytes or, less frequently, clusters or nodular aggregates of lymphocytes within the submucosa (Figure 26). There was a positive trend in suppurative inflammation in the urinary bladder that was significantly increased in male mice exposed to 400 ppm α-pinene.

Ovary: There were higher incidences of benign granulosa cell tumor in the ovary in all exposed groups of female mice (Table 19). There was a positive trend, and the incidence of malignant granulosa cell tumor in the ovary was higher in the 400 ppm group; however, the incidence was not statistically significant. The incidence of granulosa cell tumor, benign, malignant (combined) was significantly increased in female mice exposed to 400 ppm α-pinene and exhibited a positive trend.

Table 19 Incidences of Neoplastic and Nonneoplastic Lesions of the Ovary in Female B6C3F1/N Mice in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 100 ppm | 200 ppm | 400 ppm
n^a^ | 48 | 49 | 36 | 46
Hyperplasia, Tubulostromal (Includes Bilateral)^b^ | 1** (1.0)^c^ | 18** (1.6) | 21** (1.9) | 28** (2.8)
Granulosa Cell Tumor, Benign^d^ | 0 | 2 | 2 | 2
Granulosa Cell Tumor, Malignant^e^ | 0* | 1 | 0 | 3
Granulosa Cell Tumor, Benign, Malignant (Combined)^f^
Overall rate^g^ | 0/48 (0%) | 3/49 (6%) | 2/36 (6%) | 5/46 (11%)
Adjusted rate^h^ | 0% | 7.11% | 6.11% | 12.85%
Terminal rate^i^ | 0/32 (0%) | 2/29 (7%) | 2/24 (8%) | 3/22 (14%)
First incidence (days) | –^j^ | 702 | 731 (T) | 644
Poly-3 test^k^ | p = 0.024 | p = 0.121 | p = 0.184 | p = 0.024
Tubulostromal Adenoma^l^
Overall rate | 0/48 (0%) | 0/49 (0%) | 1/36 (3%) | 7/46 (15%)
Adjusted rate | 0% | 0% | 3.06% | 18.03%
Terminal rate | 0/32 (0%) | 0/29 (0%) | 1/24 (4%) | 4/22 (18%)
First incidence (days) | – | – | 731 (T) | 683
Poly-3 test | p < 0.001 | (e) | p = 0.452 | p = 0.005

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

(T) = terminal euthanasia; (e) = value of statistic could not be computed.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion. For nonneoplastic lesions, each exposed group was compared to the 0 ppm chamber group using the Poly-3 test.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for 2-year inhalation studies (mean ± standard deviation): 0/146 (0% ± 0%); range: 0% to 0%; all routes: 2/465 (0.37% ± 0.76%); range: 0% to 2%.

^e^ Historical control incidence for 2-year inhalation studies: 0/146 (0% ± 0%); range: 0% to 0%; all routes: 0/465 (0% ± 0%); range: 0% to 0%.

^f^ Historical control incidence for 2-year inhalation studies: 0/146 (0% ± 0%); range: 0% to 0%; all routes: 2/465 (0.37% ± 0.76%); range: 0% to 2%.

^g^ Number of animals with neoplasm/number of animals necropsied.

^h^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^i^ Observed incidence at study termination.

^j^ Not applicable; no neoplasms in group.

^k^ Beneath the 0 ppm chamber group incidence is the p value associated with the trend test. Beneath the exposed group incidence is the p value corresponding to pairwise comparisons between the 0 ppm chamber group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. All trend and pairwise p values are reported as one-sided.

^l^ Historical control incidence for 2-year inhalation studies: 0/146 (0% ± 0%); range: 0% to 0%; all routes: 1/465 (0.23% ± 0.68%); range: 0% to 2%.

Benign granulosa cell tumors were expansile masses composed of polygonal cells with round to oval nuclei and scant eosinophilic cytoplasm resembling granulosa cells arranged in cords and trabeculae supported by scant fibrovascular stroma. Occasionally, fluid or blood-filled cystic spaces were present within the neoplasms. Malignant granulosa cell tumors were expansile masses similarly composed of polygonal cells with round to oval nuclei and scant eosinophilic cytoplasm resembling granulosa cells. Malignant granulosa cell tumors were distinguished from benign granulosa cell tumors by the presence of cellular atypia and pleomorphism, multiple growth patterns, and a high mitotic rate. Focal areas of necrosis and hemorrhage and/or local invasion may be present.

There was a positive trend, and the incidence of tubulostromal adenoma was significantly increased in the 400 ppm group (Table 19). Ovarian tubulostromal adenomas were characterized by nodular structures consisting of delicate tubules lined by low cuboidal epithelium that was continuous with that of the ovary surface epithelium (Figure 27A). Tubules were densely packed (Figure 27B) or separated by cords and packets of sex cord stromal cells and/or macrophages. The incidence of tubulostromal hyperplasia was significantly increased in all exposed groups of female mice with a positive trend (Table 19). Ovarian tubulostromal adenomas were distinguished from marked tubulostromal hyperplasia by lesion size (larger than a normal corpus luteum) and/or compression or replacement of the remaining ovarian tissue.

Figure 27

Representative Images of Tubulostromal Adenoma in the Ovary of a Female Mouse in the Two-year Inhalation Study of α-Pinene (H&E)

(A) The ovary tubulostromal adenoma (arrows) involves half of the ovary in a 400 ppm female mouse, and even at low magnification, the uniform cellular pattern is apparent. There is also tubulostromal hyperplasia in the ovary (asterisk) (2×). (B) A higher magnification of the tubulostromal adenoma in panel A. The ovarian tumor is a solid mass of ribbons and tubules of low cuboidal cells with basally located, oval, basophilic nuclei, morphologically similar to the cells in tubulostromal hyperplasia (20×). H&E = hematoxylin and eosin stain.

Ovarian tubulostromal hyperplasia was minimal to mild in severity and was characterized by the extension of the ovarian surface epithelium into the ovary that formed ribbons and fine tubules of low cuboidal epithelium (Figure 28A). The tubules or ribbons were either densely packed or separated by cords and packets of sex cord stromal cells and/or macrophages of varying quantities (Figure 28B).

Figure 28

Representative Images of Tubulostromal Hyperplasia in the Ovary of a Female Mouse in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Ovary tubulostromal hyperplasia in a 400 ppm female mouse. There are areas throughout the ovary with basophilic ribbons of cells (arrows) forming tubules (4×). (B) A higher magnification of the tubulostromal hyperplasia from panel A. The surface epithelium forms invaginations into the ovary (thin arrows), and the basophilic, cuboidal epithelium is arranged in tubules (thick arrows), which are separated by clusters of macrophages that have abundant foamy eosinophilic cytoplasm (asterisks) (20×). H&E = hematoxylin and eosin stain.

Stomach, forestomach: In male mice, there was a positive trend and higher incidence of forestomach papilloma in the 200 and 400 ppm groups (Table 20). Papillomas of the forestomach were exophytic proliferations of the mucosal squamous epithelium that projected from the mucosal surface as frond-like proliferations supported by a fibrous stalk (Figure 29A).

Table 20 Incidences of Neoplastic and Nonneoplastic Lesions of the Stomach of Male and Female B6C3F1/N Mice in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 100 ppm | 200 ppm | 400 ppm
Male
n^a^ | 49 | 49 | 50 | 48
Forestomach, Epithelium, Hyperplasia, Focal^b^ | 1 (1.0)^c^ | 2 (2.5) | 2 (2.5) | 4 (1.8)
Forestomach, Papilloma^d^
Overall rate^e^ | 0/49 (0%) | 0/49 (0%) | 2/50 (4%) | 3/48 (6%)
Adjusted rate^f^ | 0% | 0% | 4.73% | 7.38%
Terminal rate^g^ | 0/39 (0%) | 0/30 (0%) | 1/34 (3%) | 2/31 (6%)
First incidence (days) | –^h^ | – | 624 | 609
Poly-3 test^i^ | p = 0.022 | (e) | p = 0.224 | p = 0.102
Female
n | 49 | 49 | 38 | 49
Forestomach, Epithelium, Hyperplasia, Focal | 0** | 0 | 0 | 5* (2.2)
Forestomach, Squamous Cell Carcinoma^j^
Overall rate | 0/49 (0%) | 0/49 (0%) | 0/38 (0%) | 2/49 (4%)
Adjusted rate | 0% | 0% | 0% | 4.9%
Terminal rate | 0/33 (0%) | 0/29 (0%) | 0/24 (0%) | 1/24 (4%)
First incidence (days) | – | – | – | 716
Poly-3 test | p = 0.047 | (e) | (e) | p = 0.227

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

(e) = value of statistic could not be computed.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion. For nonneoplastic lesions, each exposed group was compared to the 0 ppm chamber group using the Poly-3 test.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for 2-year inhalation studies (mean ± standard deviation): 1/150 (0.67% ± 1.15%); range: 0% to 2%; all routes: 1/440 (0.25% ± 0.71%); range: 0% to 2%.

^e^ Number of animals with neoplasm/number of animals necropsied.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at study termination.

^h^ Not applicable; no neoplasms in group.

^i^ Beneath the 0 ppm chamber group incidence is the p value associated with the trend test. Beneath the exposed group incidence is the p value corresponding to pairwise comparisons between the 0 ppm chamber group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. All trend and pairwise p values are reported as one-sided.

^j^ Historical control incidence for 2-year inhalation studies (mean ± standard deviation): 0/149 (0.0% ± 0.0%); range: 0% to 0%; all routes: 0/489 (0.0% ± 0.0%); range: 0% to 0%.

Figure 29

Representative Images of Papilloma, Squamous Cell Carcinoma, and Hyperplasia in the Forestomach of Male and Female Mice in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Forestomach papilloma in a 400 ppm male occurred as frond-like proliferations of squamous epithelium (arrows) supported by a fibrous stalk (asterisk), extending from the mucosal surface (2×). (B) Forestomach squamous cell carcinoma in a 400 ppm female mouse has invaded and effaced the mucosa, submucosa lamina propria, and smooth muscle layers (arrows) (4×). (C) Forestomach hyperplasia in a 400 ppm male mouse occurred as a focal proliferation of thickened squamous epithelium, which was often accompanied by hyperkeratosis (arrows) (4×). (D) A higher magnification of the tissue in panel C. Focal hyperplasia in the forestomach was sometimes associated with inflammation (arrows). The epithelium was not anaplastic and did not display invasion into the underlying lamina propria (10×). H&E = hematoxylin and eosin stain.

In female mice, there was a positive trend and higher incidence of squamous cell carcinoma in the 400 ppm group. The incidence of focal hyperplasia in the forestomach epithelium was significantly increased in the 400 ppm group and exhibited a positive trend (Table 20). Squamous cell carcinomas were masses composed of dysplastic, anaplastic squamous epithelium that invaded and effaced the mucosa and underlying submucosal tissue (lamina propria), in one case extending into the muscle layers to the serosal surface of the forestomach (Figure 29B). Focal hyperplasia of the forestomach epithelium was characterized by variably well-demarcated areas of increased mucosal thickness, sometimes resulting in the formation of short papillary projections into the lumen and/or rete peg-like structures extending into the submucosa (lamina propria) (Figure 29C). Hyperkeratosis was often seen when hyperplasia of the mucosa was present. Inflammation in the submucosa may also be present (Figure 29D).

Testis: The incidences of degeneration and degeneration or atrophy (combined) in the germinal epithelium of the testis exhibited a positive trend and were significantly increased in male mice exposed to 400 ppm α-pinene (Table 21). There was a positive trend in the incidence of atrophy in the germinal epithelium of the testis. Degeneration of the germinal epithelium of the testis was characterized by disorganization/depletion of the germinal epithelium with or without multinucleated cells and vacuolation (Figure 30A, Figure 30B).

Table 21 Incidences of Select Nonneoplastic Lesions in the Testis and Epididymis of Male B6C3F1/N Mice in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 100 ppm | 200 ppm | 400 ppm
Testis^a^ | 50 | 49 | 50 | 47
Germinal epithelium, degeneration (includes bilateral)^b^ | 14** (1.4)^c^ | 9 (1.8) | 15 (1.4) | 28** (1.4)
Germinal epithelium, atrophy (includes bilateral) | 2* (2.5) | 1 (2.0) | 3 (2.0) | 6 (2.0)
Germinal epithelium, degeneration or atrophy (combined, includes bilateral) | 14** (1.6) | 9 (1.8) | 16 (1.4) | 28** (1.5)
Epididymis | 50 | 49 | 50 | 48
Duct, exfoliated germ cell (includes bilateral) | 2** (1.0) | 5 (1.2) | 2 (1.0) | 18** (1.2)

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion. Each exposed group was compared to the 0 ppm chamber group using the Poly-3 test.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 30

Representative Images of Control Germinal Epithelium and Germinal Epithelial Degeneration in the Testis of a Male Mouse in the Two-year Inhalation Study of α-Pinene (H&E)

(A) Testis germinal epithelium in a control male mouse (arrows) (10×). (B) Compared to the control mouse testis, the germinal epithelial degeneration in a 400 ppm male mouse is characterized by tubules that have a loss or disorganization of the normal germ cell layers (arrows) (10×). (C) A higher magnification of germinal epithelium from panel B shows tubules that have few remaining germ cells left (asterisks). Vacuolation of the germinal epithelium (arrow) was another change observed with degeneration (20×). H&E = hematoxylin and eosin stain.

Epididymis: In male mice, the incidence of exfoliated germ cells in the epididymal ducts was significantly increased in the 400 ppm group with a positive trend (Table 21). Exfoliated germ cells in the duct of the epididymis were minimal in severity and were characterized by the presence of sloughed testicular germ cells and/or cell debris within the ductular lumen (Figure 31).

Figure 31

Representative Image of Exfoliated Germ Cells in the Epididymal Ducts in a Male Mouse in the Two-year Inhalation Study of α-Pinene (H&E)

Epididymal ducts contain numerous exfoliated germ cells (arrows) in this 400 ppm male mouse (40×). H&E = hematoxylin and eosin stain.

Other lesions: In addition to the lesions described above, significant increases in nonneoplastic lesions were observed in the preputial gland in male mice (Appendix G). The biological and toxicological significance of these lesions is not known.

## Reproductive Assessment in Rats and Mice

### Three-month Reproductive Study in Rats

As described in the methods, sperm parameter data are not presented for rats because of the presence of artifacts (e.g., clumping of cells, too many sperm in sample).

Negative trends were observed for both left and right absolute epididymis and testis weights (Table 22). There were significant decreases in the 400 ppm group for absolute left and right epididymis (6%) and testis weights (8%–9%) with corresponding significant decreases in the relative left and right testis weights. There was a positive trend in the incidences of atrophy and degeneration or atrophy (combined) in the germinal epithelium of the testis with no incidences in any group except the 400 ppm group, which had two (Appendix G). No histopathological lesions in the epididymis were attributed to α-pinene exposure.

Table 22 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male Rats in the Three-month Reproductive Study of α-Pinene

| 0 ppm | 100 ppm | 200 ppm | 400 ppm
n | 25 | 25 | 25 | 25
Terminal Body Wt. (g)^a,b^ | 411.4 ± 6.3 | 420.4 ± 7.0 | 411.9 ± 4.6 | 406.1 ± 4.7
Right Epididymis
Absolute (g) | 0.6290 ± 0.0095** | 0.6379 ± 0.0095 | 0.6309 ± 0.0104 | 0.5901 ± 0.0178*
Relative (mg/g)^c^ | 1.53 ± 0.02 | 1.52 ± 0.02 | 1.54 ± 0.03 | 1.46 ± 0.05
Left Epididymis
Absolute (g) | 0.6428 ± 0.0092** | 0.6510 ± 0.0073 | 0.6415 ± 0.0078 | 0.6051 ± 0.0148*
Relative (mg/g) | 1.57 ± 0.03 | 1.55 ± 0.02 | 1.56 ± 0.02 | 1.49 ± 0.04
Right Testis
Absolute (g) | 1.998 ± 0.024** | 1.976 ± 0.029 | 1.995 ± 0.030 | 1.826 ± 0.063**
Relative (mg/g) | 4.88 ± 0.08 | 4.71 ± 0.06 | 4.85 ± 0.08 | 4.50 ± 0.15*
Left Testis
Absolute (g) | 2.006 ± 0.025* | 1.990 ± 0.027 | 2.012 ± 0.034 | 1.844 ± 0.060*
Relative (mg/g) | 4.89 ± 0.07 | 4.75 ± 0.07 | 4.90 ± 0.09 | 4.55 ± 0.15*

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

### Three-month Study in B6C3F1/N Mice and Three-month Reproductive Study in CD-1 Mice

As described in the methods, sperm parameter data are not presented for B6C3F1/N or CD-1 mice because of the presence of artifacts (e.g., clumping of cells, too many sperm in sample).

In CD-1 mice, there were significant increases in the relative left epididymis and relative left and right testis weights in the 400 ppm group, but they were considered secondary to the marginally lower body weight (Table 23). No histopathological lesions in the testis or epididymis of CD-1 mice were attributed to α-pinene exposure (Appendix G). In B6C3F1/N mice, absolute left and right testis weights were significantly decreased in the 200 and 400 ppm groups (by 7%–8% and 16%, respectively) compared to the control group, and there was a negative trend in the absolute and relative left and right testis weights (Table 23). There was also a negative trend in the absolute right epididymis weights. However, there were no corresponding histopathological lesions in the testis or epididymis of B6C3F1/N mice attributed to α-pinene exposure (Appendix G).

Table 23 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male CD-1 Mice in the Three-month Reproductive Inhalation Study and B6C3F1/N Mice in the Three-month Inhalation Study of α-Pinene

| 0 ppm | 100 ppm | 200 ppm | 400 ppm
CD-1 Male
n | 25 | 25 | 25 | 25
Terminal Body Wt. (g)^a,b^ | 43.7 ± 0.9 | 43.8 ± 0.9 | 43.2 ± 0.8 | 41.4 ± 0.7
Right Epididymis
Absolute (g) | 0.0576 ± 0.0018 | 0.0595 ± 0.0018 | 0.0563 ± 0.0016 | 0.0591 ± 0.0016
Relative (mg/g)^c^ | 1.32 ± 0.03 | 1.37 ± 0.05 | 1.31 ± 0.04 | 1.43 ± 0.04
Left Epididymis
Absolute (g) | 0.0630 ± 0.0016 | 0.0649 ± 0.0014 | 0.0642 ± 0.0020 | 0.0651 ± 0.0017
Relative (mg/g) | 1.44 ± 0.03* | 1.50 ± 0.04 | 1.49 ± 0.04 | 1.58 ± 0.04*
Right Testis
Absolute (g) | 0.130 ± 0.004 | 0.130 ± 0.004 | 0.131 ± 0.006 | 0.137 ± 0.004
Relative (mg/g) | 2.99 ± 0.09** | 2.99 ± 0.11 | 3.05 ± 0.13 | 3.32 ± 0.10*
Left Testis
Absolute (g) | 0.123 ± 0.004 | 0.123 ± 0.004 | 0.125 ± 0.005 | 0.131 ± 0.004
Relative (mg/g) | 2.84 ± 0.09** | 2.84 ± 0.10 | 2.90 ± 0.12 | 3.17 ± 0.10*
B6C3F1/N Male
n | 10 | 10 | 10 | 10
Terminal Body Wt. (g) | 31.7 ± 1.0 | 31.2 ± 1.0 | 31.6 ± 0.6 | 29.2 ± 0.5
Right Epididymis
Absolute (g) | 0.0441 ± 0.0009* | 0.0448 ± 0.0014 | 0.0440 ± 0.0025 | 0.0405 ± 0.0013
Relative (mg/g) | 1.40 ± 0.04 | 1.44 ± 0.03 | 1.39 ± 0.07 | 1.39 ± 0.05
Left Epididymis
Absolute (g) | 0.0477 ± 0.0013 | 0.0474 ± 0.0019 | 0.0457 ± 0.0011 | 0.0454 ± 0.0011
Relative (mg/g) | 1.51 ± 0.05 | 1.52 ± 0.03 | 1.45 ± 0.03 | 1.56 ± 0.05
Right Testis
Absolute (g) | 0.121 ± 0.002** | 0.118 ± 0.002 | 0.112 ± 0.004* | 0.102 ± 0.003**
Relative (mg/g) | 3.86 ± 0.11* | 3.80 ± 0.10 | 3.54 ± 0.13 | 3.52 ± 0.11
Left Testis
Absolute (g) | 0.118 ± 0.002** | 0.116 ± 0.002 | 0.108 ± 0.004* | 0.099 ± 0.003**
Relative (mg/g) | 3.76 ± 0.10* | 3.76 ± 0.12 | 3.42 ± 0.11 | 3.40 ± 0.12

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

### Reproductive Performance in Rats and CD-1 Mice

Twenty-five male Sprague Dawley rats and CD-1 mice were paired with their respective naïve females to determine the reproductive performance of male rats and mice exposed to α-pinene. No exposure-related effects were observed in mating (mated/paired) or pregnancy (pregnant/mated) rates in Sprague Dawley rats or CD-1 mice (Appendix G).

After examination of pregnant female rats on gestation day (GD) 14, there was a negative trend in the number of implantations, and while a smaller litter size (live embryos/litter) was observed in exposed groups, there was no statistical pairwise difference in litter size compared to the control group or in the trend test (Appendix G).

In pregnant CD-1 female mice on GD 14, there were no effects on implantation numbers, pre- or postimplantation loss, or live embryos per litter (Appendix G). In all groups in which the males were exposed, a significant decrease in the number of corpora lutea per female was observed. This decrease reflected the natural variability in the CD-1 model, as females were not exposed to α-pinene and the number of corpora lutea per female is independent of male influence.

## Three-month Investigative Study in Rats

The 3-month investigative study in male and female rats (n = 10) was undertaken to collect samples for evaluation of early biomarkers associated with mammary gland carcinogenesis observed in the 2-year study and evaluation of vaginal cytology and sperm parameters. In addition, blood and mammary gland were collected from male and female rats (n = 5) for evaluation of internal concentrations of α-pinene and α-pinene oxide.

One male rat in the 100 ppm group was euthanized as moribund on study day 84. All other animals survived to study termination (Appendix G). No clinical observations were attributed to α-pinene exposure in male or female rats.

In male rats from study day 21 through study day 77, there was a negative trend in body weights, with minor (5%–7%) but significant decreases in all exposed groups during that period, with few exceptions (Table 24; Figure 32). No exposure-related changes in the body weights of female rats were observed (Table 25; Figure 32).

Table 24 Summary of Survival and Body Weights of Male Rats in the Three-month Investigative Inhalation Study of α-Pinene

Study Day^a^ | 0 ppm | | 50 ppm | | | 100 ppm | | | 200 ppm
Study Day^a^ | Wt. (g)^b,c^ | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n
0 | 150.9 ± 2.9 | 15 | 149.0 ± 2.7 | 98.7 | 15 | 149.4 ± 2.9 | 99.0 | 15 | 149.5 ± 3.2 | 99.1 | 15
7 | 195.4 ± 2.9 | 15 | 189.4 ± 3.3 | 96.9 | 15 | 191.6 ± 3.4 | 98.0 | 15 | 191.6 ± 3.4 | 98.0 | 15
14 | 238.3 ± 3.1 | 15 | 231.0 ± 3.9 | 96.9 | 15 | 231.2 ± 4.3 | 97.0 | 15 | 229.9 ± 3.5 | 96.5 | 15
21 | 272.5 ± 2.9* | 15 | 261.3 ± 3.8 | 95.9 | 15 | 260.0 ± 4.7 | 95.4 | 15 | 260.3 ± 3.6 | 95.5 | 15
28 | 298.2 ± 3.0* | 15 | 281.5 ± 3.9* | 94.4 | 15 | 281.2 ± 5.1* | 94.3 | 15 | 282.1 ± 3.9* | 94.6 | 15
35 | 318.5 ± 3.7* | 15 | 300.4 ± 4.1* | 94.3 | 15 | 301.1 ± 5.8* | 94.5 | 15 | 301.6 ± 4.2* | 94.7 | 15
42 | 340.4 ± 4.2** | 15 | 319.2 ± 4.3** | 93.8 | 15 | 319.0 ± 6.3** | 93.7 | 15 | 319.7 ± 4.7** | 93.9 | 15
49 | 353.5 ± 4.0* | 15 | 331.8 ± 4.5* | 93.9 | 15 | 333.8 ± 6.5* | 94.4 | 15 | 333.9 ± 5.3* | 94.5 | 15
56 | 367.5 ± 4.6** | 15 | 342.8 ± 4.6** | 93.3 | 15 | 346.1 ± 6.9** | 94.2 | 15 | 343.8 ± 5.2** | 93.6 | 15
63 | 379.0 ± 4.8** | 15 | 352.2 ± 5.0** | 92.9 | 15 | 356.6 ± 7.0** | 94.1 | 15 | 353.5 ± 5.5** | 93.3 | 15
70 | 386.2 ± 5.6* | 15 | 362.0 ± 5.3* | 93.7 | 15 | 366.7 ± 7.4 | 95.0 | 15 | 364.4 ± 6.1* | 94.4 | 15
77 | 397.4 ± 5.4* | 15 | 369.9 ± 6.0** | 93.1 | 15 | 375.1 ± 7.6* | 94.4 | 15 | 373.8 ± 6.1* | 94.1 | 15
84 | 404.0 ± 5.7 | 15 | 376.6 ± 6.2* | 93.2 | 15 | 381.4 ± 8.0 | 94.4 | 15 | 383.9 ± 6.7 | 95.0 | 15

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Study day 0 is the day animals were placed on study.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Weights shown are mean ± standard error.

Figure 32

Growth Curves for Male and Female Rats in the Three-month Investigative Inhalation Study of α-Pinene

Growth curves are shown for (A) males and (B) females.

Table 25 Summary of Survival and Body Weights of Female Rats in the Three-month Investigative Inhalation Study of α-Pinene

Study Day^a^ | 0 ppm | | 50 ppm | | | 100 ppm | | | 200 ppm
Study Day^a^ | Wt. (g)^b,c^ | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n
0 | 125.1 ± 1.5 | 15 | 125.5 ± 1.6 | 100.3 | 15 | 126.0 ± 1.6 | 100.7 | 15 | 123.9 ± 1.3 | 99.0 | 15
7 | 147.7 ± 2.0 | 15 | 145.9 ± 2.3 | 98.8 | 15 | 148.3 ± 2.1 | 100.4 | 15 | 147.6 ± 1.6 | 100.0 | 15
14 | 167.3 ± 2.6 | 15 | 164.4 ± 2.4 | 98.2 | 15 | 168.4 ± 2.7 | 100.6 | 15 | 163.6 ± 1.7 | 97.8 | 15
21 | 181.4 ± 2.6 | 15 | 178.0 ± 2.6 | 98.1 | 15 | 183.9 ± 2.8 | 101.4 | 15 | 179.7 ± 1.8 | 99.1 | 15
28 | 195.6 ± 3.1 | 15 | 192.3 ± 3.1 | 98.3 | 15 | 196.2 ± 3.0 | 100.3 | 15 | 189.8 ± 2.3 | 97.0 | 15
35 | 202.7 ± 3.0 | 15 | 202.5 ± 3.1 | 99.9 | 15 | 210.6 ± 3.5 | 103.9 | 15 | 201.4 ± 2.2 | 99.4 | 15
42 | 213.4 ± 3.7 | 15 | 210.4 ± 3.0 | 98.6 | 15 | 220.1 ± 3.6 | 103.1 | 15 | 207.7 ± 2.5 | 97.3 | 15
49 | 220.1 ± 3.3 | 15 | 219.6 ± 3.8 | 99.8 | 15 | 226.4 ± 3.9 | 102.9 | 15 | 218.3 ± 2.6 | 99.1 | 15
56 | 228.0 ± 3.7 | 15 | 223.4 ± 3.4 | 98.0 | 15 | 231.1 ± 3.6 | 101.4 | 15 | 224.0 ± 2.6 | 98.2 | 15
63 | 231.8 ± 3.9 | 15 | 226.8 ± 3.1 | 97.9 | 15 | 238.4 ± 3.5 | 102.9 | 15 | 227.5 ± 2.8 | 98.1 | 15
70 | 235.0 ± 3.4 | 15 | 232.3 ± 3.5 | 98.8 | 15 | 242.5 ± 3.6 | 103.2 | 15 | 230.7 ± 3.2 | 98.2 | 15
77 | 236.1 ± 3.4 | 15 | 233.6 ± 4.4 | 98.9 | 14^d^ | 244.2 ± 3.5 | 103.4 | 15 | 231.6 ± 2.8 | 98.1 | 15
84 | 237.9 ± 3.4 | 15 | 235.8 ± 3.6 | 99.1 | 15 | 243.9 ± 3.9 | 102.5 | 15 | 233.9 ± 2.8 | 98.3 | 15

^a^ Study day 0 is the day animals were placed on study.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests. No statistically significant findings were noted at p ≤ 0.05.

^c^ Weights shown are mean ± standard error.

^d^ One animal weight was excluded from analysis on study day 77.

In male rats, the absolute left testis and epididymis weights in the 50 ppm group were significantly decreased (approximately 10%) relative to the control group but were not associated with histopathological changes and were therefore not attributed to α-pinene exposure (Appendix G). In male and female rats, there were no exposure-related histopathological findings in the tissues examined (Appendix G).

Assessments of sperm parameters in males and estrous cyclicity in females were conducted. No exposure-related changes were noted in sperm parameters (Appendix G). The numbers of cauda sperm in the 50 and 200 ppm groups were lower by 24% and 21%, respectively, compared to the control group, but no significant trend was observed, and the differences were not significant (Table 26).

Table 26 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Investigative Inhalation Study of α-Pinene

| 0 ppm | 50 ppm | 100 ppm | 200 ppm
n | 10 | 10 | 10 | 10
Weights (g)^a,b^
Left cauda epididymis | 0.269 ± 0.006 | 0.234 ± 0.009* | 0.263 ± 0.010 | 0.262 ± 0.007
Left epididymis | 0.6618 ± 0.0140 | 0.6008 ± 0.0199* | 0.6449 ± 0.0176 | 0.6317 ± 0.0113
Left testis | 1.983 ± 0.038 | 1.778 ± 0.083* | 1.918 ± 0.046 | 1.937 ± 0.037
Spermatid Measurements^a,c^
Spermatid heads (10^6^/g testis) | 102.2 ± 2.9 | 100.0 ± 4.0 | 103.4 ± 2.3 | 101.7 ± 4.2
Spermatid heads (10^6^/testis) | 157.0 ± 4.2 | 141.8 ± 11.7 | 160.0 ± 8.5 | 155.3 ± 6.7
Epididymal Spermatozoal Measurements^a,c^
Sperm motility (%) | 77.1 ± 1.6 | 74.3 ± 2.4 | 79.8 ± 1.9 | 76.1 ± 2.1
Sperm progressive motility (%) | 74.1 ± 1.4 | 70.9 ± 2.3 | 76.9 ± 2.1 | 73.3 ± 2.2
Sperm (10^6^/g cauda epididymis) | 660.9 ± 51.9 | 583.3 ± 60.2 | 660.0 ± 50.3 | 537.7 ± 56.6
Cauda epididymis sperm count (millions) | 179.7 ± 16.1 | 136.2 ± 15.4 | 174.2 ± 15.0 | 141.3 ± 15.7

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group.

* Statistically significant at p ≤ 0.05.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and the Williams or Dunnett (pairwise) tests.

^c^ Statistical analysis performed by the Jonckheere (trend) and the Shirley or Dunn (pairwise) tests.

The number of females cycling and overall estrous cycle length were not affected by exposure. However, a marginal but significant decrease was observed in proestrus cycle length in the 100 and 200 ppm groups compared to the control group (Table 27; Figure 33).

Table 27 Summary of Estrous Cycle Data and Markov Model Estimates of Estrous Stage Length and 95% Confidence Intervals for Female Rats in the Three-month Investigative Inhalation Study of α-Pinene

| 0 ppm | 50 ppm | 100 ppm | 200 ppm
No. of Regular Cycling Females^a^ | 10 | 10 | 9 | 10
Estrous Cycle Length (days)^b^ | 5.1 ± 0.1 | 5.0 ± 0.1 | 5.0 ± 0.4 | 5.1 ± 0.2
Estrous Stage Length^c,d^
Diestrus | 2.6 (2.3, 3.0) | 2.4 (2.1, 2.7) | 2.3 (1.9, 2.7) | 2.1 (1.8, 2.3)
Proestrus | 0.6 (0.5, 0.7) | 0.6 (0.5, 0.7) | 0.2** (0.1, 0.4) | 0.4* (0.2, 0.5)
Estrus | 1.3 (1.1, 1.5) | 1.3 (1.1, 1.6) | 1.8 (1.2, 3.3) | 1.6 (1.3, 1.9)
Metestrus^e^ | 0.1 | 0.1 | 0.1 | 0.1

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. *Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ No. of Regular Cycling Females = number of animals cycling.

^b^ Estrous cycle length data are presented as mean ± standard error. Animals not cycling were excluded from the cycle length calculation. Statistical analysis performed by the Jonckheere (trend) and the Shirley or Dunn (pairwise) tests.

^c^ Estrous stage length data are presented as days (95% confidence interval).

^d^ Pairwise tests are performed using a permutation null hypothesis testing method and have been adjusted for multiple comparisons using a Hommel correction within each stage.

^e^ Because of a very low number of observations of metestrus, stage lengths were estimated using a profile likelihood approach. As a result, confidence intervals are not available for the metestrus stage length estimate.

Figure 33

Markov Model Estimates of Stage Lengths and 95% Confidence Intervals for Female Rats in the Three-month Investigative Inhalation Study of α-Pinene

Dots = estimated stage lengths; bars = 95% confidence intervals; low = 50 ppm; mid = 100 ppm; high = 200 ppm. Metestrus estimates are not shown here because of very low numbers of observations of this stage. Y-axis scales differ for each stage.

Mammary gland samples were collected for a mammary whole-mount assessment, but artifacts introduced during slide preparation prevented evaluation.

## Internal Concentration Assessment in Rats and Mice

Blood and/or mammary gland samples were collected for the measurement of α-pinene and the purported reactive metabolite, α-pinene oxide. Samples from the 2-year studies were collected at study termination to determine the feasibility of this assessment—specific sample collection and handling protocols for volatile/reactive analytes were not developed at the time of this sample collection. Blood was analyzed using qualified analytical methods (Appendix D), whereas mammary gland was analyzed using validated analytical methods (Appendix D).^62,63^ To perform a definitive assessment, animals were added to the subsequent 3-month investigative rat study, wherein samples were collected immediately following exposure on the last exposure day using an established sample collection and handling protocol for collection of volatile/reactive analytes (Appendix D) and analyzed using validated analytical methods.^62,63^

α-Pinene and α-pinene oxide were detected in blood and mammary gland following exposure to α-pinene in both the 2-year and 3-month investigative studies. Blood data are reported as ng/mL, whereas mammary gland data are presented as both ng/g mammary gland and ng/g lipid. For comparisons between mammary gland and blood, ng/g mammary gland and ng/mL blood data, respectively, were used, assuming a density of 1 g/mL for mammary gland. For comparison of mammary gland data between analytes, species, and sexes, ng/g lipid data were used.

### Two-year Study in Rats

Cause-of-death information from early removals in the 2-year rat study revealed the mammary gland was a target tissue. To best leverage the available study animals, blood and mammary gland were collected from the remaining 2-year study rats to obtain preliminary information on blood and tissue concentrations of α-pinene and to investigate potential formation of reactive metabolites (e.g., α-pinene oxide). However, at the time of collection, specific protocols for sample collection and handling of volatile and/or reactive constituents were not available. Because of the number of exposure-related early deaths, few samples were available for analysis in female rats. The primary goal of the 2-year study was to generate data related to chronic toxicity and carcinogenicity; therefore, the number of animals with blood and tissue available for the internal concentration determination was variable across groups and may have been impacted by the need to prioritize other endpoints (e.g., histopathology). Because sample collection procedures were not adapted for volatile or reactive metabolites, the internal concentration data from the 2-year study (Table 28) may not reflect accurate measurements of the α-pinene and α-pinene oxide internal concentrations. Blood α-pinene and α-pinene oxide concentrations increased less than proportionally to the exposure concentration in male and female rats. α-Pinene and α-pinene oxide concentrations were similar between male and female rats, indicating no apparent sex differences (Table 28).

Table 28 Summary of Internal Concentration Data in Blood and Mammary Gland for Male and Female Rats in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 50 ppm | 100 ppm | 200 ppm
Male
Blood Concentration^a^ | 10 | 10 | 10 | 10
α-Pinene (ng/mL)^b,c^ | BD^d^ | 10.9 ± 2.06 | 14.8 ± 1.51^e^ | 24.2 ± 4.68
α-Pinene oxide (ng/mL) | BD | 22.7 ± 2.69 | 26.8 ± 4.15 | 43.4 ± 8.80
Female
Blood Concentration^f^ | 10 | 10 | 10 | 4
α-Pinene (ng/mL) | BD | 11.5 ± 2.46 | 16.5 ± 2.14 | 11.2 ± 2.26
α-Pinene oxide (ng/mL) | BD | 24.4 ± 5.58 | 30.9 ± 5.60 | 12.1 ± 5.02
Mammary Concentration | 16 | 10 | 6 | 1
α-Pinene (ng/g)^g^ | 48.3 ± 6.37** | 37,600 ± 8,140** | 209,000 ± 45,400** | 40,800
α-Pinene lipid (g/g)^g^ | 0.287 ± 0.0339 | 0.290 ± 0.0528 | 0.135 ± 0.0177 | 0.125
α-Pinene oxide (ng/g) | BD^h^ | 1,600 ± 388 | 10,600 ± 5,760 | 279
α-Pinene oxide lipid (g/g)^g^ | 0.303 ± 0.0392^i^ | 0.300 ± 0.0364 | 0.248 ± 0.0538^j^ | 0.169
Lipid-adjusted α-pinene (ng/g lipid)^g^ | 179 ± 26.8** | 148,000 ± 37,800** | 1,580,000 ± 346,000** | 326,000
Lipid-adjusted α-pinene oxide (ng/g lipid) | BD^i^ | 6,190 ± 1,800 | 7,330 ± 1,220^j^ | 1,650

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

BD = below detection; group did not have more than 20% of its values above the limit of detection (LOD).

^a^ Number of animals.

^b^ Data are presented as mean ± standard error.

^c^ If over 20% of the animals in a group were above the LOD, one-half of the LOD was substituted for values below the LOD.

^d^ When the 0 ppm chamber group did not have over 20% of its values above the LOD, no mean or standard error was calculated, and no statistical analysis was performed.

^e^ n = 9. One male was identified as an outlier and thus excluded from analysis.

^f^ Changes in the number of animals across different exposure groups are due to the availability of animals to sample in each group unless otherwise indicated.

^g^ Statistical analysis performed by the Jonckheere (trend) and the Shirley or Dunn (pairwise) tests. No pairwise comparisons were performed when there was only one animal in the exposure group.

^h^ n = 10. Six females did not have sufficient volume for analysis.

^i^ n = 7. Nine females did not have sufficient volume for analysis.

^j^ n = 3. Three females did not have sufficient volume for analysis.

In mammary gland samples collected from female rats, negligible levels of α-pinene were detected in control rat samples. Lipid adjusted α-pinene levels in control rats were approximately 820-fold lower than those observed for the lowest exposure group of 50 ppm and were therefore unlikely to impact study interpretation. α-Pinene and α-pinene oxide concentrations in mammary gland samples were much higher than those observed in blood. Unlike with blood, the concentration of α-pinene was much higher than the oxide. There was no distinct exposure concentration-related increase in either α-pinene or the oxide.

### Two-year Study in Mice

Blood α-pinene and α-pinene oxide concentrations increased less than proportionally to the exposure concentration in male and female mice. The concentration of α-pinene was slightly higher than α-pinene oxide in both sexes. α-Pinene and α-pinene oxide concentrations in male and female mice were similar except at the highest exposure concentration of 400 ppm, where concentrations in females were higher than in males (Table 29).

Table 29 Summary of Internal Concentration Data in Blood and Mammary Gland for Male and Female B6C3F1/N Mice in the Two-year Inhalation Study of α-Pinene

| 0 ppm | 100 ppm | 200 ppm | 400 ppm
Male
Blood Concentration^a^ | 10 | 10 | 10 | 7
α-Pinene (ng/mL)^b,c^ | BD^d^ | 18.7 ± 2.03 | 44.3 ± 8.26 | 46.3 ± 12.5
α-Pinene oxide (ng/mL) | BD | 4.98 ± 0.485 | 10.3 ± 1.39 | 11.1 ± 2.79
Female
Blood Concentration | 11 | 10 | 10 | 10
α-Pinene (ng/mL) | BD | 28.4 ± 4.15 | 45.5 ± 5.69 | 89.4 ± 16.1
α-Pinene oxide (ng/mL) | BD^e^ | 7.59 ± 1.21 | 10.1 ± 1.72 | 18.1 ± 2.88
Mammary Concentration | 26 | 23 | 20 | 18
α-Pinene (ng/g)^f^ | 61.1 ± 3.35** | 26,600 ± 2,810** | 56,900 ± 5,070** | 126,000 ± 14,200**
α-Pinene lipid (g/g)^f^ | 0.244 ± 0.0215 | 0.367 ± 0.0284** | 0.258 ± 0.0345 | 0.274 ± 0.0318^g^
α-Pinene oxide (ng/g) | BD | 553 ± 68.4 | 509 ± 82.6 | 1,320 ± 260
α-Pinene oxide lipid (g/g)^f^ | 0.333 ± 0.0230** | 0.456 ± 0.0144** | 0.472 ± 0.0239** | 0.445 ± 0.0190**
Lipid-adjusted α-pinene (ng/g lipid)^f^ | 277 ± 16.0** | 81,300 ± 12,400** | 262,000 ± 37,000** | 617,000 ± 90,000**^g^
Lipid-adjusted α-pinene oxide (ng/g lipid) | BD | 1,280 ± 173 | 1,090 ± 153 | 3,010 ± 636

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

BD = below detection; group did not have more than 20% of its values above the limit of detection (LOD).

^a^ Number of animals. Changes in the number of animals across different exposure groups are due to the availability of animals to sample in each group unless otherwise indicated.

^b^ Data are presented as mean ± standard error.

^c^ If over 20% of the animals in a group were above the LOD, one-half of the LOD was substituted for values below the LOD.

^d^ When the 0 ppm chamber group did not have over 20% of its values above the LOD, no mean or standard error was calculated, and no statistical analysis was performed.

^e^ n = 10. One female did not have data available for analysis.

^f^ Statistical analysis performed by the Jonckheere (trend) and the Shirley or Dunn (pairwise) tests.

^g^ n = 17. One female was excluded from analysis.

Similar to the rats, in mammary gland samples collected from female mice, negligible levels of α-pinene were detected in control mouse samples. Lipid-adjusted α-pinene levels were approximately 290-fold lower than those observed for the lowest exposure group of 100 ppm and hence unlikely to affect study interpretation. α-Pinene and α-pinene oxide concentrations in mammary gland samples were much higher than those observed in blood. As observed with blood, the concentration of α-pinene was higher than α-pinene oxide. α-Pinene and α-pinene oxide concentrations increased with increasing exposure concentration; while α-pinene concentrations increased more than proportionally to the exposure concentration, the increase in α-pinene oxide was less than proportional.

### Three-month Investigative Study in Rats

Blood α-pinene concentration increased with the exposure concentration in both male and female rats, although the increase in general was less than proportional. Blood α-pinene oxide concentration was generally higher than the α-pinene concentration, although unlike α-pinene, α-pinene oxide did not increase with exposure concentration in male or female rats. In general, female rats had higher concentrations of α-pinene and α-pinene oxide than male rats (Table 30).

Table 30 Summary of Internal Concentration Data in Blood and Mammary Gland for Male and Female Rats in the Three-month Investigative Inhalation Study of α-Pinene

| 0 ppm | 50 ppm | 100 ppm | 200 ppm
Male
Blood Concentration^a^ | 5 | 5 | 4^b^ | 5
Lipid (g/mL)^c,d^ | 0.00361 ± 0.000165* | 0.00406 ± 0.000175 | 0.00383 ± 0.000283 | 0.00442 ± 0.000130*
α-Pinene (ng/mL) | BD^e^ | 34.9 ± 1.77 | 43.2 ± 8.34 | 81.9 ± 2.17
α-Pinene oxide (ng/mL) | BD | 86.2 ± 3.98 | 89.4 ± 3.53 | 104 ± 5.80
Lipid-adjusted α-pinene (ng/g lipid) | BD | 8,710 ± 819 | 11,500 ± 2,730 | 18,500 ± 243
Lipid-adjusted α-pinene oxide (ng/g lipid) | BD | 21,400 ± 1,460 | 23,600 ± 1,570 | 23,500 ± 930
Mammary Concentration | 5 | 5 | 4^b^ | 5
α-Pinene (ng/g)^f^ | 20.3 ± 6.14** | 32,900 ± 3,210** | 93,400 ± 13,700** | 210,000 ± 15,100**
α-Pinene lipid (g/g)^f^ | 0.0719 ± 0.00458** | 0.217 ± 0.0360* | 0.174 ± 0.0251* | 0.223 ± 0.0263**
α-Pinene oxide (ng/g) | BD | 3,740 ± 1,010 | 5,760 ± 584 | 5,110 ± 699
α-Pinene oxide lipid (g/g)^f^ | 0.161 ± 0.0252 | 0.189 ± 0.0481 | 0.156 ± 0.0378 | 0.191 ± 0.0123
Lipid-adjusted α-pinene (ng/g lipid)^f^ | 411 ± 139**^g^ | 163,000 ± 21,100* | 560,000 ± 86,300** | 1,010,000 ± 180,000**
Lipid-adjusted α-pinene oxide (ng/g lipid) | BD | 20,900 ± 3,990 | 47,300 ± 15,700 | 27,000 ± 3,240
Female
Blood Concentration | 5 | 5 | 5 | 5
Lipid (g/mL) | 0.00484 ± 0.000252 | 0.00502 ± 0.000123 | 0.00507 ± 0.000331 | 0.00491 ± 0.000241
α-Pinene (ng/mL) | BD | 56.8 ± 0.278^h^ | 124 ± 10.3 | 143 ± 12.7
α-Pinene oxide (ng/mL) | BD | 129 ± 8.00 | 196 ± 22.6 | 182 ± 13.7
Lipid-adjusted α-pinene (ng/g lipid) | BD | 11,500 ± 241^h^ | 24,800 ± 2,440 | 29,700 ± 3,470
Lipid-adjusted α-pinene oxide (ng/g lipid) | BD | 25,800 ± 1,660 | 38,700 ± 4,090 | 37,200 ± 2,460
Mammary Concentration | 5 | 5 | 5 | 5
α-Pinene (ng/g)^f^ | 18.6 ± 6.09** | 82,500 ± 8,550** | 250,000 ± 26,400** | 470,000 ± 22,400**
α-Pinene lipid (g/g)^f^ | 0.0718 ± 0.00524* | 0.205 ± 0.0471** | 0.0988 ± 0.0135 | 0.201 ± 0.0418**
α-Pinene oxide (ng/g) | BD | 5,320 ± 793 | 13,800 ± 2,610 | 13,600 ± 1,410
α-Pinene oxide lipid (g/g)^f^ | 0.182 ± 0.0243 | 0.174 ± 0.0454 | 0.239 ± 0.0321 | 0.193 ± 0.00711
Lipid-adjusted α-pinene (ng/g lipid)^f^ | 430 ± 60.0**^i^ | 533,000 ± 151,000 | 2,760,000 ± 553,000* | 2,940,000 ± 798,000*
Lipid-adjusted α-pinene oxide (ng/g lipid) | BD | 34,600 ± 5,610 | 61,400 ± 13,100 | 71,000 ± 7,670

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 ppm chamber group. Statistical significance for the 0 ppm chamber group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BD = below detection; group did not have more than 20% of its values above the limit of detection (LOD).

^a^ Number of animals.

^b^ One male rat in the 100 ppm group was euthanized as moribund on study day 84.

^c^ Data are presented as mean ± standard error.

^d^ If over 20% of the animals in a group were above the LOD, one-half of the LOD was substituted for values below the LOD.

^e^ When the 0 ppm chamber group did not have over 20% of its values above the LOD, no mean or standard error was calculated, and no statistical analysis was performed.

^f^ Statistical analysis was performed by Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^g^ n = 3. Two males were excluded from analysis.

^h^ n = 4. One female was excluded from analysis.

^i^ n = 2. Three females were excluded from analysis.

Mammary gland α-pinene and α-pinene oxide concentrations were much higher than those observed in blood. α-Pinene concentration increased proportionally to the exposure concentration in male and female rats, except in the 200 ppm female rats. Mammary α-pinene oxide concentrations were lower than α-pinene concentrations and increased less than proportionally to the exposure concentration. As observed with blood, female rats had higher concentrations of α-pinene and α-pinene oxide than male rats in mammary gland.

α-Pinene and α-pinene oxide concentrations in the 3-month investigative rat study were higher than those in the 2-year rat study, and the difference was not consistent across matrices and analytes. Up to 4-fold and 5- to 15-fold higher concentrations were observed in male and female blood, respectively, and 2- to 43-fold higher concentrations were observed in female mammary gland. Because both α-pinene and α-pinene oxide have long half-lives in rats,^6^ the observed higher concentrations in the 3-month study cannot be entirely due to the differences in sample collection timing between the two studies. Inadequate sample collection and storage procedures used during the 2-year study leading to loss/instability of analytes, in addition to differences in sample analysis, may have also played a role in the observed lower concentrations and variability between matrices and analytes.