# Materials and Methods

## Procurement and Characterization of α-Pinene

α-Pinene was obtained from The John Walsh Company, Inc. (Ringwood, NJ) in one lot (A-9211). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at RTI International (Research Triangle Park, NC) and the study laboratory at Battelle (Columbus, OH) (Appendix A). Reports on analyses performed in support of α-pinene studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot A-9211, a clear oily liquid at room temperature, was identified as α-pinene by the analytical chemistry laboratory using gas chromatography (GC) with mass spectrometry (MS) detection and by the study laboratory using infrared (IR) and ^1^H and ^13^C nuclear magnetic resonance (NMR) spectroscopies. All spectra were consistent with reference spectra and the anticipated structures of the test article (Appendix A). Enantiomeric composition was determined to be approximately 68% (+) α-pinene [(1R)-(+)-α-pinene] and approximately 32% (−) α-pinene [(1S)-(−)-α-pinene] with chiral GC/MS and optical polarimetry by the analytical chemistry laboratory and with GC with flame ionization detection (FID) by the study laboratory. Elemental analysis was performed by Galbraith Laboratories, Inc. (Knoxville, TN) to aid in identification. The elemental compositions were within 4% of theoretical values for α-pinene.

Purity of lot A-9211 was evaluated by GC/MS at both laboratories and by GC/FID at the study laboratory. Four reportable impurities with peak areas between 0.09% and 0.63% of the total integrated peak area were detected. Three of the reportable impurities were identified as camphene, tricyclene, and β-pinene. The fourth was not conclusively identified. Lot A-9211 was also analyzed by GC/MS for butylated hydroxytoluene (BHT), a commonly used antioxidant for preventing radical-mediated oxidation of compounds, and it was confirmed to be BHT-free. Moisture content was determined by Karl Fischer titration at Galbraith Laboratories, Inc. (Knoxville, TN) and yielded an average water content of <0.38%. The overall purity was determined to be >98%.

During the studies and between the 2-year and 3-month investigative rat studies, bulk α-pinene was stored in the original shipping containers at room temperature. Periodic reanalysis of the bulk chemical was performed by the study laboratory before and after the study, at regular intervals during each chronic study, and during all studies using GC/FID, and no degradation was detected.

## Vapor Generation and Exposure System

A diagram of the vapor generation and delivery system used in the studies is shown in Figure A-5. The test chemical, α-pinene, was pumped from an 8-gallon stainless steel reservoir into a heated glass vaporizer column filled with glass beads and completely wrapped with heat tape. A waste collection flask was connected to the bottom of the vaporizer column to collect residual chemical not completely vaporized.

Preheated nitrogen entered the vaporizer column from below, vaporized the test chemical, and carried the vapor from the generator cabinet to the distribution manifold through a heated chemical transport line. The nitrogen-chemical mixture was diluted with heated air before entering the distribution manifold. Concentration in the manifold was determined by the chemical pump rate, nitrogen flow rate, and dilution air flow rate. The pressure in the distribution manifold was kept fixed to ensure constant flow rates through the manifold and into all exposure chambers as the flow of vapor to each chamber was adjusted.

Individual heated Teflon^®^ delivery lines carried the vapor from the distribution manifold to three-way exposure valves at the chamber inlets. The chamber exposure valves diverted vapor delivery to the manifold exhaust until the generation system stabilized and exposure could proceed. The delivery rate to each chamber was controlled by a precision metering valve at the manifold. To initiate exposure, the chamber exposure valves were rotated to direct α-pinene vapor into the chamber inlet, where it was diluted with conditioned, filtered, and temperature-controlled air to achieve the desired exposure concentration.

The study laboratory designed the inhalation exposure chamber (Lab Products, Inc.; Seaford, DE) so that uniform vapor concentrations could be maintained throughout the chambers. The total active mixing volume of each chamber was 1.7 m^3^. A condensation particle detector (Model 3022A; TSI, Inc.; St. Paul, MN) was used in the exposure chambers before and during animal exposure to ensure that α-pinene vapors (and not aerosols) were produced. Particle counts <200 particles/cm^3^ are typical of an exposure atmosphere when no generation is occurring. Particle counts above this level suggest a contribution to the aerosol concentration due to the generation system. Particle counts above 200 particles/cm^3^ were detected at one target concentration before exposure and at seven target concentrations after exposure in a test prior to the studies, indicating particle contamination was due to generation. This observation was in contrast to the previously published 3-month studies in Fischer 344 (F344/N) rats and B6C3F1/N mice in which particle counts were consistently below 200 particles/cm^3^.^2^ Particle counts were collected from all chambers at regular intervals during all studies, and particle counts were frequently >200 particles/cm^3^ except for the 400 ppm chamber for Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats in the 3-month reproductive study. The source and identity of the particles were undetermined. Using a scanning mobility particle sizer (SMPS; TSI, Model 3036), the particles were determined to have a mass median aerodynamic diameter of approximately 0.2 microns. Using this diameter and assuming a density of 1 g/cm^3^, the total mass of the particles was calculated in each exposure chamber atmosphere as a percentage by weight of the amount of α-pinene. Across all studies and in all chambers, the contribution of particle formation on the overall exposure was very small, with the maximum particle concentrations by weight being less than 0.1% of the target α-pinene concentration. Based on this consideration, there was not a concern for the particle formation to affect the overall interpretation because impurities less than or equal to 0.1% of the total concentration are considered acceptable and do not need to be reported.

## Vapor Concentration Monitoring

Exposure chamber and room concentrations of α-pinene were monitored using an online GC/FID (Table A-2). Samples from exposure and control chambers were drawn approximately two times per hour during each exposure period. Samples were drawn through Teflon^®^ tubing connected to each exposure chamber’s sampling line using a 16-port Hastelloy^®^-C stream-select valve that directs a continuous stream of sampled atmosphere to a 6-port Hastelloy^®^-C gas-sampling valve with a 1 mL Silcosteel^®^ sample loop. Both valves and the sampling loop were mounted in a dedicated valve oven. A vacuum regulator maintained a constant vacuum in the sample loop to compensate for variations in sample line pressure. An in-line flow meter between the vacuum regulator and GC allowed for digital measurement of sample flow. Summaries of the chamber vapor concentrations are given in Table A-3 through Table A-7. The mean measured chamber concentrations were within the acceptance criteria of 10% for all exposure groups of every study. The number of acceptable samples was ≥99% for all exposure groups of every study except for the 100 ppm group of the 3-month reproductive study in Sprague Dawley rats, which was 98%.

## Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined with and without animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after vapor generation was terminated (T_10_) was approximately 9 minutes. T_90_ and T_10_ values ranged from 9 to 10 minutes without animals present and from 9 to 12 minutes with animals present. Because the presence of animals may have had a slight effect on the time for the vapor concentration to build up and decay, a value of 12 minutes was selected for T_90_ during in-life exposure.

The persistence of α-pinene in the chambers after vapor delivery ended was determined by monitoring α-pinene concentrations in the 200 ppm rat chambers and 400 ppm mouse chambers with and without animals present. The time for the chamber concentration to decay to <1% of the starting concentration after vapor generation was terminated (T_1_) was 21 minutes for both chambers without animals present and 28 minutes (200 ppm rat chamber) and 31 minutes (400 ppm mouse chamber) with animals present.

The uniformity of α-pinene vapor concentration in the chambers was evaluated with and without animals present. Vapor concentrations were measured using the online GC/FID at 12 chamber positions: one in front and one in the back for each of the six possible animal cage unit positions per chamber. The uniformity of the vapor in the chambers without animals was within the acceptable range of ≤5% relative standard deviation (RSD). During the studies, concentrations were measured at the regular monitoring port and from chamber positions where animals were present. Chamber concentration uniformity was maintained throughout the studies.

To measure stability and purity of the test article in the generation and delivery system prior to the study, samples of the test atmosphere from the distribution line, generator reservoir, and low and high exposure concentration chambers for each species were collected at the beginning and end of the exposure day, with and without animals present. The atmospheric samples were collected with sorbent gas-sampling tubes, and an additional liquid sample was collected from the generator reservoir. All samples were analyzed for purity and enantiomeric composition. No evidence of degradation or change in enantiomeric composition was noted in any part of the exposure system. Overall, purity of α-pinene in the exposure chambers reflected the purity of the bulk test chemical. α-Pinene was stable under the generation and exposure conditions used during the studies.

## Animal Source

Male and female Sprague Dawley rats were obtained from Envigo (formerly Harlan Laboratories, Inc.; Indianapolis, IN) for the 2-year and 3-month reproductive studies. Male and female Sprague Dawley rats were obtained from Envigo (Haslett, MI) for the 3-month investigative study. Male and female B6C3F1/N mice were obtained from the National Toxicology Program (NTP) colony maintained by Taconic Biosciences, Inc. (Germantown, NY), and CD-1 mice were obtained from Charles River (Kingston, NY).

## Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Battelle (West Jefferson, OH) Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health (NIH) and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Exposure Concentration Selection Rationale

Exposure concentration selection for the 2-year studies was based primarily on findings from the 3-month studies in F344/N rats and B6C3F1/N mice.^2^ In the previous 3-month studies, six out of ten female F344/N rats in the 400 ppm group died prior to study termination, indicating overt toxicity. All other signs of toxicity observed in male and female F344/N rats at the 200 ppm exposure concentration in the 3-month studies (i.e., increased liver and kidney weights in male and female rats and decreased sperm in male rats) were considered not to be exposure limiting. Therefore, a high exposure concentration of 200 ppm was selected for the 2-year study using Sprague Dawley rats under the assumption that they would exhibit a similar level of sensitivity to α-pinene as F344/N rats. Male F344/N rats in the previous 3-month study exhibited similar patterns of effect between the 200 and 400 ppm exposure concentrations; therefore, 200 ppm was selected as the high exposure concentration for both male and female Sprague Dawley rats in the 2-year study to facilitate comparison across sexes. Exposure concentrations for the 2-year Sprague Dawley rat study were 0, 50, 100, and 200 ppm α-pinene. There were no premature deaths in the previous 3-month studies in B6C3F1/N mice, and all observed toxicity findings at the 400 ppm exposure concentration were considered not to be exposure limiting. Therefore, 400 ppm was selected as the high exposure concentration for the 2-year studies in male and female B6C3F1/N mice. Exposure concentrations for the 2-year B6C3F1/N mice study were 0, 100, 200, and 400 ppm α-pinene. These exposure concentrations (0, 100, 200, and 400 ppm) were also used for the 3-month reproductive studies in male Sprague Dawley rats and CD-1 mice and for the 3-month study in B6C3F1/N mice to maximize the likelihood of detecting functional effects on reproduction following exposure of male animals to α-pinene and to allow for direct comparison with the findings in the previous 3-month studies in F344/N rats and B6C3F1/N mice. In the 3-month investigative study in male and female Sprague Dawley rats, exposure concentrations matching those used in the 2-year studies (0, 50, 100, and 200 ppm) were included to allow for measurement of interim α-pinene concentrations and to investigate early biomarkers of carcinogenesis.

## Study Design for Rats

### Two-year Study in Rats

Male and female rats were approximately 4 weeks old upon receipt and were quarantined for 11 days before study start. Rats were randomly assigned to one of four exposure groups (n = 50 rats/sex/exposure group). Randomization was stratified by body weight that produced similar group mean weights using NTP Provantis software (Instem, Stone, UK). Rats were exposed to α-pinene via whole-body inhalation for 6 hours plus T_90_ per day for 5 days per week (excluding holidays) at one of four target concentrations (0, 50, 100, or 200 ppm) for 2 years.

Twenty male and 20 female rats were randomly selected for parasite evaluation and gross observation of disease. The health of the rats was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Rats were housed individually. Feed and water were available ad libitum, except during exposure when feed was removed. Cages and racks were changed and rotated at least once weekly. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is given in Appendix B.

Table 1 Experimental Design and Materials and Methods in the Two-year and Three-month Reproductive and Investigative Inhalation Studies of α-pinene

Rats | Mice
Testing Facility
Battelle/AmplifyBio^1^; 1 These studies were conducted under the NIEHS contract with Battelle Memorial Institute (HHSN273201400015C). The studies were initiated at the Battelle testing facility in West Jefferson, Ohio. On May 1, 2021, the testing facility was transferred to a new company, AmplifyBio. The study was transferred to AmplifyBio as a subcontract under HHS273201400015C.; (West Jefferson, Ohio) | Same as rats
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) | 3-month reproductive study in CD-1 mice: CD-1
| 3-month study in B6C3F1/N mice: B6C3F1/N
| 2-year study: B6C3F1/N
Animal Source
3-month reproductive study: Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN) | B6C3F1/N: Taconic Biosciences, Inc. (Germantown, NY)
3-month investigative study: Envigo (Haslett, MI) | CD-1: Charles River (Kingston, NY)
2-year study: Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN)
Time Held Before Studies
3-month reproductive study (males): 11 days | 3-month reproductive study in CD-1 mice (males): 11 days
3-month investigative study: 13–15 days | 3-month study in B6C3F1/N mice: 11 days
2-year study: 11 days | 2-year study: 11 days
Average Age When Studies Began
3-month reproductive study: 6 weeks (males) or 14 weeks (females) | 3-month reproductive study in CD-1 mice: 6 weeks (males) or 14 weeks (females)
3-month investigative study: 6 weeks | 3-month study in B6C3F1/N mice: 6 weeks
2-year study: 6 weeks | 2-year study: 6 weeks
Date of First Exposure
3-month reproductive study: February 23, 2015 (males) or not exposed (females) | 3-month reproductive study in CD-1 mice: February 9, 2015 (males) or not exposed (females)
3-month investigative study: November 15–17, 2017 | 3-month study in B6C3F1/N mice: February 9, 2015
2-year study: February 23, 2015 | 2-year study: February 9, 2015
Duration of Exposure
3-month reproductive study (males): 6 hours plus T_90_ (12 minutes)/day for 5 days/week for 3 months | 3-month reproductive study CD-1 mice (males): Same as 3-month reproductive study rats
3-month investigative study: Same as 3-month reproductive study rats | 3-month study in B6C3F1/N mice: Same as 3-month reproductive study rats
2-year study: 6 hours plus T_90_ (12 minutes)/day for 5 days/week for 2 years | 2-year study: Same as 2-year study rats
Date of Last Exposure
3-month reproductive study (males): May 22, 2015 | 3-month reproductive study in CD-1 mice (males): May 8, 2015
3-month investigative study: February 13–15, 2018 | 3-month study in B6C3F1/N mice: May 8, 2015
2-year study: February 20–22, 2017 | 2-year study: February 5–9, 2017
Necropsy Dates
3-month reproductive study: June 8–10 (males) or 9–22 (females), 2015 | 3-month reproductive study in CD-1 mice: May 26–28 (males) or May 26–June 7 (females), 2015
3-month investigative study: February 14–16, 2018 (core) or February 13–14, 2018 (biosample) | 3-month study in B6C3F1/N mice: May 8, 2015
2-year study: February 21–23, 2017 | 2-year study: February 6–10, 2017
Average Age at Necropsy
3-month reproductive study: 21 (males) or 16–18 weeks (females) | 3-month reproductive study in CD-1 mice: 21 (males) or 17–18 (females) weeks
3-month investigative study: 19 weeks | 3-month study in B6C3F1/N mice: 18 weeks
2-year study: 110 weeks | 2-year study: Same as 2-year study rats
Size of Study Groups
3-month reproductive study: 25/sex | 3-month reproductive study in CD-1 mice: Same as 3-month reproductive study rats
3-month investigative study: 10/sex (core); 5/sex (biosample) | 3-month study in B6C3F1/N mice: 10 males
2-year study: 50/sex | 2-year study: Same as 2-year study rats
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights using NTP Provantis (Instem, Stone, UK). | Same as rats
Animals per Cage
3-month reproductive study: 1 (male) or 1 (female), except during mating | 3-month reproductive study in CD-1 mice: Same as 3-month reproductive study rats
3-month investigative study: 1 (male) or 1 (female) | 3-month study in B6C3F1/N mice: 1 (male)
2-year study: 1 (male) or 1 (female) | 2-year study: Same as 2-year study rats
Method of Animal Identification
Cage card and tail tattoo | Same as rats
Diet
3-month reproductive study: Irradiated NIH-07 wafer feed (males and females during cohabitation until termination) or irradiated NTP-2000 wafer feed (males during 13-week exposure phase) (Zeigler Brothers, Inc., Gardners, PA), available ad libitum (except males during exposure), changed at least weekly | 3-month reproductive study in CD-1 mice: Same as 3-month reproductive study rats
3-month investigative study: Irradiated NTP-2000 wafer feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum (except during exposure), changed at least weekly | 3-month study in B6C3F1/N mice: Same as 2-year study rats
2-year study: Irradiated NTP-2000 wafer feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum (except during exposure), changed at least weekly | 2-year study: Same as 2-year study rats
Water
Tap water (Village of West Jefferson, OH municipal supply) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as rats
Cages
3-month reproductive study: A combination of R-24 or R-16 wire-mesh cage units (males during 13-week exposure), changed and rotated at least weekly, or solid polycarbonate cages (males following exposure and females) (Lab Products, Inc., Seaford, DE), changed at least weekly | 3-month reproductive study in CD-1 mice: A combination of M-40 or M-60 wire-mesh cage units (males), changed and rotated at least weekly, or polycarbonate cages (males following exposure and females) (Lab Products, Inc., Seaford, DE), changed at least weekly
3-month investigative study: R-24 wire-mesh cage units (Lab Products, Inc., Seaford, DE), changed and rotated at least weekly | 3-month study in B6C3F1/N mice (males): A combination of M-40 or M-60 wire-mesh cage units (Lab Products, Inc., Seaford, DE), changed and rotated at least weekly
2-year study: R-24 (females) and a combination of R-24 or R-16 (males) wire-mesh cage units (Lab Products, Inc., Seaford, DE), changed and rotated at least weekly | 2-year study: A combination of M-40 or M-60 wire-mesh cage units (Lab Products, Inc., Seaford, DE), changed and rotated at least weekly
Bedding
3-month reproductive study: Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corporation, Montville, NJ), changed with cage changes | 3-month reproductive study in CD-1 mice: Same as 3-month reproductive study rats
3-month investigative study: Not applicable | 3-month study in B6C3F1/N mice: Same as 3-month reproductive study rats
2-year study: Not applicable | 2-year study: Not applicable
Cage Board
3-month reproductive study: Excreta pans and cage boards lining the pans, changed daily (males during 13-week exposure), or spun-bonded polyester (National Filter Media Corporation, Olive Branch, MS), changed at least every 2 weeks (males following exposure and females) | 3-month reproductive study in CD-1 mice: Same as 3-month reproductive study rats
3-month investigative study: Excreta pans and cage boards lining the pans, changed daily | 3-month study in B6C3F1/N mice: Excreta pans and cage boards lining the pans, changed daily
2-year study: Excreta pans and cage boards lining the pans, changed daily | 2-year study: Same as 2-year study rats
Racks
3-month reproductive study: Stainless steel army rack (Lab Products, Inc., Seaford, DE), changed and sanitized at least weekly (males during 13-week exposure), or stainless steel rack (Lab Products, Inc., Seaford, DE), changed, sanitized, and rotated at least every 2 weeks (males following exposure and females) | 3-month reproductive study in CD-1 mice: Same as 3-month reproductive study rats
3-month investigative study: Stainless steel army rack (Lab Products, Inc., Seaford, DE), changed, sanitized, and rotated at least weekly | 3-month study in B6C3F1/N mice: Stainless steel army rack (Lab Products, Inc., Seaford, DE), changed and sanitized at least weekly
2-year study: Stainless steel army rack (Lab Products, Inc., Seaford, DE), changed and sanitized at least weekly | 2-year study: Same as 2-year study rats
Chamber Air Supply Filters
Intake air was conditioned by passage through Purafil, charcoal, and high efficiency particulate air (HEPA) filters | Same as rats
Chambers
Stainless steel chamber (Lab Products, Inc., Seaford, DE), changed and sanitized at least weekly | Same as rats
Animal Room and Chamber Environment
3-month reproductive study, males during 13-week exposure (exposure chambers): Temperature: 70°F–79°F Relative humidity: 38%–72% Room fluorescent light: 12 hours/day Chamber air changes: at least 10/hour | 3-month reproductive study in CD-1 mice, males during 13-week exposure (exposure chambers): Temperature: 72°F–78°F Relative humidity: 35%–72% Room fluorescent light: 12 hours/day Chamber air changes: at least 10/hour
3-month reproductive study, males following exposure (mating room) and females (quarantine and mating room): Temperature: 71°F–73°F Relative humidity: 48%–63% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | 3-month reproductive study in CD-1 mice, males following exposure (mating room) and females (quarantine and mating room): Temperature: 66°F–73°F Relative humidity: 48%–55% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
3-month investigative study (exposure chambers): Temperature: 72°F–77°F Relative humidity: 45%–70% Room fluorescent light: 12 hours/day Chamber air changes: at least 10/hour | 3-month study in B6C3F1/N mice (exposure chambers): Temperature: 72°F–78°F Relative humidity: 35%–72% Room fluorescent light: 12 hours/day Chamber air changes: at least 10/hour
2-year study (exposure chambers): Temperature: 70°F–80°F Relative humidity: 31%–87% Room fluorescent light: 12 hours/day Chamber air changes: at least 10/hour | 2-year study (exposure chambers): Temperature: 69°F–79°F Relative humidity: 28%–82% Room fluorescent light: 12 hours/day Chamber air changes: at least 10/hour
Exposure Concentrations
3-month reproductive study (males): 0, 100, 200, or 400 ppm | 3-month reproductive study in CD-1 mice (males): Same as 3-month reproductive study rats
3-month investigative study: 0, 50, 100, 200 ppm | 3-month study in B6C3F1/N mice: 0, 100, 200, or 400 ppm
2-year study: 0, 50, 100, or 200 ppm | 2-year study: 0, 100, 200, or 400 ppm
Type and Frequency of Observation
3-month reproductive study (males): Observed twice daily. Animals were weighed and clinical observations were recorded initially, weekly for 13 weeks during the exposure period, weekly during the mating period, and at study termination. | 3-month reproductive study in CD-1 mice (males): Same as 3-month reproductive study male rats
3-month reproductive study (females): Observed twice daily. Animals were weighed and clinical observations were recorded weekly during the mating period, twice weekly following confirmation of mating (GD 0 until GD 14), and at study termination. | 3-month reproductive study in CD-1 mice (females): Same as 3-month reproductive study female rats
3-month investigative study: Observed twice daily. Animals were weighed and clinical observations were recorded prior to exposure on day 0, weekly for 13 weeks, and at study termination. | 3-month study in B6C3F1/N mice (males): Observed twice daily. Animals were weighed and clinical observations were recorded initially, weekly for 13 weeks, and at study termination.
2-year study: Observed twice daily. Weighed initially, weekly for 13 weeks, every 4 weeks thereafter, and at study termination. Clinical observations were recorded every 4 weeks, coinciding with body weight collection days, and at study termination. | 2-year study: Same as 2-year study rats
Method of Euthanasia
3-month reproductive study, F_0_: Thoracotomy and bilateral thoracic puncture | 3-month reproductive study in CD-1 mice, F_0_: 70% carbon dioxide/30% oxygen
3-month reproductive study, F_1_ pups: Decapitation | 3-month reproductive study in CD-1 mice, F_1_ pups: Decapitation
3-month investigative study: 70% carbon dioxide/30% oxygen followed by exsanguination | 3-month study in B6C3F1/N mice: Thoracotomy and bilateral thoracic puncture or 70% carbon dioxide/30% oxygen followed by exsanguination
2-year study: Not reported | 2-year study: 70% carbon dioxide/30% oxygen followed by exsanguination
Necropsy
3-month reproductive study: Necropsies were performed on all male rats, female rats that had no evidence of mating (with the exception of 11 rats that were kept on study because of body weight changes indicative of pregnancy), and female F_0_ rats with a scheduled termination on GD 14. Uterine exams were performed on female F_0_ rats with a scheduled termination on GD 14 to record the number of viable and nonviable embryos, early resorptions, and the total number of implantations. The number of corpora lutea on each ovary was recorded for gravid females that did not deliver. | 3-month reproductive study in CD-1 mice: Necropsies were performed on all male mice, female mice that had no evidence of mating (with the exception of four mice that were kept on study because of body weight changes indicative of pregnancy), and female F_0_ mice with a scheduled termination on GD 14. Uterine exams were performed on female F_0_ mice with a scheduled termination on GD 14 to record the number of viable and nonviable embryos, early resorptions, and the total number of implantations. The number of corpora lutea on each ovary was recorded for gravid females that did not deliver.
3-month investigative study: Necropsies were performed on all rats. | 3-month study in B6C3F1/N mice: Necropsies were performed on all mice.
2-year study: Necropsies were performed on all rats. | 2-year study: Necropsies were performed on all mice.
Histopathology
3-month reproductive study (males): Histopathological examination of the urinary bladder and kidney was performed on 10 randomly selected male rats per group; the right testis, right epididymis, and remainder of the left epididymis were examined for all animals. | 3-month reproductive study in CD-1 mice (males): Histopathological examination of the right testis and right epididymis for all mice and the urinary bladder from 10 designated mice.
3-month investigative study: In addition to gross lesions and tissue masses, the following tissues were examined in all core rats: mammary glands 4 and 5 (right, whole mounts), mammary glands 4 and 5 (left, paraffin embedded), testes with epididymides, and uterus/cervix/vagina. Given the poor quality of samples, the mammary whole-mount slides were not evaluated. | 3-month study in B6C3F1/N mice: Histopathological examination of the urinary bladder, right testis, and right epididymis was performed on all animals.
2-year study: Complete histopathology was performed on all rats. In addition to gross lesions and tissue masses (if observed), the following tissues were examined: adrenal glands, brain [seven sections including (1) olfactory bulbs, (2) frontoparietal cortex and basal ganglia, (3) mid-parietal cortex and thalamus, (4) mid-brain with substantia nigra and red nucleus, (5) posterior colliculi, (6) mid-cerebellum including cranial nerve VIII, and (7) posterior medulla], cervix/vagina, clitoral glands, esophagus, eyes, femur (including diaphysis with marrow cavity and epiphysis [femoral condyle with epiphyseal cartilage plate, articular cartilage, and articular surface]), Harderian glands, heart and aorta, kidneys, large intestine (cecum, colon, and rectum), larynx, liver (two sections including left lateral lobe and median lobe), lungs and mainstem bronchi, lymph nodes (mandibular, mesenteric, bronchial, and mediastinal), mammary gland with adjacent (inguinal) skin, nasal cavity and nasal turbinates (three sections), nerve (sciatic, tibial, and trigeminal with ganglion, if neurological signs present), ovaries, pancreas, parathyroid glands, pituitary gland, preputial glands, prostate, salivary glands, seminal vesicles, small intestine (duodenum, jejunum, and ileum), spinal cord (three sections, if neurological signs present), spleen, stomach (forestomach and glandular), testes with epididymides, thigh muscle (if neuromuscular signs present), thymus, thyroid gland, trachea, urinary bladder, and uterus. | 2-year study: Complete histopathology was performed on all mice. In addition to gross lesions and tissue masses (if observed), the following tissues were examined: adrenal glands, brain [seven sections including (1) olfactory bulbs, (2) frontoparietal cortex and basal ganglia, (3) mid-parietal cortex and thalamus, (4) mid-brain with substantia nigra and red nucleus, (5) posterior colliculi, (6) mid-cerebellum including cranial nerve VIII, and (7) posterior medulla], cervix/vagina, clitoral glands, esophagus, eyes, femur (including diaphysis with marrow cavity and epiphysis [femoral condyle with epiphyseal cartilage plate, articular cartilage and articular surface]), gall bladder, Harderian glands, heart and aorta, kidneys, large intestine (cecum, colon, and rectum), larynx, liver (two sections including left lateral lobe and median lobe), lungs and mainstem bronchi, lymph nodes (mandibular, mesenteric, bronchial, and mediastinal), mammary gland with adjacent (inguinal) skin, nasal cavity and nasal turbinates (three sections), nerve (sciatic and trigeminal with ganglion, if neurological signs present), ovaries, pancreas, parathyroid glands, pituitary gland, preputial glands, prostate, salivary glands, seminal vesicles, small intestine (duodenum, jejunum, and ileum), spinal cord (if neurological signs present), spleen, stomach (forestomach and glandular), testes with epididymides, thigh muscle (if neuromuscular signs present), thymus, thyroid gland, trachea, urinary bladder, and uterus.
Internal Concentration Assessment
3-month reproductive study: None | 3-month reproductive study in CD-1 mice: None
3-month investigative study: At study termination, blood from the retroorbital plexus from surviving biosample rats, as well as mammary glands (4 and/or 5 from all females), were collected for α-pinene and α-pinene oxide concentrations using a validated method (Appendix D).^62,63^ | 3-month study in B6C3F1/N mice: None
2-year study: At study termination, blood from the heart from up to 10 randomly selected animals/sex/exposure group, as well as mammary glands 1, 2, and 3 from up to 16 females/exposure group, were collected for α-pinene and α-pinene oxide determination in blood using a qualified method (Appendix D) and mammary gland using a validated method.^62,63^ | 2-year study: At study termination, blood from the heart from up to 11 randomly selected animals/sex/exposure group, as well as mammary glands 1, 2, and 3 from up to 26 females/exposure group, were collected for α-pinene and α-pinene oxide determination in blood using a qualified method (Appendix D) and mammary gland using a validated method.^62,63^
Sperm Motility and Vaginal Cytology
3-month reproductive study (males): The left testis and left epididymis were collected from all male rats for sperm count and motility evaluations. The following parameters were evaluated: cauda epididymal sperm motility, cauda epididymal and testicular sperm concentration, cauda epididymal and testicular sperm head counts, and testicular sperm production rate. The left and right epididymides and left and right testes were weighed. Given the artifacts identified during analysis (e.g., clumping of cells, too many sperm in sample), sperm motility and count data were not analyzed or reported. | 3-month reproductive study in CD-1 mice (males): Same as 3-month reproductive study rats
3-month investigative study: The left testis and left epididymis were collected from all core male rats for sperm count and motility evaluations. The following parameters were evaluated: cauda epididymal sperm motility, cauda epididymal and testicular sperm concentration, and cauda epididymal and testicular sperm head counts. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for 17 consecutive days before study termination from core female rats in the 0, 50, 100, and 200 ppm groups for vaginal cytology evaluations. | 3-month study in B6C3F1/N mice: The left testis and left epididymis were collected from all male mice for sperm count and motility evaluations. The following parameters were evaluated: cauda epididymal sperm motility, cauda epididymal and testicular sperm concentration, cauda epididymal and testicular sperm head counts, and testicular sperm production rate. The left and right epididymides and left and right testes were weighed. Given the artifacts identified during analysis (e.g., clumping of cells, too many sperm in sample), sperm motility and count data were not analyzed or reported.
2-year study: None | 2-year study: None
Molecular Pathology
3-month reproductive study (males): A sample of grossly normal urinary bladder and half of any gross lesions of the urinary bladder were collected. | 3-month reproductive study in CD-1 mice (males): Same as 3-month reproductive study male rats
3-month investigative study: None | 3-month study in B6C3F1/N mice: Same as 3-month reproductive study male rats
2-year study: Mammary tumors (fibroadenomas and adenocarcinomas) arising spontaneously or following chronic α-pinene exposure were subjected to whole-genome sequencing. Tumors >5 mm in diameter were dissected in half, and one-half was collected in 10% NBF and the other half was snap frozen in liquid nitrogen and stored at −80°C until DNA was extracted for subsequent whole-genome sequencing studies. Additional details are available in Appendix E. | 2-year study: Hepatocellular carcinomas and alveolar/bronchiolar carcinomas arising spontaneously or following chronic α-pinene exposure were subjected to whole-genome sequencing. Tumors >5 mm in diameter were dissected in half, and one-half was collected in 10% NBF and the other half was snap frozen in liquid nitrogen and stored at −80°C until DNA was extracted for subsequent whole-genome sequencing studies. Additional details are available in Appendix E.

T_90_ = time to achieve 90% of the target concentration after the beginning of vapor generation; GD = gestation day; NBF = neutral buffered formalin.

### Three-month Reproductive Study in Rats

Male rats were approximately 4 weeks old upon receipt and were quarantined for 11 days before study start. Male rats were randomly assigned to one of four exposure groups (n = 25 rats/exposure group). Randomization was stratified by body weight that produced similar group mean weights using NTP Provantis software (Instem, Stone, UK). Male rats were exposed to α-pinene via whole-body inhalation for 6 hours plus T_90_ per day for 5 days per week (excluding holidays) at one of four target concentrations (0, 100, 200, or 400 ppm) for 3 months.

Following 3 months of exposure, male rats were removed from exposure, transferred to the room housing unexposed naïve female rats, and housed individually for 3 days before cohabitation. Unexposed females were approximately 12 weeks old upon receipt and were quarantined for 11 days before study start. Female rats were randomly assigned to male rats for mating purposes only and were never administered α-pinene. The first day of cohabitation marked reproductive study day 1, when unexposed females were mated with exposed males. Reproductive study rats remained paired until evidence of mating was confirmed by daily examination (vaginal copulatory plug or presence of sperm in vaginal lavage sample) or until reproductive study day 15, whichever came first. Upon confirmation of copulation, male and female rats were housed individually until study termination, and this was considered gestation day (GD) 0. During the mating period, individual body weights of male and female animals were obtained weekly, beginning on the first day of cohabitation through reproductive study day 15 and again before study termination. Following confirmation of mating, female rats were weighed twice weekly, beginning on GD 0 through GD 14.

Two diets were used in the 3-month reproductive study: (1) NTP-2000 during the 13-week exposure phase for males and (2) NIH-07 during cohabitation until termination. The NIH-07 diet is a higher protein diet that supports reproduction and lactation in rodents, whereas the NTP-2000 diet is a lower protein diet that decreases the incidence of chronic nephropathy in adult rats. Information on feed composition and contaminants for both diets is provided in Appendix B.

## Study Design for Mice

### Two-year Study in B6C3F1/N Mice

Male and female B6C3F1/N mice were approximately 4 weeks old upon receipt and were quarantined for 11 days before study start. Mice were randomly assigned to one of four exposure groups (n = 50 mice/sex/exposure group). Randomization was stratified by body weight that produced similar group mean weights using NTP Provantis software (Instem, Stone, UK). Mice were exposed to α-pinene via whole-body inhalation for 6 hours plus T_90_ per day for 5 days per week (excluding holidays) at one of four target concentrations (0, 100, 200, or 400 ppm) for 2 years.

Twenty male and 20 female B6C3F1/N mice were randomly selected for parasite evaluation and gross observation of disease. The health of the mice was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Mice were housed individually. Feed and water were available ad libitum, except during exposure when feed was removed. Cages and racks were changed and rotated at least once weekly. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is given in Appendix B.

### Three-month Study in B6C3F1/N Mice

Male B6C3F1/N mice were approximately 4 weeks old upon receipt and were quarantined for 11 days before study start. Male B6C3F1/N mice were randomly assigned to one of four exposure groups (n = 10 mice/exposure group). Randomization was stratified by body weight that produced similar group mean weights using NTP Provantis software (Instem, Stone, UK). Male B6C3F1/N mice were exposed to α-pinene via whole-body inhalation for 6 hours plus T_90_ per day for 5 days per week (excluding holidays) at one of four target concentrations (0, 100, 200, or 400 ppm) for 3 months. Following 3 months of exposure, male B6C3F1/N mice were euthanized.

Mice were housed individually. Feed and water were available ad libitum, except during exposure when feed was removed. Cages and racks were changed and rotated at least once weekly. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is given in Appendix B.

### Three-month Reproductive Study in CD-1 Mice

Male CD-1 mice were approximately 4 weeks old upon receipt and were quarantined for 11 days before study start. Male CD-1 mice were randomly assigned to one of four exposure groups (n = 25 mice/exposure group). Randomization was stratified by body weight that produced similar group mean weights using NTP Provantis software (Instem, Stone, UK). Male CD-1 mice were exposed to α-pinene via whole-body inhalation for 6 hours plus T_90_ per day for 5 days per week (excluding holidays) at one of four target concentrations (0, 100, 200, or 400 ppm) for 3 months.

Five CD-1 mice were randomly selected for parasite evaluation and gross observation of disease. The health of the mice was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Following 3 months of exposure, male CD-1 mice were removed from exposure, transferred to the room housing unexposed naïve female CD-1 mice, and housed individually for 2 days before cohabitation. Unexposed CD-1 females were approximately 12 weeks old upon receipt and were quarantined for 11 days before study start. Female CD-1 mice were randomly assigned to male CD-1 mice for mating purposes only and were never administered α-pinene. The first day of cohabitation marked reproductive study day 1, when unexposed CD-1 females were mated with exposed CD-1 males. Reproductive study CD-1 mice remained paired until evidence of mating was confirmed by daily examination (vaginal copulatory plug or presence of sperm in vaginal lavage) or until reproductive study day 15, whichever came first. Upon confirmation of copulation, CD-1 males and females were housed individually until study termination, and this was considered GD 0. During the mating period, individual body weights of male and female CD-1 mice were obtained weekly, beginning on the first day of cohabitation through reproductive study day 15 and again before study termination. Following confirmation of mating, female CD-1 mice were weighed twice weekly, beginning on GD 0 through GD 14.

Two diets were used in the 3-month reproductive study: (1) NTP-2000 during the 13-week exposure phase for CD-1 males and (2) NIH-07 during cohabitation until termination. The NIH-07 diet is a higher protein diet that supports reproduction and lactation in rodents, whereas the NTP-2000 diet is a lower protein diet that decreases the incidence of chronic nephropathy in adult mice. Information on feed composition and contaminants for both diets is provided in Appendix B.

## Clinical Examinations and Pathology for Two-year and Three-month Studies

In the 2-year studies in rats and mice, animals were observed twice daily for signs of morbidity and moribundity and were weighed initially, weekly for the next 13 weeks, every 4 weeks thereafter, and at study termination. Clinical observations were recorded every 4 weeks, coinciding with body weight collection days, and at study termination.

Necropsies were performed on the 3-month study male B6C3F1/N mice following 3 months of exposure and the 3-month reproductive study male rats and CD-1 mice following 3 months of exposure and subsequent cohabitation and potential breeding with naïve females. Organ weights were recorded for the left and right testes and left and right epididymides. Samples were collected for sperm motility and count evaluations from 3-month study male B6C3F1/N mice and the 3-month reproductive study male rats and CD-1 mice. The parameters evaluated are listed in Table 1. The tail of the epididymis (cauda epididymis) was removed and weighed. An incision was made in the distal region of the left cauda epididymis, and the cauda was placed in a beaker containing M199 solution (maintained at approximately 37°C) with 0.5% bovine serum albumin (BSA). A small sample of the diluted sperm was loaded into an 80 µm-chambered slide for determination of motility. After completion of sperm motility estimates, the remainder of the diluted sperm and cauda epididymis in M199/BSA solution and the left testis were stored frozen (approximately −70°C) until enumeration of sperm concentration was performed. The left cauda epididymis in M199/BSA solution was thawed, homogenized, and evaluated for epididymal sperm numbers. The left testis was thawed and homogenized in 0.9% saline with 0.05% Triton-X 100. Homogenized samples were mixed with a DNA-specific fluorescent dye (IDENT) to allow for sperm identification under fluorescent illumination. Given the artifacts identified (e.g., clumping of cells, too many sperm in sample), meaningful interpretation of sperm motility and count data was not possible, nor was enumeration of epididymal and testicular sperm concentration and sperm production rate. A gross and histopathological examination of the urinary bladder and kidneys was performed on 10 randomly selected 3-month reproductive study male rats per exposure group. A gross and histopathological examination of the urinary bladder was performed for all 3-month study B6C3F1/N male mice and for 10 designated 3-month reproductive study CD-1 male mice per exposure group. For all male rats and CD-1 mice in the 3-month reproductive and B6C3F1/N mice in the 3-month studies, the right testis, right epididymis, and the remainder of the left epididymis (for rats) were examined. The right testis, right epididymis, and remainder of the left epididymis were first fixed in modified Davidson’s solution and then preserved in 10% neutral buffered formalin (NBF). Tissues were processed and trimmed, embedded in paraffin, sectioned at a thickness of 4–6 μm, and stained with H&E for microscopic evaluation. For molecular pathology, a sample of grossly normal urinary bladder and half of any gross lesions of the urinary bladder were collected and frozen.

Necropsies were also performed on the 3-month reproductive study female rats and CD-1 mice following the mating period (for females with no evidence of mating, with the exception of 11 rats and four CD-1 mice that were kept on the study because of body weight changes indicative of pregnancy) or at study termination on GD 14 (for females exhibiting evidence of mating) for gross examination, and the number of viable and nonviable embryos, early resorptions, and the total number of implantations were recorded. The number of corpora lutea on each ovary was recorded for gravid females that did not deliver. Uteri that appeared nongravid upon macroscopic evaluation were opened (for rats only) and placed in a 10% (rats) or 11.5% (CD-1 mice) ammonium sulfide solution for detection of early implantation loss.

Blood was collected from the heart of up to 10 (rats) or 11 (mice) randomly selected animals per sex per exposure group to determine the feasibility of internal concentration assessment at the end of the 2-year studies for rats and B6C3F1/N mice (Appendix D). Animals were anesthetized with a 70% carbon dioxide/30% oxygen mixture and bled in a random order. Blood was collected into tubes containing tripotassium ethylenediaminetetraacetic acid (K_3_ EDTA). Two 100 μL aliquots of whole blood were transferred into separate tubes and stored frozen (approximately −70°C). Remaining blood was processed to plasma, and three aliquots (at least 100 μL each) of plasma were collected and stored frozen (approximately −70°C). Tissues from mammary glands 1, 2, and 3 were collected from up to 16 (rats) or 26 (mice) female animals and B6C3F1/N mice per exposure group. Each side was stored separately, with one side used for internal concentration assessment and the other side used for molecular pathology. Both sides were snap frozen in liquid nitrogen and stored frozen (approximately −70°C). For internal concentration assessment, α-pinene and α-pinene oxide concentrations were determined in whole blood samples using a qualified method (Appendix D) and in the mammary gland using a validated method.^62,63^

Complete necropsies and microscopic examinations were performed on all rats and B6C3F1/N mice at the end of the 2-year studies. All organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% NBF, except for the eyes, which were first fixed in Davidson’s solution, and testes, vaginal tunics, and epididymides, which were first fixed in modified Davidson’s solution. Lungs were fixed using a Marriott bottle at approximately 25 cm water pressure or until fixative flow stopped due to equalization of pressure. The uterus/cervix/vagina and ovaries were mounted on cardstock before fixation. Rat mammary and mouse liver and lung tumors >5 mm in diameter were dissected in half, and one-half was collected in 10% NBF and the other half was snap frozen in liquid nitrogen and stored at −80°C until processed for a molecular pathology study (Appendix E). Tissues were processed and trimmed, embedded in paraffin, sectioned at a thickness of 4–6 μm, and stained with hematoxylin and eosin (H&E) for microscopic examination. Complete histopathological examinations were performed by the study laboratory pathologist on all organs with gross lesions and on all tissues collected from all rats and mice in the 2-year studies. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by a board-certified veterinary pathologist, and the pathology data were entered into the NTP Provantis software (Instem, Stone, UK). The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory and storage. An audit of pathology specimens was conducted wherein the wet tissues, blocks, and slides were examined for quality and adherence to the NTP Specifications (published in 2011)^64^ by technical staff, and the wet tissues were examined by a team of pathologists to ensure all tissues were sampled according to NTP Specifications. The slide and tissue counts were also verified. Slide-mounted, H&E-stained slides were evaluated for accuracy and consistency of diagnoses by a team of quality assessment (QA) pathologists at a pathology laboratory independent of the study laboratory. The histotechnique was also evaluated. For the 2-year studies, QA pathologists evaluated slides from all tumors and all potential target organs and other slides as identified during the pathology data review, which included the Harderian gland (B6C3F1/N mice only), liver (B6C3F1/N mice only), nose, larynx, trachea, lung, bone marrow (rats only), stomach (forestomach; B6C3F1/N mice only), testis (B6C3F1/N mice only), epididymis (B6C3F1/N mice only), mammary gland (females only), ovary (B6C3F1/N mice only), and urinary bladder (B6C3F1/N mice only) of core animals, as well as the kidney (rats only), testis, epididymis, and urinary bladder (B6C3F1/N and CD-1 mice only) of the 3-month study male B6C3F1/N mice and 3-month reproductive study male rats and CD-1 mice.

The QA report and the reviewed slides were submitted to the Pathology Working Group (PWG) coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and QA pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the QA pathologist and other pathologists experienced in rodent toxicological pathology. When the PWG consensus diagnosis differed from that of the laboratory pathologist, the diagnosis was changed. The study pathologist and QA pathologist read the slides in an informed manner (with knowledge of the animal numbers and which exposure groups the animals were from), but the PWG members reviewed the slides in a blinded fashion (with no knowledge of exposure groups). The rationale for this is presented in Sills et al.^65^ Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^66^ and Boorman et al.^67^ For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of Brix et al.^68^

## Three-month Investigative Study in Rats

### Study Design

Male and female Sprague Dawley rats were approximately 4 weeks old on receipt and were quarantined for 13–15 days before study start. Rats were randomly assigned to one of four exposure groups (core group: n = 10 rats/sex/exposure group; biosample group: n = 5 rats/sex/exposure group). Randomization was stratified by body weight that produced similar group mean weights using NTP Provantis software (Instem, Stone, UK). Rats were exposed to α-pinene via whole-body inhalation for 6 hours plus T_90_ per day for 5 days per week (excluding holidays) at one of four target concentrations (0, 50, 100, or 200 ppm) for 3 months.

Five male and five female rats were randomly selected for parasite evaluation and gross observation of disease. The health of the rats was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Rats were housed individually. Feed and water were available ad libitum, except during exposure when feed was removed. Cages and racks were changed and rotated at least once weekly. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is given in Appendix B.

### Clinical Examinations and Pathology

In the 3-month investigative study, rats were observed twice daily for signs of morbidity or moribundity and were weighed on the first day of exposure, weekly thereafter for the next 3 months, and at study termination. Clinical observations were recorded at least weekly and at study termination.

On the last day of exposure, animals designated for biosampling were removed immediately following exposure for tissue and blood collection. Animals were anesthetized with a 70% carbon dioxide/30% oxygen mixture and bled in a random order. Blood was collected from the retroorbital plexus into tubes containing K_3_ EDTA, aliquoted as appropriate for analysis of α-pinene and α-pinene oxide (Appendix D), and stored between −85°C and −60°C. Immediately following terminal blood collection, samples of the fourth and/or fifth mammary gland were excised, trimmed of excess adipose tissue, divided as appropriate for analysis, flash frozen in liquid nitrogen, and stored between −85°C and −60°C. For internal concentration assessment, whole blood and mammary gland samples were analyzed for α-pinene and α-pinene oxide concentrations using a previously validated method.^62,63^

Samples were collected for vaginal cytology and sperm motility evaluations and a limited necropsy was performed on all rats. Vaginal cytology smears were prepared for all female core group rats for 17 consecutive days up to and including the day of scheduled necropsy and for all female biosample group rats only on the day of necropsy. The estrous stage was determined for females on the basis of microscopic evaluation of the uterine and vaginal epithelial tissue. Organ weights were recorded for the left testis and left epididymis. The cauda epididymis was removed and weighed. Sperm motility and count were determined in the core males at the time of necropsy, using the Tox IVOS^®^ analysis system. At necropsy, all organs and tissues were examined for grossly visible lesions. The tissues collected (epididymides, mammary glands, testes, uterus, cervix, and vagina) were fixed and preserved in 10% NBF except for the testis and epididymis, which were first fixed in modified Davidson’s solution. Tissues were processed and trimmed, embedded in paraffin, sectioned at a thickness of 4–6 μm, and stained with H&E for microscopic examination. The parameters evaluated are listed in Table 1.

For the female core rats, the fourth and fifth mammary glands were removed as a single tissue. The mammary gland was slide-mounted, fixed, stained in carmine alum, and made transparent for 3-dimensional evaluation of the epithelial structures. Due to issues with sample quality, the slides were not evaluated.

## Statistical Methods

For all analyses, p values ≤0.05 were considered statistically significant. Statistical significance is one component of the “weight-of-evidence” approach to evaluate carcinogenicity (described in the Explanation of Levels of Evidence of Carcinogenic Activity section).

### Survival Analyses

The probability of survival in the chronic studies was estimated by the product-limit procedure of Kaplan and Meier^69^ and is presented graphically. Animals surviving to the end of the observation period are treated as censored observations (i.e., included in analysis while accounting for unknown true lifespan), as are animals dying from unnatural causes (e.g., via laboratory accident) within the observation period. Animals dying from natural causes (i.e., found dead or moribund) are included in analyses and are treated as uncensored observations. Exposure concentration-related trends are identified with Tarone’s life-table test,^70^ and pairwise exposure concentration-related effects are assessed using Cox’s method.^71^ All reported p values for the survival analyses are two-sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented as the numbers of animals bearing such lesions at a specific anatomic site. For calculation of incidence rates, the denominator for most neoplasms and all nonneoplastic lesions is the number of animals for which the site was examined microscopically. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominator consists of the number of animals on which a necropsy was performed. Additional study data also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm in the chronic studies. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal euthanasia.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidence

The Poly-k test^72-74^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to account for survival differences. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is 1 if the animal had a lesion at that site or if it survived until terminal euthanasia; if the animal died before terminal euthanasia and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only on the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^72^ Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^72^ after an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control Fischer 344 (F344) rats and B6C3F1 mice.^75^ Bailer and Portier^72^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^76^ Poly-3 tests used the continuity correction described by Nam.^77^

Tests of significance included pairwise comparisons of each exposed group with control groups and a test for an overall exposure concentration-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence in the chronic studies. No Poly-3 adjustment is needed for subchronic studies, so Cochran-Armitage trend tests and Fisher’s exact test were used. All reported p values are one-sided.

### Analysis of Continuous Variables

Before statistical analysis, outliers identified using the Dixon and Massey test^78^ for small samples (n < 20) and Tukey’s outer fences method^79^ for large samples (n ≥ 20) were examined by Division of Translational Toxicology (DTT) personnel, and biologically implausible values (likely due to experimental error) were eliminated from the analysis. Organ and body weight measurements, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^80^ and Williams.^81,82^ Per-litter endpoints (live embryos, dead embryos, early/late resorptions, total resorptions), precoital interval, corpora lutea per female, pre/postimplantation loss, and tissue concentration data were analyzed using the nonparametric multiple comparison methods of Shirley^83^ (as modified by Williams^84^) and Dunn,^85^ given that these endpoints typically have skewed distributions. For all quantitative endpoints unaffected by litter structure, the Jonckheere test^86^ was used to assess the significance of the exposure concentration-related trends and to determine at the 0.01 level of significance whether a trend-sensitive test (the Williams or Shirley test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic exposure concentration-related trend (the Dunnett or Dunn test). P values for these analyses are two-sided.

### Analysis of Gestational and Fertility Indices

Cochran-Armitage trend tests were used to test the significance of trends in gestational and fertility indices across exposure groups. Fisher’s exact test was used to conduct pairwise comparisons of each exposed group with the control group. P values for these analyses are two-sided.

### Analysis of Vaginal Cytology Data

Vaginal cytology data consist of daily observations of estrous cycle stages over a 17-day period. Differences from the control group for cycle length and number of cycles were analyzed using a Dunn’s test or a Shirley’s test as determined by the results of a Jonckheere trend test.

To identify disruptions in estrous cyclicity, a continuous-time Markov chain model (multistate model) was fit using a maximum likelihood approach,^87^ producing estimates of stage lengths for each exposure group, or these estimates were obtained using bootstrap sampling of the individual animal cycle sequences. Stage lengths that were significantly different from the control group were identified using permutation testing with a Hommel adjustment.

### Historical Control Data

The concurrent control group is the most valid comparison to the exposure groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential exposure-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control data must be generally similar. Significant factors affecting the background incidence of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period,^88-90^ including the concurrent control for comparison across multiple technical reports. In general, the historical control data for a given study include studies using the same route of administration, and the overall incidence of neoplasms in control groups for all routes of administration is included for comparison, including the current study. Note that in this report, the historical control data for the inhalation route of exposure consist of three studies, one of which is the current study.

## Quality Assurance Methods

The 2-year and 3-month rat and 2-year mouse studies were conducted in compliance with U.S. Food and Drug Administration Good Laboratory Practice Regulations.^91^ In addition, the study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by DTT staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.