# Introduction

## Chemical and Physical Properties

α-Pinene (Figure 1) is a bicyclic monoterpene within the diverse terpene class of compounds. It is a fragrant volatile organic compound emitted from natural sources as well as anthropogenic activities. α-Pinene exists naturally as a mixture of (+) and (−) enantiomers. It is a clear colorless liquid with a boiling point of 155°C and a vapor pressure of 4.75 mm Hg. α-Pinene is poorly soluble in water (1.82 × 10^−5^ mol/L) and has a logP (octanol:water partition coefficient) value of 4.83.^8,9^ Once in the atmosphere, α-pinene can react with ozone to create secondary organic aerosols.^10^

Figure 1

α-Pinene (CASRN 80-56-8; Chemical Formula: C_10_H_16_; Molecular Weight: 136.24 g/mol)

Synonyms: acitene A; cyclic dexadiene; 2-pinene; 2,6,6-trimethylbicyclo[3.1.1]hept-2-ene.

## Production, Use, and Human Exposure

α-Pinene occurs naturally in a wide variety of plants, such as pine trees,^11^ rosemary and other herbs,^12^ and cannabis.^13^ Various essential oils (i.e., hydrophobic liquid fractions extracted from plants) contain α-pinene (e.g., turpentine contains 44% to 94% α-pinene) along with other volatile hydrocarbons.^14^ The ratio of (+) to (−) enantiomers of α-pinene can differ across plant species and plant parts, with ranges of 27%–62% (+) α-pinene and 38%–73% (−) α-pinene measured in Norway spruce (Picea abies), Scots pine (Pinus sylvestris), and juniper (Juniperus communis) in one study^15^ and ranges of 72%–89% (+) α-pinene and 11%–28% (−) α-pinene measured in loblolly pine (Pinus taeda) in another study.^16^ Much larger ranges of enantiomeric ratios were measured in cannabis (Cannabis sativa) at 0%–90% (+) α-pinene and 10%–100% (−) α-pinene.^17^ Turpentine has been used in complementary medicine as a topical antibacterial ointment,^18^ and pine bark extract is a common dietary supplement ingredient.^19^ α-Pinene, within essential oil mixtures or as a pure compound, is widely used as a flavor and fragrance ingredient. The daily per capita intake of α-pinene in the United States from food was estimated to be 317 µg/day.^20^ The fragrance profile of α-pinene has made it a popular ingredient in consumer products. It can be found in personal care products, air fresheners, and cleaners.^21-23^ The fragrance associated with α-pinene differs between enantiomers, with (−) α-pinene having a pine scent and (+) α-pinene having a slightly minty scent.^24^

A summary of literature reporting exposure to α-pinene from consumer products, occupational exposures, and indoor air environments is available in Appendix G. Occupational exposure to α-pinene in the lumber industry has been widely reported. In a Canadian softwood lumber mill, α-pinene levels were measured ranging from below the limit of detection (LOD; 0.3 µg/m^3^) to 5.1 mg/m^3^ (approximately 0.92 ppm).^25^ New Zealand plywood mill workers were exposed to α-pinene concentrations with geometric means ranging from 0.5 to 2.4 mg/m^3^ (approximately 0.09 to 0.43 ppm).^26^ Higher levels of α-pinene were measured in Finnish saw mills with arithmetic means in the range of 57 to 152 mg/m^3^ (approximately 10 to 27 ppm) and total monoterpenes (α-pinene, β-pinene, Δ^3^-carene, and limonene) reaching 326 mg/m^3^ (approximately 59 ppm).^27^ Similarly, total terpenes measured in a Swedish saw mill ranged from 100 to 550 mg/m^3^ (approximately 18 to 99 ppm), with an average of 254 mg/m^3^ (approximately 46 ppm).^28^ While α-pinene has been measured in other occupational settings with anticipated exposure (e.g., greenhouses or industries in which cleaning and consumer products containing α-pinene are widely used), levels appear to be an order of magnitude lower than in the lumber industry. For example, in a National Institute for Occupational Safety and Health (NIOSH) study measuring volatile organic compounds in health care workers, α-pinene exposures were in the low ppb range (median concentrations <0.25 ppb).^29^

α-Pinene is frequently detected in studies evaluating indoor air quality. For example, α-pinene was measured in 100% of indoor air samples from three cities in Michigan, with overall mean, median, and maximum values of 9.04, 3.16, and 139.2 µg/m^3^ (0.0016, 0.00057, and 0.025 ppm), respectively.^30^ In a study of emissions from a newly manufactured house, α-pinene was measured at 0.042 ppm.^31^ Concentrations of α-pinene inside taxis ranged from 0.2 to 1.8 µg/m^3^ (approximately 0.00004 to 0.00032 ppm).^32^ A review of the effects of excessive fragrances on indoor air quality cataloged mean and maximum concentrations of α-pinene ranging from 0.1 to 32 µg/m^3^ (approximately 0.00002 to 0.00574 ppm) and 0.7 to 854 µg/m^3^ (approximately 0.00013 to 0.15 ppm), respectively.^33^

In the United States, occupational exposure limits pertain to turpentine and are not specific to α-pinene. The NIOSH-recommended exposure limit and the Occupational Safety and Health Administration (OSHA) permissible exposure limit for turpentine are both 100 ppm, whereas the American Conference of Governmental Industrial Hygienists (ACGIH) threshold limit value is 20 ppm.^34-36^ Belgium, Canada, and Switzerland each have an occupational exposure limit for α-pinene of 20 ppm, whereas Sweden’s limit is 25 ppm.^37^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

As part of the NTP research program on α-pinene, the toxicokinetic (TK) behavior of α-pinene and its potential reactive metabolite, α-pinene oxide, was investigated in the blood and mammary gland following whole-body inhalation exposure of adult male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and B6C3F1/N mice to α-pinene for 6 hours per day for 7 days at 50 ppm (279 and 282 mg/m^3^ for rats and mice, respectively) or 100 ppm (557 and 561 mg/m^3^ for rats and mice, respectively).^6^ The focus on α-pinene oxide was based on its status as a metabolite of α-pinene^38^ and the potential reactivity based on its structure.

In both rats and mice, the systemic exposure to α-pinene increased with exposure concentration. Given the blood maximum concentration (C_max_) and area under the curve (AUC), the exposure in female rats was approximately 1.5-fold and 2-fold higher, respectively, than in male rats.^6^ However, unlike in rats, no sex difference in systemic exposure to α-pinene was found in mice. When the magnitude of systemic exposure to α-pinene was compared between rats and mice, male and female rats had higher exposures than male and female mice. α-Pinene was eliminated from blood with half-lives of 12.2–17.4 hours for rats and 6.18–19.4 hours for mice. The long elimination half-life suggests α-pinene has a high affinity for poorly perfused tissues.

α-Pinene oxide was measured in the blood of rats and mice of both sexes, and concentrations were lower than α-pinene. In general, α-pinene oxide increased with the exposure concentration of α-pinene in rats and mice. The ratio of α-pinene oxide to α-pinene was higher in rats (C_max_ ratio 0.200–0.237; AUC ratio 0.279–0.615) than in mice (C_max_ ratio 0.060–0.086; AUC ratio 0.036–0.105) at 50 ppm, and females had higher values than males in both species. The ratio was lower at the higher exposure concentration of 100 ppm, pointing to saturation of pathways leading to the formation of α-pinene oxide, and the decrease was more evident in rats than in mice. There were no apparent species or sex differences in the ratio of α-pinene oxide to α-pinene at 100 ppm. The blood elimination half-life of α-pinene oxide in rats was 11.6–19.2 hours, with no apparent exposure concentration- or sex-related differences. The blood elimination half-life of α-pinene oxide in mice was shorter than in rats, with male mice having a longer half-life than female mice (7.70–7.91 hours versus 1.31–2.37 hours, respectively) and with no apparent exposure concentration-related difference.^6^

α-Pinene and α-pinene oxide were distributed to the mammary glands of rats and mice of both sexes. α-Pinene and α-pinene oxide concentrations in mammary glands were ≥23-fold higher than those in blood, demonstrating retention of these analytes in lipid-rich tissues. Many of the patterns described in blood were also observed in mammary glands, with female rats having higher concentrations than male rats and rats having higher concentrations than mice.

### Humans

The TK behavior of α-pinene has been reported in male volunteers (n = 8) following a single inhalation exposure to 10, 225, or 450 mg/m^3^ (1.8, 40, or 81 ppm, respectively) of (+) α-pinene for 2 hours during mild physical exercise.^39^ During exposure, α-pinene blood concentrations first increased rapidly, then leveled off, reaching a maximum at the termination of exposure, before declining postexposure. α-Pinene blood concentrations at the termination of exposure increased linearly with the exposure concentration. For the 10 and 225 mg/m^3^ exposures, blood α-pinene concentrations were below the LOD (10 nmol/L) 4 hours after exposure; hence, TK parameters were provided only for the 450 mg/m^3^ group. The elimination of α-pinene from blood was triphasic with alpha-, beta-, and gamma-phase half-lives of 4.8 minutes (0.08 hours), 38 minutes (0.63 hours), and 695 minutes (11.6 hours), respectively. The estimated clearance up to 21 hours after exposure at 450 mg/m^3^ was 1.09 L/h*kg. The authors reported no difference in the observed TK behavior following exposure to 450 mg/m^3^ (−) α-pinene enantiomer.^39^ In another investigation, following inhalation of α-pinene as turpentine, the observed TK behavior of α-pinene in male volunteers was demonstrated to be similar.^40^ Urinary metabolites identified following inhalation exposure in humans (sex not specified) were cis- and trans-verbenol and myrtenol.^41,42^

## Toxicity

### Experimental Animals

Previous NTP studies investigated the toxicity of α-pinene in male and female Fischer 344 (F344/N) rats and B6C3F1/N mice following whole-body inhalation exposure 6 hours per day, 5 days per week for 2 weeks and 3 months.^2^ In the 2-week studies, following exposure to 0, 100, 200, 400, 800, or 1,600 ppm α-pinene, a significant decrease in survival of male and female rats and mice in the 800 and 1,600 ppm groups was observed. Clinical signs of toxicity were observed in rats exposed to ≥400 ppm and mice exposed to ≥800 ppm, as well as significantly increased absolute and/or relative liver weights in both species. In the 3-month studies following exposure to 0, 25, 50, 100, 200, or 400 ppm, all animals survived to the end of the study except six out of ten 400 ppm female rats that died before study termination. The major target organs were the urinary system (kidney of rats and urinary bladder of mice) and the male reproductive system.^2^ In prenatal developmental studies with gavage administration of an essential oil containing α-pinene (20% to 25%), β-pinene (15% to 18%), and sabinene (38% to 42%), the number of live offspring per dam was significantly decreased at doses ≥120 and ≥56 mg/kg body weight/day (mg/kg/day) in CD-1 mice and Wistar rats, respectively.^43^ α-Pinene was positive in an acute dermal irritation assay.^44^ Results in skin sensitization assays were mixed. α-Pinene tested negative in a guinea pig maximization test^44^ and a murine local lymph node assay,^45^ but was positive in an open epicutaneous test in guinea pigs.^46^

### Humans

In humans, reports of toxicity resulting from α-pinene alone or terpene mixtures containing α-pinene indicate potential respiratory and skin irritation. Johard et al.^47^ assessed the effects of short-term inhalation exposure to a terpene mixture (α-pinene, β-pinene, and Δ^3^-carene) on bronchioalveolar lavage fluid from eight healthy volunteers and found that macrophage and mast cell counts increased following exposure to 450 mg/m^3^. Irritation of the eyes, nose, and throat has been observed in volunteers exposed to 450 mg/m^3^ α-pinene.^39^ Dermal exposure to α-pinene has been associated with an allergic response.^48^

## Reproductive and Developmental Toxicity

Limited data are available on the reproductive and developmental toxicity of α-pinene. In the NTP 3-month toxicity inhalation studies of α-pinene in male and female F344/N rats and B6C3F1/N mice, significantly lower numbers of sperm per cauda compared to the chamber control group were observed in the 200 and 400 ppm male rats (19% lower) and 100, 200, and 400 ppm male mice (24%, 33%, and 40% lower, respectively). Mouse testis weight in the 400 ppm group was 7% lower than that of the control group.^2^ In a screening-level hazard characterization of bicyclic terpene hydrocarbons, the U.S. Environmental Protection Agency referenced a series of developmental toxicity studies in CD-1 mice, Wistar Han rats, and golden hamsters dosed via gavage on gestation day (GD) 6 through GD 15 with an essential oil containing 20%–25% α-pinene, 15%–18% β-pinene, and 38%–42% sabinene.^43^ Significant decreases in live offspring per dam were reported in mice at 120 and 560 mg/kg/day and rats at 56 and 260 mg/kg/day but not in hamsters.^43^

## Carcinogenicity

Limited carcinogenicity data are available for α-pinene. Two epidemiological studies have examined associations between turpentine or terpene exposure in occupational settings and cancer outcomes. In a case-control study of Finnish woodworkers, a weak association (odds ratio [OR] = 1.33; 95% confidence interval [CI]: 0.78, 2.27 for any exposure to terpenes lasting over 1 month) was found between respiratory cancer and exposure to terpenes (primarily α-pinene and Δ^3^-carene) and other heating products of pine and spruce.^49^ Another case-control study found an association between paternal exposure to turpentine and neuroblastoma in offspring (OR = 1.9; CI: 1.0, 3.6 to 10.4; CI: 2.4, 44.8, depending on methods for exposure categorization).^50^ The literature contains limited studies on the chronic toxicity of α-pinene. A single study in rats, aimed at characterizing potential chronic nephrotoxicity associated with turpentine exposure, used a rudimentary inhalation chamber to expose animals to turpentine at unknown concentrations and found no exposure-related histopathological changes in the kidney following up to 293 days of exposure.^51^

## Genetic Toxicity

Results from previous NTP genotoxicity tests, including the original Ames test with α-pinene at doses up to 10,000 μg/plate in three strains of bacteria, as well as in vivo peripheral blood micronucleus tests conducted in male and female B6C3F1/N mice that were integrated into the 3-month NTP toxicity studies, were reported previously in TOX 81.^2^ Both tests yielded negative results, indicating that in these two assays, α-pinene was not mutagenic and did not induce chromosomal alterations.

In contrast, a recent study demonstrated that the metabolite α-pinene oxide was highly mutagenic in the Ames test.^5^ The authors proposed that α-pinene is metabolized to α-pinene oxide in the standard Ames test when in the presence of rat liver S9, but the concentrations of α-pinene oxide generated by S9 are approximately threefold lower than the lowest dose (25 μg/plate) of α-pinene oxide that showed mutagenic activity. Therefore, metabolism may be a factor to consider in all in vitro assays conducted with the parent compound α-pinene.

Consistent with the earlier NTP data, results of several other mutation assays with α-pinene that used multiple strains of bacteria, with and without rat liver S9 mix, were also negative.^52-54^ Two other monoterpenes, β-myrcene and α-terpinene, were shown to be nonmutagenic in several strains of Salmonella typhimurium, with and without rat liver S9.^54,55^ In contrast, pine bark extract induced mutations in S. typhimurium strains TA100 (only with S9) and TA98 (with and without S9),^56^ two strains that detect different mechanisms of mutation. Pine bark extract is the only monoterpene-related substance tested in NTP studies that has shown mutational potential in bacteria and, for strain TA98, both directly (without S9) and after metabolic activation (with S9). However, the increases in mutational events induced by pine bark extract were seen only at high doses that generally exceeded the Organisation for Economic Co-operation and Development (OECD)-recommended assay limit dose.^56,57^

No in vivo studies have been reported for α-pinene aside from the NTP in vivo micronucleus study referenced above, but a few reports from in vitro mammalian cell assays have examined DNA damage and chromosomal alterations following exposure to α-pinene. No induction of DNA damage, as measured by the comet assay, was detected in human lung A549 cells exposed to α-pinene in air in a closed system at concentrations ranging from 1 to 1,800 mg/m^3^.^58^ In contrast, exposure of Chinese hamster V79-C13 cells to α-pinene in cell culture medium was reported to induce genetic damage in the form of DNA damage (comet assay), micronuclei, and chromosome breaks; the effective concentrations of α-pinene ranged from 25 to 35 µM.^59^ These authors also reported an increase in endoreduplication and aberrant mitotic figures in α-pinene-treated cells, indicating interference with microtubule functions. A similar study measured DNA damage, micronucleus induction, and chromosomal damage in cultured human lymphocytes treated with α-pinene concentrations ranging from 0 to 200 µg/mL; in this study, no increases in any of the three endpoints of genotoxicity were observed, despite a decrease in cell viability at 200 µg/mL.^60^

The negative results with α-pinene in the in vitro human cell studies are interesting in light of the results from a recent human biomonitoring study of artists who were exposed daily to turpentine used as an oil paint thinner.^61^ In this study, blood samples were obtained from turpentine-exposed subjects and from nonexposed age- and sex-matched control subjects, and lymphocytes were cultured and evaluated in the cytokinesis-block micronucleus assay. A significant increase in micronucleated binucleated lymphocytes was observed in the turpentine-exposed group, along with other indicators of nuclear damage, such as nuclear buds, which are evaluated in this assay. Cytotoxicity was also significantly higher in the cell cultures derived from the exposed group compared with the nonexposed control samples. The researchers further stratified their exposed subjects by duration of turpentine use in preparing their paints and determined that micronucleus frequencies increased significantly with prolonged exposure.

It is possible that cytogenetic damage in exposed humans may be induced by certain constituents of turpentine or reactive metabolites of turpentine such as α-pinene oxide. α-Pinene oxide was also shown to be a potent mutagen in the Ames test, in contrast to the lack of mutagenicity observed with the parent compound α-pinene.^5^ Reactive metabolites may not be produced in sufficient amounts in human cell cultures to induce measurable genotoxicity.

## Study Rationale

The International Union of the United Auto Workers originally nominated turpentine to NTP for comprehensive assessment because of widespread exposure potential and a lack of chronic toxicity data. α-Pinene was selected for study because it is both a major constituent of turpentine and has a wider exposure profile from its use as a fragrance and flavoring ingredient. An inhalation route was chosen to reflect occupational exposure in the lumber and cleaning industries, as well as exposure through the use of consumer products such as air fresheners and perfumes. Previously reported NTP 2-week and 3-month inhalation toxicity studies with α-pinene in male and female F344/N rats and B6C3F1/N mice revealed an exposure-related significant increase in hyperplasia in the urinary bladder of mice, a potentially preneoplastic lesion, and significantly decreased cauda epididymal sperm in both rats and mice.^2^ Based on these findings, 2-year inhalation studies in Sprague Dawley rats and B6C3F1/N mice and a reproductive assessment following a 90-day exposure in male Sprague Dawley rats and CD-1 mice that were mated with naïve females were conducted. During the chronic study, early deaths observed in female rats were attributed to mammary masses or nodules and prompted a follow-up investigative 3-month study in male and female rats to evaluate early biomarkers of carcinogenicity in the mammary gland and measure internal concentrations of α-pinene and α-pinene oxide. Additionally, sperm parameters were evaluated because of the lack of sperm data from the reproductive assessment.