# Appendix G Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TR-606.

## G.1 Summary of Exposure Information

Exposure Tables

## G.2 Short-Term

### G.2.1 Three-Month Investigative Study Tables – Rats

Estrous Cycle Plots

I01 – Animal Removal Summary

I02 – Animal Removals

I03 – Growth Curve

I03C – Growth Curve

I04 – Mean Body Weight Summary

I04G – Mean Body Weight Gain

I05 – Clinical Observations Summary

PA02 - Incidence Rates of Neoplasms by Anatomic Site

PA03 - Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

PA05 - Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

PA06 - Organ Weights Summary

PA10- Statistical Analysis of Non-Neoplastic Lesions

PA14 - Individual Animal Pathology Data

PA18 - Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

PA46 - Summary of Gross Pathology

PA48 - Summary of Internal Concentration

R06 - Andrology Summary

repVaginal Cytology CMTC Results

Vaginal Cytology CMTC Results

repVaginal Cytology Summary

Vaginal Cytology Summary

### G.2.2 Three-Month Investigative Individual Animal Data – Rats

Individual Animal Andrology Data

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Gross Pathology Data

Individual Animal Internal Concentration

Individual Animal Organ Weight Data

Individual Animal Removal Reasons Data

### G.2.3 Three-Month Reproductive Study Tables – CD-1 Mice

I01 - Animal Removal Summary

I02 - Animal Removals

I03 - Growth Curve

I03C - Growth Curve

I04 - Mean Body Weight Summary

I04G - Mean Body Weight Gain

I05 - Clinical Observations Summary

PA02 - Incidence Rates of Neoplasms by Anatomic Site

PA03 - Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

PA04 - Neoplasms by Individual Animal

PA05 - Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

PA06 - Organ Weights Summary

PA07: Neoplasms By Individual Animal (Systemic Lesions Abridged)

PA09 - Non-Neoplastic Lesions by Individual Animal

PA10 - Statistical Analysis of Non-Neoplastic Lesions

PA14 - Individual Animal Pathology Data

PA18 - Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

PA46 - Summary of Gross Pathology

R02 - Reproductive Performance Summary

R09 - Uterine Content Summary

### G.2.4 Three-Month Reproductive Individual Animal Data – CD-1 Mice

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Gross Pathology Data

Individual Animal Histopathology Data

Individual Animal Organ Weight Data

Individual Animal Removal Reasons Data

Individual Animal Teratology Dam Data

Individual Animal Teratology Fetal Weight Data

Individual Animal Teratology Implant Findings Data

## G.3 Long Term

### G.3.1 Three-Month Reproductive and Chronic Study Tables – Rats

I01 - Animal Removal Summary

I02 - Animal Removals

I03 - Growth Curve

I03C - Growth Curve

I04 - Mean Body Weight Summary

I04G - Mean Body Weight Gain

I05 - Clinical Observations Summary

PA02 - Incidence Rates of Neoplasms by Anatomic Site

PA03 - Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

PA04 - Neoplasms by Individual Animal

PA05 - Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

PA06 - Organ Weights Summary

PA07: Neoplasms By Individual Animal (Systemic Lesions Abridged)

PA08 - Statistical Analysis of Primary Tumors

PA09 - Non-Neoplastic Lesions by Individual Animal

PA10 - Statistical Analysis of Non-Neoplastic Lesions

PA11 - Statistical Analysis of Survival Data

PA14 - Individual Animal Pathology Data

PA18 - Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

PA40C - Survival Curves

PA46 - Summary of Gross Pathology

PA48 - Summary of Internal Concentration

R01 - Multigeneration Cross Reference

R02 - Reproductive Performance Summary

R09 - Uterine Content Summary

### G.3.2 Three-Month Reproductive and Chronic Individual Animal Data – Rats

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Gross Pathology Data

Individual Animal Histopathology Data

Individual Animal Internal Concentration

Individual Animal Organ Weight Data

Individual Animal Removal Reasons Data

Individual Animal Reproductive Performance Data

Individual Animal Teratology Dam Data

Individual Animal Teratology Fetal Weight Data

Individual Animal Teratology Implant Findings Data

### G.3.3 Three-Month and Chronic Study Tables – B6C3F1 Mice

I01 - Animal Removal Summary

I02 - Animal Removals

I03 - Growth Curve

I03C - Growth Curve

I04 - Mean Body Weight Summary

I04G - Mean Body Weight Gain

I05 - Clinical Observations Summary

PA02 - Incidence Rates of Neoplasms by Anatomic Site

PA03 - Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

PA04 - Neoplasms by Individual Animal

PA05 - Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

PA06 - Organ Weights Summary

PA07: Neoplasms By Individual Animal (Systemic Lesions Abridged)

PA08 - Statistical Analysis of Primary Tumors

PA09 - Non-Neoplastic Lesions by Individual Animal

PA10 - Statistical Analysis of Non-Neoplastic Lesions

PA11 - Statistical Analysis of Survival Data

PA14 - Individual Animal Pathology Data

PA18 - Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

PA40C - Survival Curve

PA46 - Summary of Gross Pathology

PA48 - Summary of Internal Concentration

### G.3.4 Three- Month and Chronic Individual Animal Data – B6C3F1 Mice

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Gross Pathology Data

Individual Animal Internal Concentration

Individual Animal Histopathology Data

Individual Animal Organ Weight Data

Individual Animal Removal Reasons Data