# Appendix F Peer Review Comments

## F.1 Peer Reviewers

External peer review of the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of α-Pinene (CASRN 80-56-8) Administered by Inhalation to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats, B6C3F1/N Mice, and CD-1 Mice was conducted by seven subject matter experts who individually provided comments via letter. Individuals outside the federal government were invited to serve as peer reviewers because of their expertise and then vetted, following established National Toxicology Program (NTP) practices, to ensure no conflicts of interest. For peer review of this draft NTP report, the peer reviewers had expertise in carcinogenicity, anatomical pathology, reproductive toxicology, genetic toxicology, monoterpenes, and occupational inhalation.

The peer reviewers were charged to peer review the draft NTP report and provide recommended revisions that would strengthen the scientific analyses or conclusions.

The report preparation team carefully considered the peer reviewers’ comments in revising the report. The peer reviewers’ anonymized comments, presented in random order, are provided verbatim in this appendix, other than for the correction of minor typographical or grammatical errors.

Reviewers

- Javed A. Bhalli, Ph.D., M.Phil
  Vice President and Site Head, Safety and Toxicology
  Frontage Laboratories, Inc.
  Chicago, Illinois, USA
- Daniel J. Conklin, Ph.D.
  Director, Exposure Studies Shared Resource, Omics & Exposure Facility Core
  Co-Director, Research Engagement and Training Coordination Core
  University of Louisville
  Louisville, Kentucky, USA
- Terry Gordon, Ph.D.
  Research Professor, Department of Medicine
  New York University School of Medicine
  New York City, New York, USA
- Wendy G. Halpern, D.V.M., Ph.D.
  Senior Fellow – Pathologist
  Genentech, Inc.
  San Francisco, California, USA
- Stephen S. Hecht, Ph.D.
  Professor, Department of Laboratory Medicine and Pathology
  Masonic Cancer Center, University of Minnesota
  Minneapolis, Minnesota, USA
- Lisa A. Miller, Ph.D.
  Professor, Department of Anatomy, Physiology, and Cell Biology
  University of California, Davis School of Veterinary Medicine
  Davis, California, USA
- Wanying Zhang, M.D.
  Laboratory Director, Clinical Consultant
  Variantyx, Inc.
  Fort Lauderdale, Florida, USA

## F.2 Peer Review Charge and Instructions

Charge:

Peer review the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of α-Pinene (CASRN 80-56-8) Administered by Inhalation to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats, B6C3F1/N Mice, and CD-1 Mice.

Instructions:

For the numbered charge questions, provide any recommended revisions necessary for strengthening the scientific analyses or conclusions of the draft NTP Technical Report. As available, please provide the page and line number(s), table number, and/or figure number to which the specific comment applies.

## F.3 Peer Review Comments

### F.3.1 Reviewer 1

1. Information presentation:

a. Please comment on whether the information presented in the draft NTP Technical Report, including presentation of data in any tables and figures, is technically correct, clearly stated, and objectively presented.
  - Reviewer Comments:
    - Two-year Study in Rats
      - Line 43, page 101 “Whole-genome sequencing of fresh frozen rat mammary tumors revealed an exposure concentration-dependent increase in mutation burden and an exposure-specific mutation signature (SBS21 COSMIC signature) that is enriched for T>C transitions (data not shown).” It is odd to include this statement in the Discussion as there is no mention of conducting this analysis in the Results section. There are data shown in the Appendix, but it is presented as a completely separate results section.
    - Two-year Study in Mice
      - Whole-genome sequencing appears to have been conducted in mice, but these data are limited to the Appendix section. As with the rat study, there is no mention of the sequencing analysis in the Results.
    - Reproductive Performance in Rats and Mice
      - The results of the study were limited to males, despite the observation that females appear more sensitive to chronic exposure.
    - Three-month Investigative Study in Rats
      - Why is this study listed separately from the other rat studies in the Materials and Methods?
      - The Results for this are confusing as it only describes deposition, weight, and survival.
      - Line 17, page xix: The abstract states “Early mortalities in the chronic study, attributed to mammary masses or nodules, prompted the addition of a follow-up 3-month investigative study in male and female Sprague Dawley rats to evaluate early biomarkers of carcinogenicity in mammary gland and collect definitive internal concentration data for α-pinene and α-pinene oxide in blood and mammary gland. Mammary gland was collected for future analysis, and sperm parameters were also evaluated.” This was not mentioned in the Results. What early markers were evaluated?
      - Line 21, page xxvii: “The early signs of mammary tumors in the chronic study prompted the addition of a follow-up investigative 3-month study in male and female Sprague Dawley rats to evaluate early biomarkers of carcinogenicity in the mammary gland using error-corrected duplex sequencing and to perform a definitive evaluation of internal concentrations of α-pinene and α-pinene oxide in the blood and mammary gland using validated methods.” I could not find these data from the 3-month investigative study.
b. Please suggest any improvements to the information presented and provide your rationale or scientific support for proposed improvements where applicable.
  - Reviewer Comments:
    - In general, the report was challenging to review given the different species, strains, exposure periods and assessments (e.g., reproductive versus investigative). Perhaps consider the organization and order in which the information is presented? For example, the Materials and Methods do not align with the Results section. The Materials and Methods starts with the two-year rat study, but the Results starts with the 3-month reproductive study, etc.
    - What was the rationale for using different mouse and rat strains? And how might this have affected the interpretation of the data?
    - This is minor, but for consistency it might help to start with male outcomes, followed by female outcomes for both rats and mice.
    - In some sections the 3-month reproduction study is combined with the 2-year study. Again, it makes it difficult to follow and correlate outcomes with conclusions (see lines 23-26 page xix).
    - It is very confusing to have the mutation data presented as a separate appendix and only superficially addressed in the main body of the report.
    - While this was a comprehensive study (acute vs chronic, two species), there are potential limitations to the exposure conditions that warrant mention in the discussion. Specifically, there appeared to be some variability in particle counts (Table A-1) and less than proportional blood concentration (Tables 27, 28), which could have influenced the severity of the outcomes (although not the overall interpretation).
c. Please identify any information that should be added or deleted and provide your rationale behind the additions or deletions.
  - Reviewer Comments:
    - I don't have any deletions to suggest beyond my comments on various sections.
    - For the Material and Methods, I would suggest including a sentence that clearly states that inhalation exposure was for the entire duration of the study period (at least that is how I'm interpreting the writing). In other words, for a 3-month study, animals are exposed to alpha pinene for 24 hours/day, 7 days/week for a total of 90 days. Presumably, the animal husbandry would require periodic access to the exposure chambers, which would require evacuation of the alpha pinene to reduce occupational exposures?
    - Line 28 page xxvii has a typo (Appendix E).

2. Study design, conduct, and findings:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments:
    - Is it possible that the different sources [for] rat and mouse strains could influence interpretation of the findings between exposure periods? Particularly since the 3-month investigative study in rats showed the highest blood concentration of alpha pinene?
    - Line 35, page 9: “Male and female Sprague Dawley rats were obtained from Envigo (formerly Harlan Laboratories, Inc.; Indianapolis, IN) for the 2-year and 3-month reproductive studies. Male and female Sprague Dawley rats were obtained from Envigo (Haslett, MI) for the 3-month investigative study.” This is confusing - did the company move or is there a typographical error? Vendor sources of animals can certainly influence study outcomes.
    - It is notable that the stability of the compound was tested through the duration of the studies to determine if degradation occurred (no evidence).
    - Line 23, page 8: ”Particle counts were collected from all chambers at regular intervals during all studies, and particle counts were frequently >200 particles/cm^3^ except for the 400 ppm chamber for Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats in the 3-month reproductive study. The source and identity of the particles were undetermined.” Could this be addressed in the discussion?
b. Please comment on whether the statistical analyses have been appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: The statistical analyses appears to be appropriately applied and scientifically justified.
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not justified and provide alternate interpretation of the data.
  - Reviewer Comments:
    - Is it possible that greater death in female rats is due to higher dose/body weight?
    - The concentration assessment measures alpha pinene and alpha pinene oxide in blood with no apparent differences between males and females. Are there differences in blood volume between males and females?
    - The reproductive assessments were exclusively done in males, but females (particularly for rats) appear to be more sensitive. This is a gap in knowledge and should be pointed out in the discussion.
    - Although the concentration of blood alpha pinene and alpha pinene oxide with exposure does seem to increase with dose, the lack of proportional concentration is concerning with regard to interpretation of findings as it may have been influenced by exposure methods. At a minimum this should be addressed in the discussion.
    - Line 9, page 99: “α-Pinene and α-pinene oxide concentrations in the 3-month investigative rat study were higher than those in the 2-year rat study, and the difference was not consistent across matrices and analytes. Up to 4-fold and 5- to 15-fold higher concentrations were observed in male and female blood, respectively, and 2- to 43-fold higher concentrations were observed in female mammary gland.” This should be of concern, as it may be due to variability in exposure conditions, which would influence outcomes. In this case, it might suggest that the observed effects in the 2-year study are mild relative to what would be expected.

3. Evaluation of mutation burden and unique mutation signatures:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient:
  - Reviewer Comments: There appeared to be variability in exposure concentrations. Particle counts (Table A-1) seemed widely different between studies, particularly mice versus rats.
b. Please comment on whether the bioinformatic analyses were appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: The bioinformatic analysis appears to be appropriately applied and scientifically justified.
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not scientifically justified and provide an alternate interpretation of the data.
  - Reviewer Comments:
    - I agree that the overall conclusions of alpha pinene toxicity and carcinogenicity for the 2-year study (both rats and mice) are justified by the evidence of blood concentration and histopathologic assessments.
    - Less than proportional blood deposition might suggest variability introduced by exposure conditions, however this observation does not discount the overall conclusions of toxicity and carcinogenicity.

4. Levels of Evidence of Carcinogenic Activity categories:

Additional information on the NTP Levels of Evidence of Carcinogenic Activity is available at https://ntp.niehs.nih.gov/sites/default/files/ntp/test_info/cartox_loe_508.pdf and in the draft Technical Report.

a. Indicate your agreement or disagreement with each draft NTP Level of Evidence conclusion, taking into consideration the strength of the toxicology and carcinogenicity results in Hsd:Sprague Dawley^®^ rats and B6C3F1/N mice exposed to α-pinene.
  - Male Hsd:Sprague Dawley^®^ SD^®^ rats:
    - Some evidence of carcinogenic activity
      - Higher incidence of urinary bladder papilloma
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Female Hsd:Sprague Dawley^®^ SD^®^ rats:
    - Clear evidence of carcinogenic activity
      - Increased incidences of mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined)
      - Increased incidences of stromal polyp; adenocarcinoma; squamous cell carcinoma; and squamous cell papilloma, squamous cell carcinoma, adenoma, or adenocarcinoma (combined) in the uterus were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Male B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidences of Harderian glad adenoma, adenocarcinoma, and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); and alveolar/bronchiolar adenoma and adenoma or carcinoma (combined)
      - Higher incidences of urinary bladder papilloma and forestomach papilloma were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Female B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidences of Harderian gland adenoma and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); alveolar/bronchiolar adenoma, carcinoma, and adenoma or carcinoma (combined); and mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined)
      - Increased incidences of granulosa cell tumor, benign, malignant (combined) and tubulostromal adenoma in the ovary and a higher incidence of squamous cell carcinoma in the forestomach were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:

5. Please provide any additional comments, suggestions, or recommendations for improving the report and provide rationale or scientific support for proposed improvements where applicable.

- Reviewer Comments: This study provides a comprehensive histopathologic assessment of the toxicity and carcinogenicity of alpha pinene using two in vivo models of exposure. It is possible that some of the observed findings regarding alpha pinene blood deposition may be attributed to variability in exposure conditions, but ancillary data from prior peer-reviewed studies suggest that the metabolites of alpha pinene could also play a role in toxicity when less than proportional deposition concentrations of the inhalant were observed. Regardless of the gaps in understanding the mechanisms of alpha pinene metabolism, the outcome of the study in both rats and mice provides scientific evidence of toxicity and carcinogenicity following two years of chronic exposure.

### F.3.2 Reviewer 2

1. Information presentation:

a. Please comment on whether the information presented in the draft NTP Technical Report, including presentation of data in any tables and figures, is technically correct, clearly stated, and objectively presented.
  - Reviewer Comments: The information provided in this report, including tables and figures, is clear and objectively presented. However, summary can be improved to make it clear to the readers without going into the main sections of the report. For example,
  - Summary
    - Two-year Study in Rats
      - Summary states that animals were exposed to α-pinene for two years, but it is not clear if this was whole body or nose only exposure. This is also not clear if exposure was continuous during this duration or was for certain days per week etc.
      - It is stated that survival of male rats was comparable to that of control rats, whereas female survival was significantly decreased compared to control rats. However, it is not clear survival of male rats was decreased in any particular dose group or this statement talks about the cumulative decrease.
      - Same is for body weight, should be clarified which dose groups are significantly lower or if this statement is for cumulative decrease.
    - Two-year Study in Mice:
      - This title is confusing. There are two studies in this section.
        - 3 months exposure in CD-1 males and B6C3F1/N males and females for reproductive assessment.
        - 2 years toxicity and carcinogenicity study in B6C3F1/N male and female mice.
      - However, the title is “Two-year Study in Mice.” It is suggested either to clearly state the title or make Subsets A and B for the two types of studies. Also, the summary of the two study types is mixed. It is suggested to summarize the results of the 3-month study in the first paragraph and then start a separate paragraph to summarize the results of the carcinogenicity study.
      - Paragraph 2, line 3: It states that α-pinene exposure did not significantly affect survival. However, it is not stated which sex.
      - Paragraph 2, last sentence: It is stated that clinical observations were sporadic and not attributed to α-pinene exposure, but this does not state which sex, male, females, or both.
      - Paragraph 4, first sentence: Urinary bladder papilloma was observed in the 400 ppm male mice, but it is not stated which male mice, CD1 or B6C3F1/N.
b. Please suggest any improvements to the information presented and provide your rationale or scientific support for proposed improvements where applicable.
  - Reviewer Comments: The studies presented in the report are well designed and well conducted. Data supports the conclusion.
c. Please identify any information that should be added or deleted and provide your rationale behind the additions or deletions.
  - Reviewer Comments: None.

2. Study design, conduct, and findings:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments: In the Genetic Toxicity section of Overview, studies conducted reported in literature are stated. However, it does not look like an Ames study is conducted in the past where all five strains (TA98, TA100, TA1535, TA1537, and WP2uvrA) were used where α-pinene and α-pinene oxide were tested up to the dose levels recommended by the OECD and ICH guidelines, 5000 µg/plate to determine if parent compound or one of its metabolite can cause mutation induction.
  - Because now data from 2-year carcinogenicities are available to support the carcinogenic potential of these compounds, not having data for the Ames assay up to most relevant doses or in all recommended strains is not critical.
b. Please comment on whether the statistical analyses have been appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: Statistical analysis conducted is appropriate.
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not justified and provide alternate interpretation of the data.
  - Reviewer Comments: Yes.

3. Evaluation of mutation burden and unique mutation signatures:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments: Mutational spectrum as conducted using tissues from treated animals. Tissues were shipped to Sanger Institute where these were analyzed with a read depth of 45X. However, a new approach of error corrected next generation sequencing (ecNGS) also called duplex sequencing is available with multiple versions. This could have been more relevant with very low percentage of error which could have provided better results. It is recommended that this technique should be considered in future for similar studies.
b. Please comment on whether the bioinformatic analyses were appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: Bioinformatic analyses used in this report is appropriate for the mutation method used here.
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not scientifically justified and provide an alternate interpretation of the data.
  - Reviewer Comments: Yes.

4. Levels of Evidence of Carcinogenic Activity categories:

Additional information on the NTP Levels of Evidence of Carcinogenic Activity is available at https://ntp.niehs.nih.gov/sites/default/files/ntp/test_info/cartox_loe_508.pdf and in the draft Technical Report.

a. Indicate your agreement or disagreement with each draft NTP Level of Evidence conclusion, taking into consideration the strength of the toxicology and carcinogenicity results in Hsd:Sprague Dawley^®^ rats and B6C3F1/N mice exposed to α-pinene.
  - Male Hsd:Sprague Dawley^®^ SD^®^ rats:
    - Some evidence of carcinogenic activity
      - Higher incidence of urinary bladder papilloma
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Female Hsd:Sprague Dawley^®^ SD^®^ rats:
    - Clear evidence of carcinogenic activity
      - Increased incidences of mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined)
      - Increased incidences of stromal polyp; adenocarcinoma; squamous cell carcinoma; and squamous cell papilloma, squamous cell carcinoma, adenoma, or adenocarcinoma (combined) in the uterus were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Male B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidences of Harderian glad adenoma, adenocarcinoma, and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); and alveolar/bronchiolar adenoma and adenoma or carcinoma (combined)
      - Higher incidences of urinary bladder papilloma and forestomach papilloma were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Female B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidences of Harderian gland adenoma and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); alveolar/bronchiolar adenoma, carcinoma, and adenoma or carcinoma (combined); and mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined)
      - Increased incidences of granulosa cell tumor, benign, malignant (combined) and tubulostromal adenoma in the ovary and a higher incidence of squamous cell carcinoma in the forestomach were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:

5. Please provide any additional comments, suggestions, or recommendations for improving the report and provide rationale or scientific support for proposed improvements where applicable.

- Reviewer Comments: Studies presented in this report were appropriately conducted, data was interpreted with scientific vigor, and the report is written and presented well. Report can be accepted in its original form with some more clarity in the summary section.

### F.3.3 Reviewer 3

1. Information presentation:

a. Please comment on whether the information presented in the draft NTP Technical Report, including presentation of data in any tables and figures, is technically correct, clearly stated, and objectively presented.
  - Reviewer Comments: The information follows a well structured and long used pattern of presentation that is technically great, clear, and objective. Minor issues are noted in the last question below.
b. Please suggest any improvements to the information presented and provide your rationale or scientific support for proposed improvements where applicable.
  - Reviewer Comments: Given the decades of successful formatting and the proven rationale and science that is supported by the data presentation in these NTP reports, this question no longer needs to be asked and could be removed/eliminated.
c. Please identify any information that should be added or deleted and provide your rationale behind the additions or deletions.
  - Reviewer Comments: No suggestions for additions or deletion other than the inclusion of the histopathology in the report. Yes, they are important and catch my inquisitive eye as a toxicologist, but they could be eliminated or relegated to an appendix as while they do serve the purpose of backing up the data upon which the determinations are made, they don’t add much to the report.

2. Study design, conduct, and findings:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments: The study design is excellent (as all NTP chronic studies generally are). The choice of the inhalation route, the exposure concentrations, and the subchronic [underlined: add-on] studies to examine the potential adverse effects was logical and well warranted. Similarly, the mechanistic studies (e.g., mutations) were appropriately designed for inclusion. Only one minor comment – The generation reservoir and a nitrogen exhaust vent/rotameter are unclear in Figure A-5.
b. Please comment on whether the statistical analyses have been appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: The statistical analyses were appropriately applied and justified. The ‘newer’ trend analyses are quite valuable. As I believe I’ve noted on previous reviews, the inclusion of the trend’s statistical results under the control column still appears odd or confusing to me until I carefully read the footnotes. Perhaps there is a simpler or clearer way to present the trend results (or I’m just from an older generation that likes clearly understandable tables).
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not justified and provide alternate interpretation of the data.
  - Reviewer Comments: The data interpretations are clearly presented and justified. One small suggestion would be to consistently present the most significant/important findings first. For example, in the Abstract, page xxii, lines 2-4, the ‘some evidence’ finding is presented first followed by the ‘clear evidence.’

3. Evaluation of mutation burden and unique mutation signatures:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments: The mutation burden and signature data were well documented and I agree that it was logical to assess the endpoints in three major tumor types for comparison. Mutational spectrum research is not my field of expertise, but I do know that it is quite complicated. Thus, to this reviewer, it is not clear if the approach would be improved by the more precise (and costly) gene by gene analysis.
  - In Figure E-10, SBS and such are not defined.
b. Please comment on whether the bioinformatic analyses were appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: To the best knowledge of this reviewer (which is limited), these analyses were appropriate.
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not scientifically justified and provide an alternate interpretation of the data.
  - Reviewer Comments: The interpretations of the data are objectively and well presented in the report. The writing leads to clear justifications for the proposed levels of evidence of carcinogenic activity for alpha-pinene. This was particularly true for the well written Discussion section that clearly linked the findings to the exposures.

4. Levels of Evidence of Carcinogenic Activity categories:

Additional information on the NTP Levels of Evidence of Carcinogenic Activity is available at https://ntp.niehs.nih.gov/sites/default/files/ntp/test_info/cartox_loe_508.pdf and in the draft Technical Report.

a. Indicate your agreement or disagreement with each draft NTP Level of Evidence conclusion, taking into consideration the strength of the toxicology and carcinogenicity results in Hsd:Sprague Dawley^®^ rats and B6C3F1/N mice exposed to α-pinene.
  - Male Hsd:Sprague Dawley^®^ SD^®^ rats:
    - Some evidence of carcinogenic activity
      - Higher incidence of urinary bladder papilloma
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Female Hsd:Sprague Dawley^®^ SD^®^ rats:
    - Clear evidence of carcinogenic activity
      - Increased incidences of mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined)
      - Increased incidences of stromal polyp; adenocarcinoma; squamous cell carcinoma; and squamous cell papilloma, squamous cell carcinoma, adenoma, or adenocarcinoma (combined) in the uterus were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Male B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidences of Harderian glad adenoma, adenocarcinoma, and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); and alveolar/bronchiolar adenoma and adenoma or carcinoma (combined)
      - Higher incidences of urinary bladder papilloma and forestomach papilloma were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Female B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidences of Harderian gland adenoma and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); alveolar/bronchiolar adenoma, carcinoma, and adenoma or carcinoma (combined); and mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined)
      - Increased incidences of granulosa cell tumor, benign, malignant (combined) and tubulostromal adenoma in the ovary and a higher incidence of squamous cell carcinoma in the forestomach were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:

5. Please provide any additional comments, suggestions, or recommendations for improving the report and provide rationale or scientific support for proposed improvements where applicable.

- Reviewer Comments:
  - Abstract – page xx, line 15 – it’s not clear what this % decrease refers to as it’s male mice and one concentration.
  - Abstract – page xx, lines 26-31 – here and elsewhere, why are there redundant sentences where the first sentence states the general finding and the second sentence is nearly identical but just adds the data (e.g., “There were exposure-related significant increases in the incidences of hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined) in male and female mice. The incidences of hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined) were significantly increased at concentrations of ≥200, 400, and ≥100 ppm α-pinene, respectively, in male mice, and ≥100, 400, and ≥100 ppm, respectively, in female mice.”)
  - Abstract – page xxi, line 15-16 – I suggest that this be a new paragraph as it’s unrelated to the preceding.
  - Abstract – page xxii, line 27 – should ‘these’ be ‘the’?
  - Abstract – page xxv – Unclear why ‘Equivocal Findings’ is noted here. [Does]n’t ‘equivocal’ come after ‘Some evidence’? It just seems odd to see it pop up here as a subcategory when Some and Clear are presented in the next line of Level of Evidence.
  - Abstract – page xxviii – Shouldn’t ‘NTP’ be ‘alpha-pinene’?
  - Page 2, lines 17-31 – To show clearer real-world relevance, perhaps add some comparative calculations for an oral dose/day vs. an inhaled dose/day for occupational and environmental/indoor exposures?
  - Page 5, line 39 – Is it correct to state “No in vivo studies…’ if Reference 81 is a mouse micronucleus study?
  - Page 24, lines 9-12 – First, to the non-initiated, ‘censored’ and ‘uncensored’ are unclear terms (i.e., this inhalation toxicologist with over 40 years of experience had to read this 3 or 4 times to figure out what ‘censored’ meant (i.e., as in it means counted or eliminated as in ‘this thesis was censored’). Second, for the less knowledgeable, like myself, it would help if ‘natural’ and ‘unnatural’ causes are defined. Bottom line, this ‘survival analyses’ terminology can be confusing.
  - Page 87, line 12 – ‘the presence of artifacts’ needs further explanation for the decision to reject data output. Was it technical error or the machine broke or there was contamination or the samples were not stored properly or analyzed in time?
  - Page 90, line 13 – confusing as the sentence first states that the decrease in lutea occurred in all groups compared to controls, then talks about natural variability. Is it implying the decreases were within historical variability? Were there statistics compared to control?
  - Page 90, line 15 – the subheading title could be improved – “Investigative” is very broad.
  - Page 90, lines 16-19 – Unclear – this starts with biomarkers being investigated for mammary gland carcinogenesis and then male rat moribund data are reported next. Then, male repro data are presented on page 94. Thus, the given reasoning for the 3-month investigative study doesn’t match the endpoints or the inclusion of male rats.
  - Page 90, lines 18-19 – Unclear why this is mentioned under this subheading when the next subheading is all about the internal concentrations.
  - The Discussion section is particularly clear and links everything nicely.

### F.3.4 Reviewer 4

1. Information presentation:

a. Please comment on whether the information presented in the draft NTP Technical Report, including presentation of data in any tables and figures, is technically correct, clearly stated, and objectively presented.
  - Reviewer Comments: In general, the data appear internally consistent across narrative descriptions, figures, and tables. Analytical and histopathological findings are clearly linked to exposure concentrations. Tables and figures are generally well-constructed with informative titles, footnotes, and unites of measurement. Statistical trends and significance are clearly annotated. The narrative maintains scientific neutrality. Interpretations of findings are well-supported by data without overreaching conclusion. Minor changes will clarify some of the confusions including:
    - In some of the tables, for example Table 5 (page 67, line 5), the legends of “Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked” should have a clarification of how was this graded. If it is a grade system for hyperplasia or adenoma, it can be based on proliferative indices like Ki-67, size of the lesions, or purely morphological evaluation.
    - Figure 4 on the page of 68 shows an area where only tumor tissue presents. It will be beneficial to include some uninvolved mammary gland tissue from control group. This can help identify species-related, strain-related, age-related changes, and other normal variability that occur naturally or spontaneously vs. those potentially induced by the chemical.
    - Figure 9 on the page of 79, legend B is not accurately stated. The ratio of hematopoietic cells and marrow fat is age related in healthy individuals. The right comparison of the ratio should be in between control group animals and experimental group animals of the same age.
b. Please suggest any improvements to the information presented and provide your rationale or scientific support for proposed improvements where applicable.
  - Reviewer Comments: The information is clearly presented, technically accurate, and appropriately supported by the data. However, there is information suggested to be added. Please review the next section.
c. Please identify any information that should be added or deleted and provide your rationale behind the additions or deletions.
  - Reviewer Comments: Two areas need to be taken into consideration or if additional data is available to clarify:
    - Given the reported tumors in the uterus and mammary glands of female animals, the report would benefit from a discussion on the potential hormonal relevance of these findings. Specifically, the authors should clarify whether endocrine mechanisms were considered and if hormone measurements (e.g., estrogen, prolactin) were taken or could be analyzed from archived samples. This would help explain sex-specific findings, particularly the broader systemic impact observed in male animals at high doses. For example, on page 22, line 36, female rats showed higher concentrations of both α-pinene and α-pinene oxide, suggesting possible sex-specific pharmacokinetics. This may be due to differences in metabolism, body fat distribution (supporting mammary gland as a primary target), or hormone-regulated enzyme activity. Supporting evidence includes the presence of stromal polyps, which are often hormone responsive. It is suggested to discuss whether specific enzyme systems (e.g., cytochrome P450s) may be involved in the bioactivation of α-pinene and whether any known sex-specific activity in these pathways could explain the observed differences.
    - On page 76, line 7 where bone marrow changes were described, to enhance the interpretation of the observed bone marrow changes, the report should compare histological findings with peripheral blood parameters (e.g., reticulocyte counts, red and white blood cell indices). This would help clarify whether the changes primarily affect a single lineage or are multilineage, and whether the response appears reactive, regenerative, or stress induced.

2. Study design, conduct, and findings:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments: The selected exposure concentrations (50 and 100 ppm) for toxicokinetic studies in rodents are relevant for investigating potential mechanistic pathways and internal dose relationships. However, these concentrations may exceed typical human occupational exposures—particularly in non-industrial environments. For context, the maximum reported workplace exposure to α-pinene is approximately 27 ppm, which is considerably lower than the high-dose test condition of 100 ppm. While the highest dose (400 ppm) is appropriate for hazard identification purposes, the report should acknowledge its limited relevance to human exposure scenarios, especially in consumer or indoor settings where α-pinene levels are typically in the sub-ppm range. To strengthen the rationale for dose selection, the report should:
    - State whether selected doses approach or exceed the maximum tolerated dose (MTD).
    - Clarify if these were based on prior studies indicating target organ toxicity.
    - Explain how these doses support hazard identification or margin-of-exposure assessments for humans.
    - Justify the use of 100 ppm as the lowest dose in the chronic study—was this based on ambient human exposures or extrapolated from the 3-month study where 25 ppm was used as the lowest dose?
    - The report identifies changes in the Harderian gland and forestomach. These organs have limited relevance to human health:
      - Harderian gland is rudimentary or absent in humans. This limitation should be acknowledged, although it does not invalidate the importance of mechanistic insights.
      - Page 115, line 9: Clarify whether similar changes occurred in the glandular stomach, or if findings were strictly localized to the forestomach which has mucosal squamous epithelium. This is important because forestomach is a rodent specific structure. Human stomach tissue is mainly glandular.
b. Please comment on whether the statistical analyses have been appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: The statistical analyses appear to be appropriately applied and scientifically justified. A threshold of p ≤ 0.05 was used to determine statistical significance across analyses. Importantly, the determination of biological relevance or potential carcinogenicity of α-pinene was not based solely on statistical significance. Instead, the findings were evaluated using a comprehensive weight-of-evidence approach as described in the Explanation of Levels of Evidence of Carcinogenic Activity section. This multifactorial assessment appropriately considers dose-response relationships, biological plausibility, consistency across studies, and concordance with related endpoints (e.g., histopathological changes, organ weights, and mechanistic data), providing a scientifically balanced interpretation of the results.
  - One area to be taken into consideration is Table 15 on page 97 includes the notations “multiple” or “including multiple.” While formal statistical analyses were not conducted on multiplicity data, the inclusion of a brief discussion on quantitative tumor burden (e.g., total mass or volume of neoplasms per dose group) would improve interpretability. This addition would help contextualize the biological significance of findings, especially in cases where multiple tumor types or co-occurring lesions were observed.
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not justified and provide alternate interpretation of the data.
  - Reviewer Comments: Overall, the interpretations presented in the draft report appear to be scientifically justified, objective, and grounded in the data. The narrative accurately reflects the findings and maintains a balanced tone when drawing conclusions, particularly in areas where statistical significance was not achieved but biological plausibility or relevance warranted discussion. However, several points would benefit from clarification to further strengthen the objectivity and rigor of the interpretations:
    - Page 96, line 28. A more detailed discussion of quantitative tumor burden (e.g., total mass or volume of neoplasms) would enhance the interpretation of biological significance, particularly in cases where tumor multiplicity or co-occurrence is noted but not statistically analyzed.
    - Page 101, line 26. Please clarify whether squamous differentiation within carcinomas was observed incidentally or occurred more frequently in high-dose animals. This may indicate divergent differentiation pathways and could have implications for understanding tumor heterogeneity and chemical-specific effects.
    - Page 110, figure 25. Clarify whether the hyperplastic and papillomatous regions occurred in the same animals or within the same anatomical locations. Figure 25 appears to show a papilloma adjacent to hyperplasia, which may suggest progression or spatial correlation worthy of further discussion.
    - Page 74, line 9. Although not statistically significant, the observed incidence of papilloma should still be noted, especially given their rarity. It would be valuable to include data on whether inflammatory or degenerative changes were observed in the bladder epithelium or submucosa across dose groups, as this may support a local irritative mechanism.
    - Page 97, line 9. Further characterization of the severity and histological grading of basophilic foci and necrosis is recommended. This would help differentiate between spontaneous background lesions and those potentially induced by α-pinene exposure.

3. Evaluation of mutation burden and unique mutation signatures:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments: The study utilized whole-genome sequencing (WGS) to characterize mutational profiles across three tumor types—mouse hepatocellular carcinomas (mHCCs), mouse alveolar/bronchiolar carcinomas (mABCs), and rat mammary tumors (rMTs)—using fresh frozen samples obtained from animals exposed to α-pinene over a 2-year period. The general design, which includes both tumor and age-matched normal tissues for comparison, is scientifically appropriate and well aligned with current genomic profiling standards. The use of recognized bioinformatics tools (e.g., GATK, Mutect2, SigProfiler) and COSMIC mutational signature databases, especially given the solid tumor types, reflects current best practices. However, several elements merit further clarification or enhancement to improve transparency and interpretability. Please review the next sections.
b. Please comment on whether the bioinformatic analyses were appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: The bioinformatic analyses appear to be generally appropriate and aligned with standard practices for tumor genomic profiling. However, critical quality control (QC) metrics were not clearly reported, which limits the ability to fully assess the reliability and interpretability of the findings.
  - Inclusion of key QC metric is recommended.
    - DNA input amount: To assess whether sufficient material was used for reliable sequencing.
    - Tumor cellularity: Low tumor purity can obscure true variants and introduce false negatives. This should be estimated (e.g., via histopathology, computational tools) and discussed.
    - Analytical sensitivity and limit of detection (LOD): Particularly relevant for low-frequency variants or samples with low cellularity. These should be clearly stated to contextualize mutation burden results.
  - Reporting QC metrics and assay sensitivity is standard practice in genomic studies (e.g., The Cancer Genome Atlas, clinical sequencing guidelines). These metrics are necessary to ensure reproducibility and transparency, determine the adequacy of variant calling thresholds (e.g., VAF cutoffs), as well as justify the inclusion or exclusion of samples with borderline quality. In the absence of tumor purity estimates and LOD, conclusions regarding differences in mutation burden (e.g., lower burden in certain subgroups) should be interpreted with caution, as they may reflect technical artifacts rather than biological signal.
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not scientifically justified and provide an alternate interpretation of the data.
  - Reviewer Comments: Tumor cellularity (also referred to as tumor burden or purity) is a critical factor in genomic analysis, particularly when using whole genome sequencing (WGS). Reliable detection of somatic variants generally requires a minimum tumor content of approximately 30%. If cellularity is low, it may result in: false negatives due to insufficient variant allele frequency (VAF) to surpass the detection threshold; increased background noise, potentially skewing mutational signature analysis; underestimation of mutational burden, especially in morphologically low-grade or mixed tumors. The lack of a clear mutational burden signal in mABCs may indeed reflect biological phenomena; however, it could also result from technical limitations imposed by low tumor cellularity. This concern is particularly relevant because ABCs often exhibit diffuse growth patterns and low tumor cell density, which are known challenges in genomic profiling of low-grade lung cancers.
  - To support the interpretations and strengthen the scientific conclusions, the following clarifications and additions are recommended:
    - Indicate whether tumor cellularity was assessed, either through histopathologic evaluation or morphologically assessment by a pathologist. If not performed, this should be explicitly stated as a limitation of the analysis.
    - Provide key analytical parameters, such as:
      - Minimum and median tumor cellularity across all sequenced samples;
      - Minimum sequencing depth and VAF thresholds used in variant calling;
      - Criteria used to determine sample quality or inclusion.
    - Clarify the intersection between sequencing sensitivity and tumor purity, including whether a minimum sensitivity threshold was applied to ensure reliability in mutation detection.
    - Discuss tumor cellularity as a potential confounder in mutational burden analysis—particularly in mABCs—given the known architectural and cytological features that may influence the interpretation.
    - Consider including power calculations or sensitivity analyses to demonstrate that the absence of detectable mutations in certain tumor types is unlikely to be due to methodological limitation.

4. Levels of Evidence of Carcinogenic Activity categories:

Additional information on the NTP Levels of Evidence of Carcinogenic Activity is available at https://ntp.niehs.nih.gov/sites/default/files/ntp/test_info/cartox_loe_508.pdf and in the draft Technical Report.

a. Indicate your agreement or disagreement with each draft NTP Level of Evidence conclusion, taking into consideration the strength of the toxicology and carcinogenicity results in Hsd:Sprague Dawley^®^ rats and B6C3F1/N mice exposed to α-pinene.
  - Male Hsd:Sprague Dawley^®^ SD^®^ rats:
    - Some evidence of carcinogenic activity
      - Higher incidence of urinary bladder papilloma
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Female Hsd:Sprague Dawley^®^ SD^®^ rats:
    - Clear evidence of carcinogenic activity
      - Increased incidences of mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined)
      - Increased incidences of stromal polyp; adenocarcinoma; squamous cell carcinoma; and squamous cell papilloma, squamous cell carcinoma, adenoma, or adenocarcinoma (combined) in the uterus were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Male B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidences of Harderian glad adenoma, adenocarcinoma, and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); and alveolar/bronchiolar adenoma and adenoma or carcinoma (combined)
      - Higher incidences of urinary bladder papilloma and forestomach papilloma were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Female B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidences of Harderian gland adenoma and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); alveolar/bronchiolar adenoma, carcinoma, and adenoma or carcinoma (combined); and mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined)
      - Increased incidences of granulosa cell tumor, benign, malignant (combined) and tubulostromal adenoma in the ovary and a higher incidence of squamous cell carcinoma in the forestomach were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:

5. Please provide any additional comments, suggestions, or recommendations for improving the report and provide rationale or scientific support for proposed improvements where applicable.

- Reviewer Comments: The draft report presents a scientifically robust and comprehensive toxicologic evaluation of α-pinene. However, several areas require clarification or expanded discussion to enhance transparency, contextual relevance, and the scientific defensibility of genomic and histopathological conclusions. Addressing tumor purity, dose relevance, and species-specific anatomical differences will strengthen the reliability and translational value of the findings.

### F.3.5 Reviewer 5

1. Information presentation:

a. Please comment on whether the information presented in the draft NTP Technical Report, including presentation of data in any tables and figures, is technically correct, clearly stated, and objectively presented.
  - Reviewer Comments: Presentation of data in tables and figures is technically correct, clearly stated, and objectively presented.
b. Please suggest any improvements to the information presented and provide your rationale or scientific support for proposed improvements where applicable.
  - Reviewer Comments: In image presentations, there could be two improvements: 1) images could include scale bars especially as magnifications are changed; and, 2) it could be more appropriate to include representative images from all treatment groups (e.g., male and female with air and alpha-pinene; or, 0, 50, 100, 200 alpha-pinene) arranged in a 4-cluster frame. Both changes will improve the utility and clarity of information contained in these images, which are excellent in terms of staining and clarity.
c. Please identify any information that should be added or deleted and provide your rationale behind the additions or deletions.
  - Reviewer Comments: It would have been highly useful to have images of nasal/nasopharynx histopathology. As rodents are obligate nose breathers, the nasal epithelium gets dosed with each breath. Others have shown that exposures short-term to aldehydes or chronically to cigarette/e-cigarette aerosols stimulate nasal epithelium remodeling/hyperplasia. Similarly, there were no special stains performed to identify select changes such as fibrosis or immune cell infiltration. Perhaps, these additional outcomes may have been deemed secondary or resource intensive.

2. Study design, conduct, and findings:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments: Experimental design and methods were excellent, well detailed, and well rationalized. These were challenging exposure studies to carry out and they were well executed and well documented.
b. Please comment on whether the statistical analyses have been appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: The statistical analyses were appropriately applied and scientifically justified especially the use of the Poly 3 k-test. The table legends are incredibly helpful in explanation of specific statistical findings.
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not justified and provide alternate interpretation of the data.
  - Reviewer Comments: Based on the statistical testing outcomes, the interpretations of the data are objectively presented and scientifically justified. There was a sense of conservative interpretation, but it is hard to objectively criticize any of the interpretations.
  - However, the data in Table 27 on the presence of alpha-pinene in female rat mammary glands but not in blood were concerning because of:
    - Measurable values in control (unexposed) rats; and,
    - Loss of level dependence at 200 ppm.

- Notably, there were also alpha-pinene levels measured in female mammary gland but not in blood in control (unexposed) mice (Table 28). Explanation of these findings is warranted.

3. Evaluation of mutation burden and unique mutation signatures:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments: The experimental design and methods used for execution of these studies appears adequate although this is an area out of my expertise.
b. Please comment on whether the bioinformatic analyses were appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: The presence of “data not shown” in the Discussion in reference to the SBS21 COSMIC was abrupt. These data could be included in the Results section and more fully elaborated there. However, these studies appear adequate although this is an area out of my expertise.
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not scientifically justified and provide an alternate interpretation of the data.
  - Reviewer Comments: These data in Appendix E could be included in the Results section and more fully elaborated there. However, these studies appear adequate although this is an area out of my expertise.

4. Levels of Evidence of Carcinogenic Activity categories:

Additional information on the NTP Levels of Evidence of Carcinogenic Activity is available at https://ntp.niehs.nih.gov/sites/default/files/ntp/test_info/cartox_loe_508.pdf and in the draft Technical Report.

a. Indicate your agreement or disagreement with each draft NTP Level of Evidence conclusion, taking into consideration the strength of the toxicology and carcinogenicity results in Hsd:Sprague Dawley^®^ rats and B6C3F1/N mice exposed to α-pinene.
  - Male Hsd:Sprague Dawley^®^ SD^®^ rats:
    - Some evidence of carcinogenic activity
      - Higher incidence of urinary bladder papilloma
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Female Hsd:Sprague Dawley^®^ SD^®^ rats:
    - Clear evidence of carcinogenic activity
      - Increased incidences of mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined)
      - Increased incidences of stromal polyp; adenocarcinoma; squamous cell carcinoma; and squamous cell papilloma, squamous cell carcinoma, adenoma, or adenocarcinoma (combined) in the uterus were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Male B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidences of Harderian glad adenoma, adenocarcinoma, and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); and alveolar/bronchiolar adenoma and adenoma or carcinoma (combined)
      - Higher incidences of urinary bladder papilloma and forestomach papilloma were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Female B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidences of Harderian gland adenoma and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); alveolar/bronchiolar adenoma, carcinoma, and adenoma or carcinoma (combined); and mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined)
      - Increased incidences of granulosa cell tumor, benign, malignant (combined) and tubulostromal adenoma in the ovary and a higher incidence of squamous cell carcinoma in the forestomach were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:

5. Please provide any additional comments, suggestions, or recommendations for improving the report and provide rationale or scientific support for proposed improvements where applicable.

- Reviewer Comments: Editorial:
  1. Please use “compare with” or “compared with” rather than “compared to” throughout the narrative. “With” is better for comparing like things whereas “to” is for metaphorical comparison (e.g., poems).
  2. Pg xxi, l. 6: The first use of “suppurative” could include in parentheses “(pus forming)” to define this term.
  3. Pg 64 (92), l. 7-9: Is it “focus” or “foci”?
  4. Pg 78 (106), l. 9-11: Statement is contradictory: “…higher in the 400 ppm group…not statistically significant.” This is repeated in other places as well, but is a number higher than another number if it is not statistically different?
  5. Pg 90 (118), l. 11: Please change “Since” to “Because” as there is no temporal reference here.
  6. Discussion would benefit from the use of sub-headers to organize topics, e.g., Urinary Bladder:.
  7. A section on [underlined: Limitations] could be included in the Discussion, e.g., Nasopharynx/Nasal Epithelium was not evaluated.
  8. The presence of “data not shown” in the Discussion in reference to the SBS21 COSMIC was abrupt. These data could be included in the Results section and more fully elaborated there.
  9. The “Conclusions” section reads more like a “Summary” than being inferential. For example, there were no inferences provided that linked mutational data with mechanisms of carcinogenesis, which may be expected. For example, some of the inferences present in Appendix E could be included. It appears that Appendix E is perhaps being “held back” for inclusion in a separate publication.
  10. Document could include “Future Directions/Follow-up/Regulatory Implications” section(s).
  11. It was slightly surprising that urinary metabolites of alpha-pinene were not measured as more stable biomarkers of exposure (see https://pubmed.ncbi.nlm.nih.gov/37889254/). Given the non-invasive collection of urine, it may be more useful for tracking occupational exposures to alpha-pinene.

### F.3.6 Reviewer 6

1. Information presentation:

a. Please comment on whether the information presented in the draft NTP Technical Report, including presentation of data in any tables and figures, is technically correct, clearly stated, and objectively presented.
  - Reviewer Comments: Overall, the information is technically correct, clearly stated, and objectively presented. I have some relatively minor comments for consideration, as noted below.
b. Please suggest any improvements to the information presented and provide your rationale or scientific support for proposed improvements where applicable.
  - Reviewer Comments:
    1. Abstract, line 5. What is the meaning of exposure to 99 ppm “total terpenes” as presumably some of these are compounds other than α-pinene. Suggest deleting this phrase.
    2. Page xxi, lines 38-40. Abstract should include the method used to quantify blood α-pinene levels.
    3. Page xxvii, lines 30-32. It is not clear why this result is “surprising” and why it would implicate α-pinene oxide specifically in the liver rather than the lung. Suggest revising this sentence.
    4. Page 3, lines 39-40. Structures of cis and trans verbenol and myrtenol should be shown.
    5. Page 6, lines 21-25. Since α-pinene oxide is a metabolite of α-pinene, data on its genotoxicity should be summarized.
    6. Page 7, line 21. Not clear what is meant by “bicyclo[3.1.0]hexane…didehydro deriv (MMEDD).”
    7. Page 94 forward. Studies of α-pinene oxide in blood are reported, but there is limited or no information regarding stability of this metabolite or possible further transformations that would indicate its presence, such as dihydrodiols or glutathione or cysteine conjugates.
    8. Table 27. Why do the α-pinene oxide concentrations in blood and tissues decrease at the highest dose (200 ppm) in female rats?
    9. It would be helpful to see a representative chromatogram on which the quantitation of α-pinene oxide is based.
    10. Page 99, lines 15-17. What is meant by “inadequate sample collection and storage procedures during the 2-year study? In a GLP study?
    11. Page 100, line 26. Remove the word modestly.
    12. Page 101, lines 23-25. Does this statement take cigarette smoking into account?
c. Please identify any information that should be added or deleted and provide your rationale behind the additions or deletions.
  - Reviewer Comments: More information on α-pinene oxide as noted above would be helpful in understanding its potential role in the carcinogenicity of α-pinene.

2. Study design, conduct, and findings:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments: The study design and methods are comprehensive and outstanding.
b. Please comment on whether the statistical analyses have been appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: The methods appear to be standard and acceptable, although this is outside of my field of expertise.
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not justified and provide alternate interpretation of the data.
  - Reviewer Comments: The interpretation of the bioassay data are objectively presented and scientifically justified. Some of the α-pinene oxide metabolism data require more detail for clarity, as noted above.

3. Evaluation of mutation burden and unique mutation signatures:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments: The design and methods appear to be acceptable for execution of the mutation studies.
b. Please comment on whether the bioinformatic analyses were appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: This is outside of my field of expertise.
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not scientifically justified and provide an alternate interpretation of the data.
  - Reviewer Comments: The scientific interpretations of the data appear to be acceptable.

4. Levels of Evidence of Carcinogenic Activity categories:

Additional information on the NTP Levels of Evidence of Carcinogenic Activity is available at https://ntp.niehs.nih.gov/sites/default/files/ntp/test_info/cartox_loe_508.pdf and in the draft Technical Report.

a. Indicate your agreement or disagreement with each draft NTP Level of Evidence conclusion, taking into consideration the strength of the toxicology and carcinogenicity results in Hsd:Sprague Dawley^®^ rats and B6C3F1/N mice exposed to α-pinene.
  - Male Hsd:Sprague Dawley^®^ SD^®^ rats:
    - Some evidence of carcinogenic activity
      - Higher incidence of urinary bladder papilloma
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Female Hsd:Sprague Dawley^®^ SD^®^ rats:
    - Clear evidence of carcinogenic activity
      - Increased incidences of mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined)
      - Increased incidences of stromal polyp; adenocarcinoma; squamous cell carcinoma; and squamous cell papilloma, squamous cell carcinoma, adenoma, or adenocarcinoma (combined) in the uterus were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Male B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidences of Harderian glad adenoma, adenocarcinoma, and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); and alveolar/bronchiolar adenoma and adenoma or carcinoma (combined)
      - Higher incidences of urinary bladder papilloma and forestomach papilloma were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Female B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidences of Harderian gland adenoma and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); alveolar/bronchiolar adenoma, carcinoma, and adenoma or carcinoma (combined); and mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined)
      - Increased incidences of granulosa cell tumor, benign, malignant (combined) and tubulostromal adenoma in the ovary and a higher incidence of squamous cell carcinoma in the forestomach were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:

5. Please provide any additional comments, suggestions, or recommendations for improving the report and provide rationale or scientific support for proposed improvements where applicable.

- Reviewer Comments: Overall, the report is outstanding. I have no further suggestions.

### F.3.7 Reviewer 7

1. Information presentation:

a. Please comment on whether the information presented in the draft NTP Technical Report, including presentation of data in any tables and figures, is technically correct, clearly stated, and objectively presented.
  - Reviewer Comments: Generally clear and straightforward. A suggestion for Table 1, page 23, for both the 3-month reproductive study in male SD rats and the 3-month study in B6C3F1/N mice, suggest to remove the following sentence “The following parameters were evaluated: cauda epididymal sperm motility, cauda epididymal and testicular sperm concentration, cauda epididymal and testicular sperm head counts, and testicular sperm production rate,” as these parameters were NOT evaluated in these studies. Also, for the 3-month reproductive study in CD1 mice, it would be good to repeat the content for clarity (especially that artifacts also precluded evaluation of sperm parameters in this study).
b. Please suggest any improvements to the information presented and provide your rationale or scientific support for proposed improvements where applicable.
  - Reviewer Comments: Generally clear and straightforward. A few suggestions to consider: 1) on page 16, lines 25-38, suggest reorganizing the sentences to reflect the procedures more accurately, if correct. That is, describe the vaginal cytology sampling, then the limited necropsy and organ weights, then the cauda epididymis sperm sampling, the mammary gland wet mounts, and finally the tissue collection, preservation and processing through microscopic evaluation. The reference to Table 1 can come at the end, as it applies to all. The current wording suggests, for example, that the sperm sampling was conducted *after* tissue preservation.
c. Please identify any information that should be added or deleted and provide your rationale behind the additions or deletions.
  - Reviewer Comments: Generally clear and straightforward. A few suggestions to consider: 1) On page 8, lines 19-27, the high particle counts are briefly described, but with little discussion of potential impact; adding a statement that the overall exposure of the particle contaminants was <1%, and therefore within accepted limits—as stated in Appendix A, page A4, lines 35-37—would benefit the reader. 2) On page 101, line 13, suggest to add …male [underlined: B6C3F1/N] mice…, and line 22 …sex, [underlined: strain] and species… 3) the paragraph starting on page 101 line 26 and ending on page 102 line 3 clearly describes the mammary gland effects of a-pinene in rats, but never explicitly states that this is considered ‘clear evidence of carcinogenic activity’ (in contrast to all other tumor types where a carcinogenicity conclusion is included).

2. Study design, conduct, and findings:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments: Overall, these studies advance our knowledge of the effects and carcinogenic potential of inhaled a-pinene in rodents. It was disappointing to me that so many of the typically routine reproductive parameter endpoints (sperm analysis, vaginal cytology, mammary wet mounts) were unable to be included due to technical challenges, but these deficiencies do not, on their own, warrant further investigation.
b. Please comment on whether the statistical analyses have been appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: No comments or specific concerns.
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not justified and provide alternate interpretation of the data.
  - Reviewer Comments: In general, no comments or concerns.

3. Evaluation of mutation burden and unique mutation signatures:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments: No comments or specific concerns; hopefully, these data will be published.
b. Please comment on whether the bioinformatic analyses were appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: No comments or specific concerns.
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not scientifically justified and provide an alternate interpretation of the data.
  - Reviewer Comments: In general, the data and conclusions are well supported. My only specific concern is with regard to the male reproductive assessments. I agree that there are no notable effects of a-pinene exposure on reproductive performance in mice or rats, but also think that the nonneoplastic effects on organ weights and histopathology of male reproductive tissues (testes, epididymides, seminal vesicles) warrant a conclusion of a potential male reproductive liability with a-pinene exposure. This could possibly be made more clear in the conclusions on page 106.

4. Levels of Evidence of Carcinogenic Activity categories:

Additional information on the NTP Levels of Evidence of Carcinogenic Activity is available at https://ntp.niehs.nih.gov/sites/default/files/ntp/test_info/cartox_loe_508.pdf and in the draft Technical Report.

a. Indicate your agreement or disagreement with each draft NTP Level of Evidence conclusion, taking into consideration the strength of the toxicology and carcinogenicity results in Hsd:Sprague Dawley^®^ rats and B6C3F1/N mice exposed to α-pinene.
  - Male Hsd:Sprague Dawley^®^ SD^®^ rats:
    - Some evidence of carcinogenic activity
      - Higher incidence of urinary bladder papilloma
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Female Hsd:Sprague Dawley^®^ SD^®^ rats:
    - Clear evidence of carcinogenic activity
      - Increased incidences of mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined)
      - Increased incidences of stromal polyp; adenocarcinoma; squamous cell carcinoma; and squamous cell papilloma, squamous cell carcinoma, adenoma, or adenocarcinoma (combined) in the uterus were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Male B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidences of Harderian glad adenoma, adenocarcinoma, and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); and alveolar/bronchiolar adenoma and adenoma or carcinoma (combined)
      - Higher incidences of urinary bladder papilloma and forestomach papilloma were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:
  - Female B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidences of Harderian gland adenoma and adenoma or adenocarcinoma (combined); hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); alveolar/bronchiolar adenoma, carcinoma, and adenoma or carcinoma (combined); and mammary gland adenocarcinoma and adenoma or adenocarcinoma (combined)
      - Increased incidences of granulosa cell tumor, benign, malignant (combined) and tubulostromal adenoma in the ovary and a higher incidence of squamous cell carcinoma in the forestomach were also considered to be related to exposure
        - ​​☒​ Agree
        - ​​☐​ Agree in principle with the exceptions listed below:
        - ​​☐​ Do not agree with interpretations because:

5. Please provide any additional comments, suggestions, or recommendations for improving the report and provide rationale or scientific support for proposed improvements where applicable.

- Reviewer Comments:
  - Given the sex and species differences in exposure and sensitivity, it should be clarified on page 3 that the human volunteers were all men (references 39 and 40). Also, although not specifically stated in references 41 and 42, these studies are also likely to be in men—it would be good to clarify that TK data from women exposed to alpha-pinene have not been specifically evaluated.
  - Minor typographic clarification on page 104, line 45 (‘Appendix E’).