# Appendix E Evaluation of Mutation Burden and Unique Mutation Signatures in Rat and Mouse Tumors Following Chronic Exposure to α-Pinene

## E.1 Introduction

Examination of the mutation signatures (mutographs) in tumors can provide potential insights into the mechanistic bases of carcinogenesis. Mutation signatures capture the overall genetic events that lead to distinct phenotypes including carcinogenic outcomes. Several well-known human carcinogens, such as aflatoxin, aristolochic acid, ultraviolet (UV) light, and tobacco, elicit exposure-specific mutation signatures in tumors from these respective exposures, and these signatures often provide a mechanistic understanding of the underlying carcinogenic process.

Chronic exposure to α-pinene has resulted in increases in neoplasia in multiple target organs, including the liver, lung, Harderian gland, urinary bladder, forestomach, mammary gland, and ovary in B6C3F1/N mice and the urinary bladder, uterus, and mammary gland in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats. Incidentally, there are relatively high background incidences of tumors within these mouse (liver and lung tumors) and rat (mammary and uterine tumors) strains. Upon chronic chemical exposures, there are often statistically significant increases in these tumor types that are histologically indistinguishable from spontaneous tumors. The underlying genomic alterations and the mode of carcinogenesis mechanisms in these tumors that arise either spontaneously or due to chronic chemical exposures are not well understood.

In this study, whole-genome sequencing experiments were performed on hepatocellular and alveolar/bronchiolar tumors from mice and mammary tumors from rats following chronic inhalation exposure to α-pinene, as well as on the corresponding tumors arising spontaneously due to aging in chamber controls. Mutation burden and de novo mutation signatures were determined, along with their decomposition into the respective somatic variant mutational signature within the published Catalogue of Somatic Mutations in Cancer (COSMIC) signatures derived from human tumors. A brief summary of findings is presented here; additional details will be included in a future publication.

## E.2 Materials and Methods

Whole-genome sequencing was performed on fresh frozen tissue samples collected from animals euthanized as moribund or at scheduled termination following the 2-year exposure. The samples included mouse hepatocellular carcinomas (mHCCs, n = 38), mouse alveolar/bronchiolar carcinomas (mABCs, n = 12), and rat mammary tumors (rMTs, n = 32), which included adenocarcinomas and fibroadenomas arising spontaneously due to aging or due to chronic inhalation exposure to α-pinene (Table E-1). Age-matched normal tissues for each of the target organs were sourced from various studies, including the current α-pinene studies (mouse liver, n = 36; mouse lung, n = 7; rat mammary gland, n = 5), to serve as genomic controls. Genomic DNA was extracted from the above fresh frozen samples using a Gentra Puregene kit (Qiagen, Germantown, MD) and shipped to the Sanger Institute (Cambridge, UK) for paired-end 150 base-paired (bp) whole-genome sequencing at a read depth of 45X.

Table E-1 Sample Counts of Tumors and Nontumor Age-matched Target Organ Controls for Whole-genome Sequencing in the Two-year Inhalation Study of α-Pinene

| Spontaneous Tumor Controls | 50 ppm | 100 ppm | 200 ppm | 400 ppm | Total Tumors | Nontumor Age-matched Target Organ Controls
mHCCs | 12 | –^a^ | 12 | 1 | 13 | 38 | 36
mABCs | 5 | – | 0 | 4 | 3 | 12 | 7
rMTs | 11 | 7 | 7 | 7 | – | 32 | 5

mHCC = mouse hepatocellular carcinomas; mABC = mouse alveolar/bronchiolar carcinomas; rMT = rat mammary tumors.

^a^ Not applicable; mice were exposed to 0, 100, 200, and 400 ppm α-pinene, whereas rats were exposed to 0, 50, 100, and 200 ppm α-pinene.

### E.2.1 Bioinformatics Analysis

The bioinformatics analysis pipelines for both the mouse and rat tumors are similar, and the description below applies to all the tumors examined in this study.

Binary alignment map (BAM) files, generated from the alignment of 150 bp paired-end reads to the Rn6 or Mm10 reference genome, were provided by the Sanger Institute. Unmapped reads were discarded, and alignments with a quality score >20 were extracted using the samtools v.1.18 view function with flags -F 4 -q 20.^115^ A panel of normals (PON) was generated from the nontumor mammary glands following Genome Analysis Toolkit (GATK) recommendations.^116,117^ In summary, the GATK (v.4.2.4) Mutect2 module with -max-mnp-distance 0 flag and the CreateSomaticPanelOfNormals module with --min-sample-count [rat = 1 flag; mouse = 2 flag (default)] were used to create the PON variant call set. Single nucleotide variants (SNVs) and small insertions or deletions (Indels) were called in tumor samples with Mutect2 using the PON and subsequently filtered with FilterMutectCalls to discard mutations derived from reads with median mapping quality <40 and median base quality <30. Clustered SNVs and Indels were discarded with the Bcftools v.1.18 filter function with flags -g 20 and -G 20 for rat only.^115,118^ The following GATK-recommended hard filters for a PON experimental design without available matched normals were applied: MIN(INFO/QD) > 2.0, MIN(INFO/SOR) < 3.0, MIN(INFO/DP) > 10, MIN(INFO/MQRankSum) > −12.5, MIN(INFO/ReadPosRankSum) > −8.0, and MIN(INFO/FS) < 60.0 (SNPs) or MIN(INFO/FS) < 200.0 (Indels). To reduce potential germline contamination in the remaining high confidence set, mutations with GERMQ score [>30 for mouse; >20 for rat] and allele frequency ≤0.1 and ≥0.9 were discarded. Previously reported mutations in rats and mice were removed to further reduce germline contamination.^119,120^ Variant call format (vcf) files were provided to generate mutation count matrices from the Rn6 or Mm10 genome with SigProfilerMatrixGenerator v.1.2.4 at default parameters.^121^ Mutation signatures were extracted from 96-single base substitution trinucleotide count matrices and decomposed into COSMIC signatures (https://cancer.sanger.ac.uk/signatures/) using SigProfilerExtractor v.1.1.4 with flags minimum_signatures = 1, reference_genome = [“rn6”; “mm10”], maximum_signatures = 10, opportunity_genome = [“rn6”; “mm10”].^122^ All figures were generated with custom R v.4.3.1 scripts.

## E.3 Results

### E.3.1 Linear Relationship between Mutation Burden and Exposure Concentration

Following chronic inhalation exposure to α-pinene, the mutation burden (single base substitutions and small indels) increased in an exposure concentration-dependent manner in both mHCCs and rMTs (Figure E-1A, Figure E-1B). However, the mutation burden in mABCs, although increased in some α-pinene-exposed mABCs (increased in three out of seven tumors), was not significant when compared to the spontaneous tumor group (Figure E-6). There were no significant differences in mutation burden between male and female mHCCs (Figure E-3).

Figure E-1

Mutation Burden and Exposure Concentration Linear Relationship in Rodent Tumors Following Chronic (Two-year) Inhalation Exposure to α-Pinene

(A) B6C3F1/N mouse hepatocellular carcinoma mutational burden. (B) Sprague Dawley rat mammary tumor mutational burden. R = Pearson’s correlation coefficient; 0 ppm = spontaneous tumor control samples.

### E.3.2 Mutation Signatures of Mouse Hepatocellular Carcinomas Arising Spontaneously or Following α-Pinene Exposure

Extraction of the de novo mutation signatures from the mHCCs resulted in three (A, B, and C) signatures (Figure E-2, Figure E-3). Signature A was predominant in the α-pinene-exposed mHCCs compared to the spontaneous mHCCs. When these de novo signatures were decomposed into COSMIC signatures (>0.80 cosine similarity), signature A did not resolve into known COSMIC signatures and was assigned a novel mouse-specific signature, mSig1. Overall, these de novo signatures resolved into mSig1 (61.8%), single base substitution 40 (SBS40) (22.1%), SBS5 (9.6%), SBS58 (2.8%), SBS3 (1.4%), and SBS1 (1.3%) (Figure E-4).

Figure E-2

De novo Mutational Spectra of Hepatocellular Carcinomas in B6C3F1/N Mice Arising Spontaneously or Following Chronic (Two-year) Inhalation Exposure to α-Pinene

De novo mutational signatures (A, B, and C) extracted from mouse hepatocellular carcinomas. C = cytosine; A = adenine; G = guanine; T = thymine.

Figure E-3

Mutation Burden of Hepatocellular Carcinomas in B6C3F1/N Mice Arising Spontaneously or Following Chronic (Two-year) Inhalation Exposure to α-Pinene

Mutation burden (absolute) with the corresponding constituent de novo signatures with the metadata on exposure level and sex.

Figure E-4

Proportion of COSMIC Signatures Decomposed from the de novo Signatures of Hepatocellular Carcinomas in B6C3F1/N Mice Arising Spontaneously or Following Chronic (Two-year) Inhalation Exposure to α-Pinene

mSig1 did not resolve into known COSMIC signatures at the default cosine similarity (0.8). COSMIC = Catalogue of Somatic Mutations in Cancer; SBS = single base substitutions.

### E.3.3 Mutation Signatures of Mouse Alveolar/Bronchiolar Carcinomas Arising Spontaneously or Following α-Pinene Exposure

Extraction of the de novo mutation signatures from the mABCs resulted in two (A and B) signatures (Figure E-5, Figure E-6). Signature A was predominant in some of the α-pinene-exposed mABCs compared to the spontaneous mABCs. These de novo signatures resolved into the following COSMIC signatures: SBS5 (71.3%), SBS58 (17.7%), SBS57 (7.7%), and SBS7a (2.7%) (Figure E-7).

Figure E-5

De novo Mutational Spectra of Alveolar/Bronchiolar Carcinomas in B6C3F1/N Mice Arising Spontaneously or Following Chronic (Two-year) Inhalation Exposure to α-Pinene

De novo signatures (A and B) extracted from mouse alveolar/bronchiolar carcinomas. C = cytosine; A = adenine; G = guanine; T = thymine.

Figure E-6

Mutation Burden of Alveolar/Bronchiolar Carcinomas in B6C3F1/N Mice Arising Spontaneously or Following Chronic (Two-year) Inhalation Exposure to α-Pinene

Mutation burden (absolute) with the corresponding constituent de novo signatures with the metadata on exposure level and sex.

Figure E-7

Proportion of COSMIC Signatures Decomposed from the de novo Signatures of Alveolar/Bronchiolar Carcinomas in B6C3F1/N Mice Arising Spontaneously or Following Chronic (Two-year) Inhalation Exposure to α-Pinene

COSMIC = Catalogue of Somatic Mutations in Cancer; SBS = single base substitutions.

### E.3.4 Mutation Signatures of Rat Mammary Tumors Arising Spontaneously or Following α-Pinene Exposure

Extraction of the de novo mutation signatures from rMTs resulted in three (A, B, and C) signatures (Figure E-8, Figure E-9). Signature A was unique to only α-pinene-exposed rMTs compared to the spontaneous rMTs. These de novo signatures resolved into SBS5 (63%), SBS21 (16%), SBS40 (11%), SBS12 (8%), and SBS1 (3%) (Figure E-10). SBS21 and SBS12 were unique to α-pinene-exposed rMTs (data not shown).

Figure E-8

De novo Mutational Spectra of Mammary Tumors in Sprague Dawley Rats Arising Spontaneously or Following Chronic (Two-year) Inhalation Exposure to α-Pinene

De novo signatures (A, B, and C) extracted from rat mammary tumors. C = cytosine; A = adenine; G = guanine; T = thymine.

Figure E-9

Mutation Burden of Mammary Tumors in Sprague Dawley Rats Arising Spontaneously or Following Chronic (Two-year) Inhalation Exposure to α-Pinene

Mutation burden (absolute) with the corresponding constituent de novo signatures with the metadata on exposure level and tumor origination. Adeno = adenocarcinoma; Fibro = fibroadenoma.

Figure E-10

Proportion of COSMIC Signatures Decomposed from the de novo Signatures of Mammary Tumors in Sprague Dawley Rats Arising Spontaneously or Following Chronic (Two-year) Inhalation Exposure to α-Pinene

COSMIC = Catalogue of Somatic Mutations in Cancer; SBS = single base substitutions.

## E.4 Discussion

Chronic α-pinene exposure resulted in a multisite carcinogenic response in mice and rats of both sexes. A recent study by Waidyanatha et al.^5^ indicated that α-pinene oxide, a metabolite of α-pinene, is mutagenic at ≥25 µg/plate in vitro. There was a significant exposure concentration-dependent increase in mutation burden in mHCCs but not in mABCs even with inhalation as the route of exposure. These data support the findings by Waidyanatha et al.,^5^ wherein inhalation and subsequent metabolism of α-pinene to α-pinene oxide in the liver may lead to higher mutagenicity at the principal site of metabolism and thus, a higher mutation burden in the liver compared to the lung in mice. While similar data in rats are not available, the exposure concentration-dependent mutation burden in the rMTs supports the findings by Waidyanatha et al.,^6^ which reported a higher blood maximum concentration (C_max_) and area under the curve (AUC) in the mammary gland than in blood for both α-pinene and α-pinene oxide. Overall, the weight of evidence suggests α-pinene’s carcinogenic activity is operating through a mutagenic mode of action following metabolic activation to α-pinene oxide.

While there were significant age/clock-like signatures (SBS1, SBS5, SBS40) in all tumors assessed, some tumors following α-pinene exposure showed distinct signatures that were likely reflective of the exposure. The novel mutation signature mSig1 was not readily resolved into known COSMIC signatures at the default setting (>0.8 cosine similarity) and was predominant in the mHCCs following α-pinene exposure but not in those arising spontaneously, suggesting that it may be related to the exposure. Similarly, the presence of SBS21 and SBS12 COSMIC signatures in the rMTs following α-pinene exposure, but not in those arising spontaneously, suggests these signatures may also be related to the exposure. These tumor-specific differences in mutation signatures may be related to the different mutagenic and DNA repair processes in the respective target organs. Further adductomic studies on the tumor target organs in rats and mice exposed to α-pinene may provide more specific information on the exogenous biochemical modification of the nucleotides leading to mutagenicity and subsequent carcinogenicity. In addition, the adductomic and multiomic studies on in vitro studies using relevant human cells/organoids will provide translationally relevant information and better inform public health risk assessments.