# Appendix D Internal Concentration Assessment

## D.1 Sample Collection

Blood and mammary gland from male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats in the 3-month investigative study and female rats and B6C3F1/N mice from the 2-year inhalation studies of α-pinene and blood from male rats and mice in the 2-year inhalation studies of α-pinene were analyzed to determine the concentrations of α-pinene and α-pinene oxide, a metabolite of α-pinene, present in the matrix at the time of collection. Lipid content was also measured in blood and mammary gland from the 3-month study and in mammary gland from the 2-year study.

Samples were shipped frozen in sealed vials to the analytical chemistry laboratory at RTI International (Research Triangle Park, NC) and stored at approximately −70°C until analysis. Standards were prepared with α-pinene (lot A-9211; The John D. Walsh Company, Inc.; Ringwood, NJ) and α-pinene oxide (lot MKBT1323V; Sigma-Aldrich; St. Louis, MO).

### D.1.1 Two-year Studies in Rats and Mice

#### D.1.1.1 Blood

At study termination, rats and mice were anesthetized with a 70% CO_2_/30% O_2_ mixture, and blood was collected from the heart of up to 10 (rats) or 11 (mice) randomly selected animals per sex per exposure group into tubes containing K_3_EDTA (tripotassium ethylene diamine tetraacetic acid). Blood samples were aliquoted as appropriate (e.g., 100 µL aliquots in 2-mL clear glass crimp-top vials for analysis of α-pinene and α-pinene oxide). Samples were flash frozen and stored between −60°C and −85°C.

#### D.1.1.2 Mammary Gland

Following blood collection at study termination, mammary glands 1, 2, and 3 were collected from the left and right side of up to 16 female rats or 26 female mice per exposure group. Female animals were wiped down with 70% ethanol prior to tissue collection. Each side was stored separately, allocated as appropriate for analysis of α-pinene and α-pinene oxide, snap frozen in liquid nitrogen, and stored at −60°C to −85°C. Tissue from one side was used for internal concentration assessment, and tissue from the other side was used for molecular pathology.

### D.1.2 Three-month Investigative Study in Rats

At the beginning of the 3-month study, five male and female rats per exposure group were randomly assigned to the biosample group and exposed in an identical fashion to the core group. Prior to study sample collection, the stability of α-pinene and α-pinene oxide under these conditions was confirmed by the analytical chemistry laboratory.

#### D.1.2.1 Blood

At study termination, rats designated for biosampling were anesthetized with a 70% CO_2_/30% O_2_ mixture, and blood was collected from the retroorbital plexus of five rats/sex/exposure group into tubes containing K_3_EDTA and immediately placed on wet ice. Separate aliquots of the samples were allocated for α-pinene and α-pinene oxide analysis. Blood allocated for α-pinene concentration analysis was spiked with internal standard (α-pinene-d3; AromaLAB GmbH; Planegg, Germany). Samples were kept on wet ice during collection and then frozen and stored between −60°C and −85°C.

#### D.1.2.2 Mammary Gland

Following blood collection at study termination, mammary glands 4 and/or 5 were collected from the left and right side of five female rats per exposure group. At least 100 mg of mammary gland sample was used for internal concentration assessment of α-pinene and α-pinene oxide. Tissue allocated for α-pinene concentration analysis was spiked with internal standard (α-pinene-d3; AromaLAB GmbH; Planegg, Germany), and stainless steel balls used for homogenization (Section D.2.2) were added. Each vial was stored separately, weighed, and snap frozen in liquid nitrogen and stored at −60°C to −85°C.

## D.2 Sample Analysis

### D.2.1 α-Pinene and α-Pinene Oxide in Blood

#### D.2.1.1 Two-year Rat and Mouse Studies

α-Pinene and α-pinene oxide concentrations in rat and mouse blood were quantified using qualified methods described in Section D.2.4.1; method qualification data are presented in Table D-2.

For quantitation of α-pinene, study samples (100 µL aliquots) were thawed and analyzed using headspace (HS) gas chromatography (GC)-mass spectrometry (MS) detection. The sample vials were heated for 10 minutes at 60°C before a 250 µL injection was made from the headspace into the HS-GC/MS (Table D-1, System A).

For quantitation of α-pinene oxide, study samples (100 µL) were vortex mixed with 300 µL of 66.7 ng/mL (+)-limonene oxide internal standard in ethyl acetate in a 1.5 mL microcentrifuge tube for 3 minutes. Samples were then centrifuged for 3 minutes at 16,000 g, and the resulting supernatant was transferred to GC autosampler vials. One microliter (1 µL) of each sample was analyzed using GC/MS (Table D-1, System B).

Corresponding matrix calibration standards, blanks, and quality control (QC) standards were prepared with commercially obtained pooled mixed-sexed Sprague Dawley rat blood and male CD-1 mouse blood (BioreclamationIVT, Westbury, NY), both containing K_3_EDTA anticoagulant. α-Pinene in rat and mouse blood was quantified using calibration curves prepared in Sprague Dawley rat blood. α-Pinene oxide was quantified using calibration curves prepared in respective rat or mouse matrix. Blank and QC standards of α-pinene oxide and α-pinene were prepared in respective rat or mouse matrix. Each standard was prepared by spiking with the appropriate volume of standard solution containing analyte (α-pinene or α-pinene oxide) and respective internal standard (n-nonane or (+)-limonene oxide) to reach the desired target concentrations. (Note: For α-pinene analysis, n-nonane standard was used in calibration standards—and not in study samples—to serve as an internal check of the instrument response only and was not used in quantification of α-pinene concentration.) Six calibration standards were prepared for α-pinene, spanning a range of 10 to 1,000 ng/mL α-pinene for both species. Seven matrix calibration standards were prepared for α-pinene oxide, spanning a range of 5 to 250 ng/mL. α-Pinene QC standards were prepared at 20, 100, and 500 ng/mL. α-Pinene oxide QC standards were prepared at 10, 50, and 175 ng/mL. All standards and blanks were prepared for analysis in the same manner as the study samples.

All samples were analyzed for α-pinene and α-pinene oxide using HS-GC/MS and GC/MS, respectively, as described in Section D.2.4.1. Blood α-pinene and α-pinene oxide concentrations were reported as ng analyte/mL blood.

#### D.2.1.2 Three-month Investigative Rat Study

α-Pinene and α-pinene oxide concentrations in rat blood were quantified using a validated method; data for the method was published previously.^62,63^

Matrix calibration standards, blanks, and QC standards were prepared with commercial male Sprague Dawley rat blood containing K_3_EDTA anticoagulant (BioreclamationIVT, Westbury, NY) and run with study samples. Seven calibration standards for each analyte were prepared, spanning a range of 5 to 500 ng/mL α-pinene and 5 to 250 ng/mL α-pinene oxide. Blanks were mixed with the appropriate internal standard. QC standards were prepared at 10, 100, and 250 ng/mL α-pinene or 10, 50, and 200 ng/mL α-pinene oxide. Blood α-pinene and α-pinene oxide concentrations were reported as both ng analyte/mL blood and ng analyte/g lipid.

### D.2.2 α-Pinene and α-Pinene Oxide in Mammary Gland

α-Pinene and α-pinene oxide concentrations in mammary gland were quantified using a validated method for both the 2-year chronic and 3-month investigative studies, and the details were published previously.^62,63^ For quantitation of α-pinene in mammary gland, calibration curves prepared in mammary gland were used while for quantitation of α-pinene oxide in mammary gland, calibration curves prepared in blood were used, which met the acceptance criteria for accuracy and precision.^62^

For a small number of samples, dilutions were made to acquire measurements within the calibration curve range.

Matrix calibration standards, blanks, and QC standards were prepared using female Sprague Dawley rat blood or mammary gland (BioreclamationIVT, Westbury, NY) as appropriate and run with study samples. Six calibration standards, spanning a range of 100 to 5,000 ng/mL α-pinene, were prepared in mammary gland, and 25 to 500 ng/mL α-pinene oxide were prepared in blood. QC standards were prepared at 250 and 2,500 ng/mL α-pinene or 50 and 400 ng/mL α-pinene oxide. For quantitation of α-pinene oxide, the mammary gland tissue dilution used to prepare the homogenate was used to convert ng/mL homogenate to ng/g of analyte in mammary gland. Mammary gland α-pinene and α-pinene oxide concentrations were reported as both ng/g mammary and ng/g lipid.

### D.2.3 Lipid Content in Blood and Mammary Gland

Lipid content of blood (3-month investigative rat study only) and mammary gland was determined based on the method described in Johnson et al.^114^ Blood samples used were separate aliquots from blood used for concentration determination of α-pinene and α-pinene oxide. Lipid content was analyzed in the following samples: the same aliquot of mammary gland used for concentration determination of α-pinene and the corresponding lipid value was used to generate the lipid-adjusted α-pinene in mammary gland; an aliquot of mammary gland homogenate used for concentration determination of α-pinene oxide and the corresponding lipid value was used to generate lipid-adjusted α-pinene oxide in mammary gland.

Soybean oil was mixed with 50/50 (v/v) methylene chloride and methanol with the appropriate volumes to create standards for a calibration concentration range of 0.12 to 1.2 mg/mL total lipids and high and low concentration QC standards.

Mammary gland samples following concentration determination of α-pinene were diluted with 800 µL of deionized water and then heated at 90°C for 2 hours, followed by vortex mixing. A 100 µL aliquot of each blood and diluted mammary gland sample was vortex mixed with 4.9 mL of 50/50 (v/v) methylene chloride and methanol and then centrifuged for 5 to 20 minutes at 3,000 rpm. A 250 µL aliquot of the mammary extract or a 1,000 µL aliquot of the blood extract was transferred to the bottom of a 13 × 100 mm glass culture tube for later reaction.

A 200 µL aliquot of the mammary gland homogenate prepared for α-pinene oxide analysis was placed in a 15-mL polypropylene centrifuge tube. Each sample was extracted as above with 50/50 (v/v) methylene chloride and methanol using 2 × 1 mL and 1 × 2 mL, and extracts were combined. The extract was transferred to a 5-mL volumetric flask, with additional extraction solvent added to the mark, and then mixed by inversion. A 100 µL aliquot of the extract was transferred to the bottom of a 13 × 100 mm glass culture tube for later reaction.

All samples, calibrations, and QC standards were evaporated to dryness in their 13 × 100 mm culture tubes in a dry block heater set at 100°C. After cooling, samples were vortex mixed with 200 µL of concentrated sulfuric acid and then dried again at 100°C in the dry block heater for approximately 15 minutes before cooling.

Samples were vortex mixed with 3 mg vanillin in 68% aqueous phosphoric acid and then allowed to react in the dark for at least 30 minutes, which produced colored solutions for analysis. Aliquots were transferred to cuvettes for ultraviolet (UV) spectroscopy analysis at 490 nm using an Acquity 2998 photodiode array detector with cuvette holder (Waters Corporation; Milford, MA). Calibration standards, QC standards, and blanks were subject to the hydrolysis reaction and UV absorption analysis in the same manner as the samples.

Calibration curves relating the response of absorbance to the concentration of the calibration standards were constructed using a 1/X weighted linear regression. The lipid concentration in study samples were calculated using their absorbance, the calibration regression equation, the sample weight, and the dilution factor. The concentration values for the standards and samples were used to calculate the individual and average concentrations and uncertainties. The sample results were calculated for the sample matrix (i.e., the lipid content in mammary gland) using the weight/volume ratio of the initial extract.

### D.2.4 Instrumentation and Quantitation

#### D.2.4.1 Qualified Analytical Methods of Blood for Two-year Studies

α-Pinene and α-pinene oxide in rat and mouse whole blood were detected using System A and System B in Table D-1, respectively. Calibration curves relating the analyte response (α-pinene) or response ratio (α-pinene oxide) to the internal standard and the concentration of α-pinene or α-pinene oxide in blood were constructed using a 1/X weighted linear regression. The concentration of α-pinene and α-pinene oxide in study samples was calculated using the response or response ratio, as appropriate, and the regression equation. Analyte concentrations were reported as ng of α-pinene and α-pinene oxide per mL of whole blood. The performance of the calibration curves for each analyte was evaluated once before study sample analysis and during study sample analysis. Each sample set, method blank, and control group was bracketed by a QC set, which consisted of three concentrations (low, medium, and high).

For the analysis of α-pinene in rat blood samples, the calibration standard curve had a correlation coefficient (r) >0.99 and a relative error (RE) ranging from −15.6% to 16.0%. The low (20.0 ng/mL), mid (100 ng/mL), and high (500 ng/mL) rat blood QC standard results gave RE values ranging from −38.2% to −7.3% and had a relative standard deviation (RSD) ≤20.4%. The higher RE and RSD values were likely attributed to not using an internal standard in the study samples to compensate for any sample preparation or instrumentation variability. The calibration curve of α-pinene mouse blood analysis had an (r) >0.99 and an RE ranging from −16.4% to 12.3%. The triplicate low (20.0 ng/mL), mid (100 ng/mL), and high (500 ng/mL) mouse blood QC standard results gave RE values ranging from −17.0% to 1.5% and an RSD of 4.5%. These data demonstrate that the analytical method is acceptable to quantitate α-pinene in rodent blood.

For the analysis of α-pinene oxide in rat blood samples, the calibration standard curve had an (r) >0.99 and an RE ranging from −9.6% to 12.2%. The triplicate low (10.0 ng/mL), mid (50.0 ng/mL), and high (175 ng/mL) rat blood QC standard results gave RE values ranging from −16.4% to 6.8% and an RSD ≤11.8%. The triplicate low (10.0 ng/mL), mid (50.0 ng/mL), and high (175 ng/mL) mouse blood QC standard results gave RE values ranging from −14.1% to −2.5% and an RSD ≤3.4%. These data demonstrate that the analytical method is acceptable to quantitate α-pinene oxide in rodent blood.

#### D.2.4.2 Validated Methods

The validated methods for analyzing α-pinene and α-pinene oxide in blood and mammary gland from the 3-month investigative rat study and mammary gland from the 2-year study were published previously.^62,63^

During blood α-pinene concentration determination in samples from the 3-month investigative study, a drop in internal standard response was observed, which was traced back to the day of sample collection, suggesting a potential error in internal standard addition between the 2 days. Therefore, to allow comparisons between sexes and matrices, quantitation of α-pinene in study sample blood was achieved without using internal standard.

Data from study samples were considered valid if they were bracketed by valid QC sets. In general, each sample set, method blank, and control was bracketed by two QC sets, which consisted of a calibration blank and two concentrations of calibration standards (QC low and QC high). A QC set passed when the measured concentration for QC standards was within 15% of its nominal value for at least 67% of all QC standards. All QC sets met acceptance criteria.

Table D-1 Analytical Systems and Parameters Used in the Internal Concentration Assessment of α-pinene and α-pinene Oxide in Blood in the Two-year Studies

Instrument and Parameter | System A | System B
System | HP 6890 plus GC/HP 5973 MSD with Agilent MassHunter software (version A.01.02) | Agilent 7890A GC/5975A MSD with MassHunter software (version B.07.00, SP2)
Sampling
Headspace Autosampler | CombiPAL Autosampler (CTC Analytics, Zwingen, Switzerland) | NA
Sample Cycle Time | 20 minutes^a^ | NA
Vial Size | 2 mL | NA
Syringe Volume and Temperature | 2.5 mL at 60°C | NA
Sample Temperature and Equilibrium Time | 60°C for 10 minutes | NA
Mixer | On | NA
Sample Volume | 250 µL (headspace injection) | 1 µL (liquid injection)
Column and Program
Column | Agilent DB-5MS (30 m × 0.25 mm ID, 0.25 μm film thickness) | Agilent DB-5MS (29 m × 0.25 mm ID, 0.25 μm film thickness)
Carrier Gas | Helium at 1.2 mL/min | Helium at 1.2 mL/min
Oven Temperature Program | 40°C for 5 minutes, then 5°C/min to 75°C, then 37.5°C/min to 150°C, 1 minute hold | 40°C for 5 minutes, then 20°C/min to 140°C, then 20°C/min to 300°C, 10 minute hold
Inlet Temperature | 270°C | 200°C
Injection Mode | Splitless | Splitless
Retention Time | ~10.6 minutes | α-pinene oxide: 16.0 minutes (+)-limonene oxide: 17.3 minutes
Auxiliary Temperature | 300°C | 280°C
MS Detector
Source Temperature | 230°C | 230°C
Quadrupole Temperature | 150°C | 150°C
Ionization Mode | EI (70 eV) | EI (70 eV)
Acquisition Mode | SIM for 10.8 to 15.0 minutes^b^ m/z 93 (quantitation ion) m/z 136 (confirmation ion) | SIM α-pinene oxide: m/z 109 (+)-limonene oxide: m/z 94

NA = not applicable; GC = gas chromatography; HP = Hewlett Packard; MSD = mass spectrometry detection; EI = Electron Impact Ionization; SIM = single ion monitoring; ID = internal diameter.

^a^ To reduce sample time in the autosampler, the PAL cycle time started 10 minutes before injection into the GC, and the PAL started the equilibration cycle of the next sample 10 minutes into the chromatography run to achieve equilibration of initial conditions by the time the next injection was made by the PAL.

^b^ The m/z 126 ion was for identity confirmation only. Data were also collected at m/z 57 and 128 from 6 to 10.8 minutes but was not used for analysis.

Table D-2 Qualification and Stability Data for α-Pinene and α-Pinene Oxide in Rat and Mouse Whole Blood Used in the Two-year Studies

Parameter | α-Pinene | | α-Pinene Oxide
Parameter | Male SD Rat | Male CD-1 Mouse | Male SD Rat | Male CD-1 Mouse
Matrix Concentration Range (ng/mL) | 10–1,000^a^ | 10–1,000^a^ | 5–250^b^ | 5–175^c^
Sensitivity
LLOQ (ng/mL) | 10.0 | 10.0 | 5.0 | 5.0
LLOQ %RE | ≤±7.7 | ≤±7.7 | ≤±12.2 | ≤±11.9
LLOQ %RSD | 5.9 | 3.8 | ≤6.8 | 7.4
LOD (ng/mL) | 1.51 | 1.14 | 1.04 | 1.05
Correlation Coefficient (r) | 0.9985 | 0.9939 | 0.9997 | 0.9985^d^
Precision and Accuracy^e^
%RSD Low | 20.7 | 4.5 | 11.8 | 3.4
%RSD Medium | 12.6 | 3.4 | 2.0 | 0.8
%RSD High | 13.5 | 1.7 | 3.8 | 0.7
%RE Low | −38.2 to −7.3 | ≤1.5 | −16.4 to 5.9 | −2.5 to −8.7
%RE Medium | −35.4 to −18.9 | ≤−11.2 | −1.8 to 1.8 | −11.5 to −10.2
%RE High | −33.3 to −12.5 | ≤−1.7 | 0.0 to 6.8 | −14.1 to −12.9

SD = Sprague Dawley; LLOQ = lower limit of quantitation; LOD = limit of detection; RSD = relative standard deviation; RE = relative error.

^a^ Range validated with six matrix calibration standards.

^b^ Range validated with seven matrix calibration standards.

^c^ Range validated with four quality control standards.

^d^ Correlation coefficient of triplicate quality control standards prepared at 10, 50, and 175 ng/mL.

^e^ Precision was estimated as %RSD. Accuracy was estimated as average %RE. Low = 20 ng/mL, medium = 100 ng/mL, and high = 500 ng/mL for α-pinene. Low = 10 ng/mL, medium = 50 ng/mL, and high = 175 ng/mL for α-pinene oxide.