# Appendix C Sentinel Animal Program

## C.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that might affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or exposed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

For these toxicology and carcinogenesis studies, blood samples were collected from each sentinel animal, allowed to clot, and the serum was separated. Additionally, fecal samples were collected and tested for endoparasites and Helicobacter species. All samples were processed appropriately with serology and Helicobacter testing performed by IDEXX BioResearch (formerly Rodent Animal Diagnostic Laboratory [RADIL], University of Missouri), Columbia, MO, for determination of the presence of pathogens. Evaluation for endo- and ectoparasites was performed in-house by the testing laboratory.

The laboratory methods and agents for which testing was performed are tabulated in Table C-1 and Table C-2 below; the times at which samples were collected during the studies are also listed.

## C.2 Results

Rats: All test results were negative.

Mice: All test results were negative.

Table C-1 Methods and Results for Sentinel Animal Testing in Male and Female Rats in the Three-month Reproductive and Two-year Inhalation Studies of α-Pinene

Collection Time Points | Three-month Reproductive Study | | | Two-year Study
Collection Time Points | Quarantine | Study Termination | Study Termination (Replacement Animal) | Quarantine | 4 Weeks | 6 Months | 12 Months | 14 Months (Unscheduled) | 15 Months (Unscheduled) | 16 Months (Unscheduled) | 18 Months | Study Termination
Number Examined (Males/Females) | 0/10 | 5/5 | 0/1 | 5/5 | 5/5 | 5/5 | 5/5 | 1/0 | 0/1 | 0/1 | 4/2 | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Kilham rat virus (KRV) | − | − | − | − | − | − | − | − | − | − | − | −
Mycoplasma pulmonis | − | − | − | − | − | − | − | − | − | − | − | −
Pneumocystis carinii | NT | NT | NT | NT | NT | − | NT | NT | NT | NT | NT | NT
Pneumonia virus of mice (PVM) | − | − | − | − | − | − | − | − | − | − | − | −
Rat coronavirus/ sialodacryoadenitis virus (RCV/SDA) | − | − | − | − | − | − | − | − | − | − | − | −
Rat minute virus (RMV) | − | − | − | − | − | − | − | − | − | − | − | −
Rat parvo virus (RPV) | − | − | − | − | − | − | − | − | − | − | − | −
Rat theilovirus (RTV) | − | − | − | − | − | − | − | − | − | − | − | −
Sendai | − | − | − | − | − | − | − | − | − | − | − | −
Theiler’s murine encephalomyelitis virus (TMEV) | − | − | − | − | − | − | − | − | − | − | − | −
Toolan’s H-1 | − | − | − | − | − | − | − | − | − | − | − | −
Immunofluorescence Assay (IFA)
RCV/SDA | NT | NT | NT | NT | NT | NT | NT | NT | NT | NT | − | NT
Number Examined (Males/Females) | 0/10 | 0/0 | 0/0 | 5/5 | 5/5 | 5/5 | 5/5 | 1/0 | 0/2 | 0/1 | 4/2 | 0/0
Method/Test
In-house Evaluation
Endoparasites (evaluation of cecal content) | − | NT | NT | − | − | − | − | − | − | − | − | NT
Ectoparasites (evaluation of perianal surface) | − | NT | NT | − | − | − | − | − | − | − | − | NT

– = negative; NT = not tested.

Table C-2 Methods and Results for Sentinel Animal Testing in Male and Female Mice in the Three-month Reproductive and Two-year Inhalation Studies of α-Pinene

Collection Time Points | Three-month Reproductive Study^a^ | | Two-year Study^b^
Collection Time Points | Quarantine | Study Termination | Quarantine | 4 Weeks | 2 Months (Unscheduled) | 6 Months | 12 Months | 18 Months | Study Termination
Number Examined (Males/Females) | 0/10 | 5/5 | 10/5 | 10/5 | 0/1 | 5/3 | 5/3 | 4/3 | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Ectromelia virus | − | − | − | − | − | − | − | − | −
Epizootic diarrhea of infant mice (EDIM) | − | − | − | − | − | − | − | − | −
Lymphocytic choriomeningitis virus | − | − | − | − | − | − | − | − | −
Mycoplasma pulmonis | − | − | − | − | − | − | − | − | −
Mouse hepatitis virus (MHV) | − | − | − | − | − | − | − | − | −
Mouse norovirus (MNV) | − | − | − | − | − | − | − | − | −
Mouse parvovirus (MPV) | − | − | − | − | − | − | − | − | −
Minute virus of mice (MVM) | − | − | − | − | − | − | − | − | −
Pneumonia virus of mice (PVM) | − | − | − | − | − | − | − | − | −
Rat theilovirus (RTV) | − | − | − | − | − | − | − | − | −
Reovirus (REO3) | − | − | − | − | − | − | − | − | −
Sendai | − | − | − | − | − | − | − | − | −
Theiler’s murine encephalomyelitis virus (TMEV) GDVII | − | − | − | − | − | − | − | − | −
Immunofluorescence Assay (IFA)
Mouse parvovirus (MPV) | NT | NT | NT | NT | NT | NT | − | NT | NT
Mouse hepatitis virus (MHV) | NT | NT | NT | NT | NT | NT | NT | NT | −
Polymerase Chain Reaction (PCR)
Helicobacter species | NT | NT | NT | NT | NT | NT | NT | − | NT
Number Examined (Males/Females) | 0/10 | 0/0 | 10/5 | 10/5 | 0/1 | 5/3 | 5/3 | 4/3 | 0/0
Method/Test
In-house Evaluation
Endoparasites (evaluation of cecal content) | − | NT | − | − | − | − | − | − | NT
Ectoparasites (evaluation of perianal surface) | − | NT | − | − | − | − | − | − | NT

^a^ Number Examined indicates number of CD-1 mice.

^b^ Number Examined for the Two-year Study Quarantine and 4 weeks was 5 male CD-1 mice, 5 male B6C3F1/N mice, and 5 female B6C3F1/N mice. All other time points in the 2-year study, including the 2-month unscheduled time point, used B6C3F1/N mice.

− = negative; NT = not tested.

Table C-3 Methods and Results for Sentinel Animal Testing in Male and Female Rats in the Three-month Investigative Inhalation Study of α-Pinene

Collection Time Point | Quarantine | 4 Weeks | Study Termination
Number Examined (Males/Females) | 5/5 | 5/5 | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Kilham rat virus (KRV) | − | − | −
Lymphocytic choriomeningitis virus (LCMV) | − | − | −
Mycoplasma pulmonis | − | − | −
Pneumocystis carinii | − | − | −
Pneumonia virus of mice (PVM) | − | − | −
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | − | − | −
Rat minute virus (RMV) | − | − | −
Rat parvo virus (RPV) | − | − | −
Rat theilovirus (RTV) | − | − | −
Reovirus (REO3) | − | − | −
Sendai | − | − | −
Theiler’s murine encephalomyelitis virus (TMEV) | − | − | −
Toolan’s H-1 | − | − | −
Polymerase Chain Reaction (PCR) – Feces
Helicobacter spp. | − | − | −
Helicobacter bilis | − | − | −
Helicobacter ganmani | − | − | −
Helicobacter hepaticus | − | − | −
Helicobacter mastomyrinus | − | − | −
Helicobacter rodentium | − | − | −
Helicobacter typhlonius | − | − | −
Aspiculuris tetraptera | − | − | −
Syphacia muris | − | − | −
Syphacia obvelata | − | − | −
Polymerase Chain Reaction (PCR) – Pelt Swabs | − | − | −
Myocoptes | − | − | −
Radfordia/Myobia | − | − | −

– = negative.