# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in NIH-07 and NTP-2000 Rat and Mouse Ration

## B.1 NIH-07 Feed

Table B-1 Ingredients of NIH-07 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 23.00
Ground #2 Yellow Shelled Corn | 24.25
Wheat Middlings | 10.00
Oat Hulls | 0.0
Alfalfa Meal (Dehydrated, 17% Protein) | 4.0
Purified Cellulose | 0.0
Soybean Meal (47% Protein) | 12.0
Fish Meal (62% Protein) | 10.0
Corn Oil (without Preservatives) | 0.0
Soy Oil (without Preservatives) | 2.5
Dried Brewer’s Yeast | 2.0
Calcium Carbonate (USP) | 0.5
Vitamin Premix^a^ | 0.25
Mineral Premix^b^ | 0.15
Calcium Phosphate, Dibasic (USP) | 1.25
Sodium Chloride | 0.5
Choline Chloride (70% Choline) | 0.10
Dried Skim Milk | 5.00
Dried Molasses | 1.50
Corn Gluten Meal (60% Protein) | 3.00
Methionine | 0.0

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-2 Vitamins and Minerals in NIH-07 Rat and Mouse Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 6,062 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 5,070 IU | D-activated animal sterol
Vitamin K | 3.1 mg | Menadione sodium bisulfite complex
Vitamin E | 22 IU | α-Tocopheryl acetate
Niacin | 33 mg | –
Folic Acid | 2.4 mg | –
d-Pantothenic Acid | 19.8 mg | d-Calcium pantothenate
Riboflavin | 3.8 mg | –
Thiamine | 11 mg | Thiamine mononitrate
B_12_ | 50 µg | –
Pyridoxine | 6.5 mg | Pyridoxine hydrochloride
Biotin | 0.15 mg | d-Biotin
Minerals
Iron | 132 mg | Iron sulfate
Zinc | 18 mg | Zinc oxide
Manganese | 66 mg | Manganese oxide
Copper | 4.4 mg | Copper sulfate
Iodine | 2.0 mg | Calcium iodate
Cobalt | 0.44 mg | Cobalt carbonate

^a^ Per kg of finished diet.

Table B-3 Nutrient Composition of NIH-07 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 22.7 ± 0.4 | 22.3–23.1 | 3
Crude Fat (% by Weight) | 5.2 ± 0.2 | 5.0–5.4 | 3
Crude Fiber (% by Weight) | 3.58 ± 0.144 | 3.46–3.74 | 3
Ash (% by Weight) | 6.26 ± 0.384 | 5.85–6.61 | 3
Amino Acids (% of Total Diet)
Arginine | 1.120 ± 0.425 | 0.258–1.49 | 12
Cystine | 0.515 ± 0.802 | 0.116–3.05 | 12
Glycine | 1.017 ± 0.320 | 0.217–1.31 | 12
Histidine | 0.922 ± 1.458 | 0.125–5.53 | 12
Isoleucine | 0.920 ± 0.223 | 0.214–1.03 | 12
Leucine | 1.879 ± 0.463 | 0.423–2.13 | 12
Lysine | 0.454 ± 0.100 | 0.111–1.32 | 12
Methionine | 0.454 ± 0.112 | 0.102–0.515 | 12
Phenylalanine | 1.023 ± 0.237 | 0.276–1.12 | 12
Threonine | 769.11 ± 2,661.3 | 0.168–9,220 | 12
Tryptophan | 0.312 ± 0.201 | 0.076–0.922 | 12
Tyrosine | 0.804 ± 0.190 | 0.209–0.894 | 12
Valine | 0.971 ± 0.367 | 0.12–1.17 | 12
Essential Fatty Acids (% of Total Diet)
Linoleic | 2.407 ± 0.477 | 1.99–3.77 | 12
Linolenic | 0.188 ± 0.112 | 0.003–0.296 | 12
Vitamins
Vitamin A (IU/kg) | 5,016 ± 31.84 | 4,780–5,380 | 3
α-Tocopherol (ppm) | 69.08 ± 9.14 | 46.8–78.7 | 12
Thiamine (ppm)^a^ | 11.87 ± 1.46 | 10.7–13.5 | 3
Riboflavin (ppm) | 12.91 ± 4.76 | 4.2–19.8 | 12
Niacin (ppm) | 95.22 ± 15.55 | 51.9–112.0 | 12
Pantothenic Acid (ppm) | 42.6 ± 5.70 | 29.4–51.1 | 12
Pyridoxine (ppm)^a^ | 14.92 ± 9.09 | 8.27–42.0 | 12
Folic Acid (ppm) | 2.32 ± 0.580 | 1.37–3.09 | 12
Biotin (ppm) | 0.274 ± 0.201 | 0.0–0.638 | 12
Vitamin B_12_ (ppb) | 48.53 ± 6.74 | 40.0–61.6 | 12
Choline (as Chloride) (ppm) | 0.643 ± 0.107 | 0.441–0.8 | 12
Minerals
Calcium (%) | 1.14 ± 0.11 | 1.06–1.26 | 3
Phosphorus (%) | 4.04 ± 5.43 | 0.87–10.3 | 3
Potassium (%) | 0.838 ± 0.037 | 0.769–0.88 | 12
Chloride (%) | 0.643 ± 0.107 | 0.441–0.8 | 12
Sodium (%) | 0.398 ± 0.114 | 0.274–0.721 | 12
Magnesium (%) | 0.185 ± 0.015 | 0.162–0.218 | 12
Iron (ppm) | 373.25 ± 59.74 | 271.0–469.0 | 12
Manganese (ppm) | 84.225 ± 18.16 | 35.3–104.0 | 12
Zinc (ppm) | 61.91 ± 10.60 | 47.4–89.2 | 12
Copper (ppm) | 12.61 ± 4.63 | 0.683–21.1 | 12
Iodine (ppm) | 1.61 ± 1.05 | 0.0–3.45 | 12
Chromium (ppm) | 2.00 ± 1.324 | 0.277–3.97 | 12
Cobalt (ppm) | 0.432 ± 0.312 | 0.0–0.965 | 12

^a^ As hydrochloride.

Table B-4 Contaminant Levels in NIH-07 Rat and Mouse Ration

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.40 ± 0.018 | 0.391–0.423 | 3
Cadmium (ppm) | 0.09 ± 0.007 | 0.08–0.093 | 3
Lead (ppm) | 0.17 ± 0.02 | 0.142–0.177 | 3
Mercury (ppm) | 0.01 ± 0.00 | 0.01–0.01 | 3
Selenium (ppm) | 0.302 ± 0.03 | 0.278–0.335 | 3
Aflatoxins (ppb)^a^ | <5.0 | – | 3
Nitrate Nitrogen (ppm)^b^ | 8.79 ± 1.66 | 7.79–10.7 | 3
Nitrite Nitrogen (ppm)^b^ | 0.15 ± 0.001 | 0.15–0.152 | 3
BHA (ppm)^a,c^ | <1.0 | – | 3
BHT (ppm)^a,c^ | <1.0 | – | 3
Aerobic Plate Count (CFU/g)^d^ | <10.0 | – | 3
Coliform (MPN/g)^d^ | <3.0 | – | 3
Escherichia coli (MPN/g)^d^ | <3.0 | – | 3
Total Nitrosamines (ppb)^e^ | 2.93 ± 3.43 | 0.0–6.7 | 3
N-Nitrosodimethylamine (ppb)^e^ | 1.63 ± 1.46 | 0.0–2.8 | 3
N-Nitrosopyrrolidine (ppb)^e^ | 1.95 ± 2.758 | 0.0–3.9 | 2
Pesticides (ppm)^f^
Methyl Chlorpyrifos | 0.045 ± 0.014 | 0.034–0.06 | 3
Malathion | 0.034 ± 0.013 | 0.022–0.049 | 3

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ Results of microbiological analyses were less than the limit of detection.

^e^ All values were corrected for percent recovery.

^f^ Only pesticides above the limit of quantitation (LOQ) are listed. All pesticides tested can be found in the Chemical Effects in Biological Systems (CEBS) database.^92^

## B.2 NTP-2000 Feed

Table B-5 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 23.00
Ground #2 Yellow Shelled Corn | 22.44
Wheat Middlings | 15.0
Oat Hulls | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5
Purified Cellulose | 5.5
Soybean Meal (49% Protein) | 4.0
Fish Meal (60% Protein) | 4.0
Corn Oil (without Preservatives) | 3.0
Soy Oil (without Preservatives) | 3.0
Dried Brewer’s Yeast | 1.0
Calcium Carbonate (USP) | 0.9
Vitamin Premix^a^ | 0.5
Mineral Premix^b^ | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4
Sodium Chloride | 0.3
Choline Chloride (70% Choline) | 0.26
Methionine | 0.2

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-6 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 4,000 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 1,000 IU | D-activated animal sterol
Vitamin K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | 100 IU | –
Niacin | 23 mg | –
Folic Acid | 1.1 mg | –
d-Pantothenic Acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
Vitamin B_12_ | 52 µg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished diet.

Table B-7 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.72 ± 0.534 | 13.7–15.7 | 27
Crude Fat (% by Weight) | 8.08 ± 0.626 | 5.1–8.6 | 27
Crude Fiber (% by Weight) | 9.54 ± 0.511 | 7.7–10.3 | 27
Ash (% by Weight) | 4.97 ± 0.164 | 4.41–5.22 | 27
Amino Acids (% of Total Diet)
Arginine | 0.807 ± 0.070 | 0.67–0.97 | 32
Cystine | 0.220 ± 0.021 | 0.15–0.25 | 32
Glycine | 0.704 ± 0.037 | 0.62–0.8 | 32
Histidine | 0.340 ± 0.067 | 0.27–0.68 | 32
Isoleucine | 0.546 ± 0.037 | 0.43–0.66 | 32
Leucine | 1.095 ± 0.060 | 0.96–1.24 | 32
Lysine | 0.698 ± 0.100 | 0.31–0.86 | 32
Methionine | 0.407 ± 0.039 | 0.26–0.49 | 32
Phenylalanine | 0.628 ± 0.035 | 0.54–0.72 | 32
Threonine | 0.513 ± 0.039 | 0.43–0.61 | 32
Tryptophan | 0.168 ± 0.070 | 0.11–0.525 | 32
Tyrosine | 0.425 ± 0.063 | 0.28–0.54 | 32
Valine | 0.668 ± 0.042 | 0.55–0.77 | 32
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.920 ± 0.242 | 3.49–4.55 | 32
Linolenic | 0.224 ± 0.134 | 0.004–0.35 | 32
Vitamins
Vitamin A (IU/kg) | 5,406 ± 548.43 | 208–2,430 | 27
α-Tocopherol (ppm) | 74.38 ± 23.62 | 20.3–124.0 | 32
Thiamine (ppm)^a^ | 7.75 ± 1.13 | 6.8–12.5 | 27
Riboflavin (ppm) | 8.02 ± 3.46 | 1.1–17.5 | 32
Niacin (ppm) | 81.46 ± 10.62 | 66.4–107.0 | 32
Pantothenic Acid (ppm) | 26.61 ± 10.6 | 17.4–81.0 | 32
Pyridoxine (ppm)^a^ | 9.60 ± 2.45 | 2.3–14.3 | 32
Folic Acid (ppm) | 1.65 ± 0.47 | 1.15–3.27 | 32
Biotin (ppm) | 0.323 ± 0.112 | 0.0–0.704 | 32
B_12_ (ppb) | 50.57 ± 33.14 | 18.3–174.0 | 32
Choline (as Chloride) (ppm) | 2,537 ± 628 | 1,160–3,790 | 32
Minerals
Calcium (%) | 0.905 ± 0.05 | 0.802–0.992 | 27
Phosphorus (%) | 0.57 ± 0.028 | 0.522–0.639 | 27
Potassium (%) | 0.662 ± 0.035 | 0.569–0.733 | 32
Chloride (%) | 0.395 ± 0.068 | 0.3–0.688 | 32
Sodium (%) | 0.192 ± 0.026 | 0.153–0.283 | 32
Magnesium (%) | 0.216 ± 0.052 | 0.185–0.49 | 32
Iron (ppm) | 181.8 ± 46.27 | 21–311 | 32
Manganese (ppm) | 49.87 ± 8.97 | 21.0–73.1 | 32
Zinc (ppm) | 51.13 ± 9.64 | 18.4–78.5 | 32
Copper (ppm) | 7.70 ± 2.42 | 3.21–16.3 | 32
Iodine (ppm) | 0.50 ± 0.236 | 0–1.0 | 32
Chromium (ppm) | 0.72 ± 0.66 | 0.249–3.97 | 31
Cobalt (ppm) | 0.215 ± 0.146 | 0.086–0.864 | 30

^a^ As hydrochloride.

Table B-8 Contaminant Levels in NTP-2000 Rat and Mouse Ration

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.248 ± 0.032 | 0.205–0.314 | 27
Cadmium (ppm) | 0.052 ± 0.004 | 0.045–0.061 | 27
Lead (ppm) | 0.117 ± 0.13 | 0.058–0.621 | 27
Mercury (ppm) | 0.01 ± 0.002 | 0.005–0.015 | 27
Selenium (ppm) | 0.164 ± 0.025 | 0.127–0.251 | 27
Aflatoxins (ppb)^a^ | <5.0 | – | 24
Nitrate Nitrogen (ppm)^b^ | 10.67 ± 2.97 | 5.05–17.7 | 27
Nitrite Nitrogen (ppm)^b^ | 0.129 ± 0.013 | 0.12–0.152 | 27
BHA (ppm)^c^ | 1.06 ± 0.245 | 1.0–2.24 | 27
BHT (ppm)^a,c^ | <1 | – | 27
Aerobic Plate Count (CFU/g) | 16.30 ± 32.72 | 10.0–180 | 27
Coliform (MPN/g)^d^ | <3 | – | 27
Escherichia coli (MPN/g)^d^ | <3 | – | 27
Salmonella sp. (MPN/g) | Negative | – | 3
Total Nitrosamines (ppb)^e^ | 8.31 ± 3.72 | 2.4–17.1 | 25
N-Nitrosodimethylamine (ppb)^e^ | 2.74 ± 2.19 | 0.0–7.9 | 25
N-Nitrosopyrrolidine (ppb)^e^ | 5.6 ± 2.468 | 1.2–12.0 | 25
Pesticides (ppm)^f^
Methyl Chlorpyrifos | 0.114 ± 0.08 | 0.026–0.36 | 25
Ethyl Chlorpyrifos | 0.025 | 0.025–0.025 | 13
Methyl Pirimiphos | 0.027 ± 0.007 | 0.025–0.05 | 13
Malathion | 0.114 ± 0.112 | 0.016–0.54 | 27
Piperonyl Butoxide | 0.011 ± 0 | 0.011–0.011 | 1
Deltamethrin | 0.03 ± 0.001 | 0.029–0.03 | 2

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ Results of microbiological analyses were less than the limit of detection.

^e^ All values were corrected for percent recovery.

^f^ Only pesticides above the limit of quantitation (LOQ) are listed. All pesticides tested can be found in the Chemical Effects in Biological Systems (CEBS) database.^92^