# Appendix A Generation of Chamber Concentrations

## A.1 Procurement and Characterization of α-Pinene

α-Pinene was obtained from The John Walsh Company, Inc. (Ringwood, NJ) in one lot (A-9211). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at RTI International (Research Triangle Park, NC) and the study laboratory at Battelle (Columbus, OH). Reports on analyses performed in support of α-pinene studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot A-9211, a clear oily liquid at room temperature, was first received by the analytical chemistry laboratory in 17 drums. At the time of receipt, identity and purity were determined for samples from five drums chosen at random using gas chromatography (GC) with mass spectrometry (MS) detection, GC/MS using a chiral column, and optical polarimetry to confirm the identity of α-pinene and measure enantiomeric composition.

Seven drums of lot A-9211 were later received by the study laboratory from the analytical chemistry laboratory and used in support of the 2-year and 3-month investigative and reproductive Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rat studies, the 2-year and 3-month studies in B6C3F1/N mice, and the 3-month reproductive study in CD-1 mice in this report. Identification was determined by the study laboratory using infrared (IR) and ^1^H and ^13^C nuclear magnetic resonance (NMR) spectroscopies (Figure A-1, Figure A-2, and Figure A-3, respectively). The IR spectrum was consistent with a reference spectrum (Sadtler Library, HLX #132, Bio-Rad, Hercules CA). ^1^H and ^13^C NMR spectra of the test article were also consistent with the structure of α-pinene and with reference spectra (Spectral Database for Organic Compounds, SDBSWeb, National Institutes of Advanced Industrial Science and Technology, Tokyo, Japan). Minor unidentified impurities were present in the ^1^H and ^13^C NMR spectra of the test article. Elemental analysis was performed by Galbraith Laboratories, Inc. (Knoxville, TN) to aid in identification. The relative amounts of carbon (87.04%), hydrogen (12.24%), and nitrogen (<0.05%) were within 4% of theoretical values (88.16%, 11.84%, and 0.00%, respectively). Enantiomeric composition measured using GC with flame ionization detection (FID) (Table A-2, System A) was determined to be 68% (+) α-pinene [(1R)-(+)-α-pinene] and 32% (−) α-pinene [(1S)-(−)-α-pinene] (Figure A-4), which was consistent with previous results obtained at the analytical laboratory.

Purity of lot A-9211, evaluated by the study laboratory using GC/FID (Table A-2, System B) and GC/MS (Table A-2, System C), was determined to be approximately 98.7%. Four reportable impurities with peak areas between 0.09% and 0.63% of the total integrated peak area were detected, and additional minor impurities were present at <0.1% peak area. Three of the reportable impurities were identified as camphene (0.63%), tricyclene (0.32%), and β-pinene (0.09%). The fourth (0.24%) was not conclusively identified. Lot A-9211 was also analyzed for butylated hydroxytoluene (BHT), a known inhibitor of α-pinene, using GC/MS (Table A-2, System C). The test article was confirmed BHT free. Moisture content was determined by Karl Fischer titration at Galbraith Laboratories, Inc. (Knoxville, TN), which yielded an average water content of <0.38%. The overall purity of lot A-9211 was determined to be >98%.

Bulk α-pinene was stored in the original shipping containers at room temperature without homogenization between drums. Reanalysis of the bulk chemical was performed by the study laboratory, using GC/FID, within 30 days prior to the start of each study, at regular intervals during each chronic study, and 30 to 60 days after termination of the last animal in each study. Purity (Table A-2, System F) and enantiomeric composition (Table A-2, System A) were measured relative to the frozen reference standard of the same lot that was collected during the initial chemical handling and stored at approximately −20°C. The purity and enantiomeric composition were consistent with the frozen reference standard, and no degradation was detected.

## A.2 Vapor Generation and Exposure System

A diagram of the vapor generation and delivery system used in the studies is shown in Figure A-5. The test chemical, α-pinene, was pumped from an 8-gallon stainless steel reservoir into a heated glass column (approximately 300°F) filled with glass beads and completely wrapped with heat tape. A waste collection flask was connected to the bottom of the vaporizer column to collect residual chemical not completely vaporized.

Preheated nitrogen (approximately 300°F) entered the vaporizer column from below, vaporized the test chemical, and carried the vapor from the generator cabinet in the exposure suite to the distribution manifold in the exposure room through a heated chemical transport line (approximately 120°F). The nitrogen-chemical mixture was diluted with heated air (approximately 120°F) before entering the distribution manifold. Concentration in the manifold was determined by the chemical pump rate, nitrogen flow rate, and dilution air flow rate. The pressure in the distribution manifold was kept fixed (approximately 7 psi) to ensure constant flow rates through the manifold and into all exposure chambers as the flow of vapor to each chamber was adjusted.

Individual heated Teflon^®^ delivery lines (approximately 90°F) carried the vapor from the distribution manifold to three-way exposure valves at the chamber inlets. The chamber exposure valves diverted vapor delivery to the manifold exhaust until the generation system stabilized and exposure could proceed. The delivery rate to each chamber was controlled by a precision metering valve at the manifold. To initiate exposure, the chamber exposure valves were rotated to direct α-pinene vapor into the chamber inlet, where it was diluted with conditioned air to achieve the desired exposure concentration. Conditioned air was a temperature-controlled and filtered mix of air derived from each exposure chamber’s wet and dry air duct supplies. The temperature was adjusted by passage over a temperature-controlled radiator after sequential treatment with Purafil^®^, charcoal, and HEPA filters. Target dew point temperatures of the wet and dry ducts were 63°F and 12°F, respectively. Air for the ducts was either passed over desiccant beds to lower the dew point (dry duct) or injected with clean steam to raise the dew point (wet duct).

The study laboratory designed the inhalation exposure chamber (Lab Products, Inc.; Seaford, DE) so that uniform vapor concentrations could be maintained throughout the chamber with catch pans in place. The total volume of the chamber was 2.3 m^3^ with an active mixing volume of 1.7 m^3^. A condensation particle detector (Model 3022A; TSI, Inc.; St. Paul, MN) was used in the exposure chambers before the start and during generation.

Prior to the studies, the chambers were tested for particle counts before and during exposure atmosphere generation. Particle counts <200 particles/cm^3^ are typical of an exposure atmosphere when no generation is occurring. Particle counts above this level, especially if the counts increase with exposure concentration and are above this level during the off-exposure period, suggest a contribution from the aerosol due to the generation system. Particle counts were detected above 200 particles/cm^3^ during the prestudy evaluations at one target concentration before exposure (1,410 particles/cm^3^) and at seven target concentrations during generation of the exposure atmosphere (1,210 to 16,000 particles/cm^3^), indicating the increase in particle counts was due to generation, although the particle counts were not proportional to the exposure concentration. To attempt to mitigate aerosol particle formation, different temperatures were tested in the vaporizer, column, and delivery line, but none of these temperature conditions affected the particle counts. Particle counts in the distribution manifold and delivery lines were measured and were below 200 particles/cm^3^, indicating particles were not sourced from the lines. Particle counts above 200 particles/cm^3^ were not present in the previously published 3-month studies conducted in Fischer 344 (F344/N) rats and B6C3F1/N mice, which used a different test article lot.^2^ To determine if the test article lot was the cause of particle formation, a small volume of the previous test article lot was evaluated in the current exposure system. No differences were observed in the high particle counts for the different lots. The chemical composition of particles was evaluated after collection on filter paper and none of the constituents correlated with the test article exposure. The source of particle formation remained undetermined.

As a final consideration to evaluate the effect of the particle formation on the experiment, the weight percentage of the aerosol contribution at the target concentrations was calculated. Using a scanning mobility particle sizer (SMPS; TSI, Model 3036), the particles were determined to have a mass median aerodynamic diameter of approximately 0.2 microns. Using this diameter and assuming a density of 1 g/cm^3^, the total mass of the particles was calculated in each exposure chamber atmosphere as a percentage by weight of the amount of α-pinene. Measurements were collected over the duration of a 6-hour test generation. During this test, the highest particle concentration (11,000 particles/cm^3^) was observed in the 50 ppm chamber, resulting in a weight percent of particles of 0.017%.

During the course of the studies, particle counts were collected monthly from all chambers, and the minimum and maximum values for each chamber are shown in Table A-1. Particle counts above 200 particles/cm^3^ were measured during all studies and in all chambers except the 400 ppm chamber for rats in the 3-month reproductive study. Using a similar approach (0.2 micron particle diameter and 1 g/cm^3^ particle density) to assess the impact of the particle formation on the overall exposure, the maximum particle concentrations by weight were less than 0.1% of the target α-pinene concentration. Based on this consideration, there was not a concern for the particle formation to affect the overall interpretation because impurities less than or equal to 0.1% of the total concentration are considered acceptable and do not need to be reported.

Table A-1 Particle Counts by Chambers during Generation

Studies, Species | 50 ppm | | 100 ppm | | 200 ppm | | 400 ppm
Studies, Species | Min | Max | Min | Max | Min | Max | Min | Max
2-year, Sprague Dawley Rats | 9 | 745 | 9 | 1,110 | 2 | 511 | NA | NA
3-month Reproductive, Sprague Dawley Male Rats | NA | NA | 32 | 585 | 70 | 839 | 14 | 50
2-year, B6C3F1/N Mice 3-month, B6C3F1/N Male Mice 3-month Reproductive, CD-1 Male Mice | NA | NA | 14 | 35,400 | 15 | 40,900 | 2 | 23,600
3-month Investigative, Sprague Dawley Rats | 4,620 | 8,270 | 2,080 | 7,550 | 6,670 | 9,640 | NA | NA

Value units are particles/cm^3^.

NA = not applicable.

## A.3 Vapor Concentration Monitoring

Exposure chamber and room concentrations of α-pinene were monitored using an online GC/FID (Table A-2, System D). Samples from exposure and control chambers were drawn approximately two times per hour during each exposure period. Samples were drawn through Teflon^®^ tubing connected to each exposure chamber’s sampling line using a 16-port Hastelloy^®^-C stream-select valve that directs a continuous stream of sampled atmosphere to a six-port Hastelloy^®^-C gas-sampling valve with a 1-mL sample loop. Both valves were mounted in a dedicated valve oven (approximately 175°C). A vacuum regulator maintained a constant vacuum in the sample loop to compensate for variations in sample line pressure. An in-line flow meter between the vacuum regulator and GC allowed for digital measurement of sample flow.

The online GC was checked at the beginning of the day and after every 12 samples for instrument drift against an online standard vapor of α-pinene in nitrogen supplied by a permeation tube standard generator (Kin-Tek; Precision Calibration Systems; La Marque, TX). The online GC was calibrated as required to meet acceptance criteria. Calibration was performed by correlating the peak area at the time of sampling with grab sample concentration data collected with activated coconut charcoal sorbent gas-sampling tubes (ORBO™-32; Supelco, Inc.; Bellefonte, PA) analyzed using an offline GC/FID (Table A-2, System E). The known volumes of chamber atmospheres were sampled from each chamber at a constant flow rate ensured by a calibrated critical-orifice-controlled sampler. Adsorbed test chemicals were extracted with toluene and analyzed with the offline GC/FID; butylbenzene was used as an internal standard (ISTD). The offline GC was calibrated with gravimetrically prepared standards of α-pinene in toluene containing the ISTD.

Summaries of the chamber vapor concentrations are given in Table A-3 through Table A-7. The mean measured chamber concentrations were within the acceptance criteria of 10% for all exposure groups of every study. The percentage of acceptable samples was ≥99% for all exposure groups of every study except for the 100 ppm group of the 3-month reproductive study in Sprague Dawley rats, which was 98%.

## A.4 Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined with and without animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after vapor generation was terminated (T_10_) was approximately 9 minutes. T_90_ and T_10_ values ranged from 9 to 10 minutes without animals present and from 9 to 12 minutes with animals. Because the presence of animals may have had a slight effect on the time for the vapor concentration to build up and decay, a value of 12 minutes was selected for T_90_ during in-life exposure.

The persistence of α-pinene in the chambers after vapor delivery ended was determined by monitoring the concentration in the 200 ppm rat chambers and 400 ppm mouse chambers with and without animals present. The time for the chamber concentration to decay to <1% of the starting concentration after vapor generation was terminated (T_1_) was 21 minutes for both the 200 ppm rat chamber and the 400 ppm mouse chamber without animals present. When animals were present, T_1_ was 28 minutes for the 200 ppm rat chamber and 31 minutes for the 400 ppm mouse chamber.

The uniformity of α-pinene vapor concentration was evaluated with and without animals present in the chambers. The vapor concentration was measured using the online GC (Table A-2, System D) with the stream-selection valve fixed in one position to allow continuous monitoring from a single input line. Prior to the study, concentrations were measured at 12 chamber positions: one in front and one in the back for each of the six possible animal cage unit positions per chamber. Chamber concentration uniformity was maintained throughout the studies; uniformity measurements were all within the acceptable criterion of <5% of the relative standard deviation (RSD).

To measure stability and purity of the test article in the generation and delivery system prior to the studies, samples of the test atmosphere from the distribution line, generator reservoir, and low and high exposure concentration chambers for each species were collected at the beginning and end of the exposure day, with and without animals present. The atmospheric samples were collected with sorbent gas-sampling tubes (ORBO™-32; Supelco, Inc.; Bellefonte, PA). Duplicate samples were collected and analyzed from the distribution line and the highest and lowest exposure concentration chambers for each species, with one set collected at the beginning and the other at the end of the exposure day. An additional liquid sample was collected from the generator reservoir. No evidence of degradation or change in enantiomeric composition was noted in any part of the exposure system in samples collected prior to the 2-year and 3-month reproductive rat studies and the 2-year and 3-month studies in B6C3F1/N mice and 3-month reproductive study in CD-1 mice, with or without animals present.

Adsorbed test chemicals from all samples were extracted with toluene and were analyzed by GC/FID for purity (Table A-2, System B) and enantiomeric composition (Table A-2, System A). In all exposure samples collected without animals present, four impurity peaks representing >0.1% of the total area were detected. The identified impurities were tricyclene, camphene, and d-limonene; one impurity was not identified. Additional impurities with areas <0.1% of the total area were also detected, including β-pinene. Concentrations were consistent among all samples. In all exposure samples collected with animals present, three impurity peaks representing >0.1% of the total area were detected. The identified impurities were tricyclene and camphene; one impurity was not identified. Additional impurities with areas <0.1% of the total area were also detected with animals present, including d-limonene and β-pinene. Concentrations were consistent among all samples.

To measure the stability of the test chemical in the exposure system, concentrations in all exposure chambers were monitored during all studies using online GC/FID (Table A-2, System D). The mean concentrations for all chambers for all studies met the acceptance criteria of being within ±10% of the target concentration with an RSD of ≤10%. The mean exposure concentrations were within 1% of the target concentrations with an RSD ranging from 1% to 4%.

Overall, the purity of α-pinene in the exposure chambers reflected the purity of the bulk test chemical. Test article purity and stability were retested before and after the 3-month investigative study in rats, and the results were consistent with the initial test.

Approximately 0.002 ppm α-pinene was detected in the 0 ppm chamber of the 2-year studies but not the field blank (room air) or solvent and sorbent blanks. Given the low concentration and the isolated incidence, the presence of α-pinene for the 0 ppm sample and the probability of an actual exposure to α-pinene in the 0 ppm group were deemed unlikely. No α-pinene was detected in the 0 ppm chamber or room air during the 3-month investigative rat study.

Table A-2 Gas Chromatography Systems Used in the Two-year Inhalation Study of α-Pinene

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | Agilent Cyclosil B (30 m × 0.25 mm ID, 0.25 µm film thickness) | Helium at 1.3 mL/min | 60°C for 0.5 minutes, then 5°C/min to 105°C; 20°C/min to 160°C
System B
Flame ionization | Restek ZB-5ms (30 m × 0.25 mm ID, 0.5 µm film thickness) | Helium at 1.2 mL/min | 40°C for 3 minutes, then 4°C/min to 300°C
System C
Mass spectrometry | Restek ZB-5ms (30 m × 0.25 mm ID, 1 µm film thickness) | Helium at 1.2 mL/min | 40°C for 3 minutes, then 4°C/min to 300°C
System D
Flame ionization | Restek Rtx-5 (15 m × 0.53 mm ID, 1.5 µm film thickness) | Nitrogen at 9 psi | Hold at 85°C
System E
Flame ionization | Restek Rtx-5 (15 m × 0.53 mm ID, 1.5 µm film thickness) | Nitrogen at 9 psi | 60°C for 1 minute, then 8°C/min to 110°C, then 15°C/min to 200°C, no final hold
System F
Flame ionization | Restek Rtx-5 (30 m × 0.53 mm ID, 1.5 µm film thickness) | Helium at 4.8 mL/min | 70°C for 1 minute, then 8°C/min to 200°C

ID = internal diameter.

Table A-3 Summary of Chamber Concentrations in the Two-year Inhalation Study of α-Pinene in Rats

Exposure Date | Target Concentration (ppm) | Total Number of Readings | Determined Concentration (ppm)^a^ | Difference from Target (%)^b^ | Acceptable Samples (%)^c^
February 2015–February 2017 | 0 (Room) | 8,110 | <LOD | NA | 100
February 2015–February 2017 | 0 | 8,063 | <LOD | NA | 100
February 2015–February 2017 | 50 | 7,901 | 50.1 ± 0.7 | 0 ± 1 | >99
February 2015–February 2017 | 100 | 7,997 | 100.3 ± 2.0 | 0 ± 2 | >99
February 2015–February 2017 | 200 | 8,007 | 200 ± 4 | 0 ± 2 | >99

LOD = limit of detection; NA = not applicable.

^a^ Data shown as mean of readings ± standard deviation.

^b^ Percent difference from target concentration ± relative standard deviation.

^c^ Acceptable range: target concentration ± 10%; except for room, acclimation, and 0 ppm chamber: <LOD (0.42 ppm).

Table A-4 Summary of Chamber Concentrations in the Three-month Reproductive Inhalation Study of α-Pinene in Rats

Exposure Date | Target Concentration (ppm) | Total Number of Readings | Determined Concentration (ppm)^a^ | Difference from Target (%)^b^ | Acceptable Samples (%)^c^
February 2015–May 2015 | 0 (Room) | 976 | <LOD | NA | 100
February 2015–May 2015 | 0 | 966 | <LOD | NA | 100
February 2015–May 2015 | 100 | 997 | 99.4 ± 3.7 | 1 ± 4 | 98
February 2015–May 2015 | 200 | 951 | 199 ± 3 | 0 ± 2 | >99
February 2015–May 2015 | 400 | 960 | 401 ± 7 | 0 ± 2 | >99

LOD = limit of detection; NA = not applicable.

^a^ Data shown as mean of readings ± standard deviation.

^b^ Percent difference from target concentration ± relative standard deviation.

^c^ Acceptable range: target concentration ± 10%; except for room, acclimation, and 0 ppm chamber: <LOD (0.42 ppm).

Table A-5 Summary of Chamber Concentrations in the Three-month Investigative Inhalation Study of α-Pinene in Rats

Exposure Date | Target Concentration (ppm) | Total Number of Readings | Determined Concentration (ppm)^a^ | Difference from Target (%)^b^ | Acceptable Samples (%)^b^
November 2017–February 2018 | 0 (Room) | 1,026 | <LOD | NA | 100
November 2017–February 2018 | 0 (Acclimation) | 34 | <LOD | NA | 100
November 2017–February 2018 | 0 | 1,019 | <LOD | NA | 100
November 2017–February 2018 | 50 | 1,002 | 49.9 ± 0.5 | 0 ± 1 | 100
November 2017–February 2018 | 100 | 1,052 | 99.5 ± 1.6 | 0 ± 2 | 100
November 2017–February 2018 | 200 | 1,006 | 200 ± 2 | 0 ± 1 | 100

LOD = limit of detection; NA = not applicable.

^a^ Data shown as mean of readings ± standard deviation.

^b^ Percent difference from target concentration ± relative standard deviation.

^c^ Acceptable range: target concentration ± 10%; except for room, acclimation, and 0 ppm chamber: <LOD (0.42 ppm).

Table A-6 Summary of Chamber Concentrations in the Two-year Inhalation Study of α-Pinene in Mice

Exposure Date | Target Concentration (ppm) | Total Number of Readings | Determined Concentration (ppm)^a^ | Difference from Target (%)^b^ | Acceptable Samples (%)^c^
February 2015–February 2017 | 0 (Room) | 8,118 | <LOD | NA | 100
February 2015–February 2017 | 0 | 8,004 | <LOD | NA | 100
February 2015–February 2017 | 100 | 8,188 | 99.8 ± 2.3 | 0 ± 2 | 99
February 2015–February 2017 | 200 | 7,796 | 200 ± 3 | 0 ± 2 | >99
February 2015–February 2017 | 400 | 7,825 | 400 ± 6 | 0 ± 1 | >99

LOD = limit of detection; NA = not applicable.

^a^ Data shown as mean of readings ± standard deviation.

^b^ Percent difference from target concentration ± relative standard deviation.

^c^ Acceptable range: target concentration ± 10%; except for room, acclimation, and 0 ppm chamber: <LOD (0.42 ppm).

Table A-7 Summary of Chamber Concentrations in B6C3F1/N Mice in the Three-month Inhalation Study and CD-1 Mice in the Three-month Reproductive Inhalation Study of α-Pinene

Exposure Date | Target Concentration (ppm) | Total Number of Readings | Determined Concentration (ppm)^a^ | Difference from Target (%)^b^ | Acceptable Samples (%)^c^
February 2015–May 2015 | 0 (Room) | 993 | <LOD | NA | 100
February 2015–May 2015 | 0 | 976 | <LOD | NA | 100
February 2015–May 2015 | 100 | 1,018 | 99.4 ± 3.6 | 1 ± 4 | 99
February 2015–May 2015 | 200 | 968 | 200 ± 3 | 0 ± 2 | >99
February 2015–May 2015 | 400 | 980 | 401 ± 7 | 0 ± 2 | >99

LOD = limit of detection; NA = not applicable.

^a^ Data shown as mean of readings ± standard deviation.

^b^ Percent difference from target concentration ± relative standard deviation.

^c^ Acceptable range: target concentration ± 10%; except for room, acclimation, and 0 ppm chamber: <LOD (0.42 ppm).

Figure A-1

Fourier Transform Infrared Absorption Spectrum of α-Pinene

Figure A-2

^1^H Nuclear Magnetic Resonance Spectrum of α-Pinene

Figure A-3

^13^C Nuclear Magnetic Resonance Spectrum of α-Pinene

Figure A-4

Representative Chromatogram for Enantiomeric Ratio Determination of α-Pinene

Figure A-5

Schematic of the Vapor Generation and Delivery System in the Inhalation Study of α-pinene