# Overview

Sulfolane was nominated to the National Toxicology Program (NTP) because of its contamination of drinking water supplies near a natural gas and petroleum refinery site. As part of the broader NTP sulfolane research program, the metabolism of sulfolane was evaluated in rats, mice, and humans (in vitro),^2^ and the kinetics of sulfolane exposure were evaluated in rats and mice.^3^ In addition, because of questions of species sensitivity, 28-day toxicity studies were conducted to determine whether guinea pigs were more sensitive to sulfolane exposure than rats and mice.^4^ Immunotoxicity studies were also conducted in rats and mice^5^ to further explore identified immune toxicity in previous studies in the literature. The 2-year carcinogenicity studies of sulfolane in rats and mice are presented in this Technical Report.