# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of Sulfolane (CASRN 126-33-0) Administered in Drinking Water to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats and B6C3F1/N Mice by letter in June 2025 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Peer review the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of Sulfolane (CASRN 126-33-0) Administered in Drinking Water to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats and B6C3F1/N Mice.

NTP carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Charles A. Easley, Ph.D.
  Associate Professor, Department of Environmental Health Science
  University of Georgia
  Athens, Georgia, USA
- Elana R. Elkin, Ph.D., M.P.H.
  Assistant Professor, Division of Environmental Health
  San Diego State University
  San Diego, California, USA
- Debie J. Hoivik, Ph.D.
  Vice President, Early Development
  Akebia Therapeutics
  Cambridge, Massachusetts, USA
- Kevin A. Keane, D.V.M., Ph.D.
  Senior Director of Pathology
  Blueprint Medicines
  Cambridge, Massachusetts, USA