# Collaborators and Contributors

## Collaborators

- Division of Translational Toxicology, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Chad R. Blystone, Ph.D., Lead Toxicologist^1,9,10^
  Mark F. Cesta, D.V.M., Ph.D., Lead Pathologist^1,5,9,10^
  Helen C. Cunny, Ph.D.^1,5,10^
  Michelle J. Hooth, Ph.D.^1,10^
  Angela P. King-Herbert, D.V.M.^5,9,10^
  Barry S. McIntyre, Ph.D. (Retired)^1,9,10^
  Georgia K. Roberts, Ph.D.^5,10^
  Kelly A. Shipkowski, Ph.D.^5,10^
  Keith R. Shockley, Ph.D.^2,5,10^
  Stephanie L. Smith-Roe, Ph.D.^5,9,10^
  Matthew D. Stout, Ph.D.^1,5,10^
  Suramya Waidyanatha, Ph.D.^1,5,9,10^
  Nigel J. Walker, Ph.D.^1,10^
- Social & Scientific Systems, a DLH Holdings Corp Company, Research Triangle Park, North Carolina, USA
  Contracts GS-00F-173CA/75N96022F00055 and HHSN273201600011C
  Shawn F. Harris, M.S.^2,10^
- ICF, Reston, Virginia, USA
  Contracts 75N96025C00003 and GS00Q14OADU417 (Order No. HHSN273201600015U)
  Lisa M. Prince, Ph.D.^9,10^

## Contributors

- Division of Translational Toxicology, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Danica Andrews, B.S.^5^
  Mamta Behl, Ph.D. (currently at Neurocrine Biosciences, Inc.)^1^
  Milene L. Brownlow, Ph.D. (currently at NIH Center for Scientific Review)^12^
  Michelle C. Cora, D.V.M.^1,9^
  Michael J. DeVito, Ph.D. (currently at U.S. Environmental Protection Agency)^1^
  Jennifer M. Fostel, Ph.D.^2,5^
  Paul M. Foster, Ph.D. (Retired)^1^
  Dori R. Germolec, Ph.D.^1^
  Ronald A. Herbert, D.V.M., Ph.D.^5^
  Grace E. Kissling, Ph.D. (Retired)^1^
  Scott A. Masten, Ph.D.^1^
  Veronica G. Robinson, M.S.^1,5^
  Kristen R. Ryan, Ph.D.^1^
  Brian C. Sayers, Ph.D. (currently at Incyte)^1^
  Jason P. Stanko, Ph.D.^5^
  Molly K. Vallant, M.T. (Retired)^1^
  Shannah K. Witchey, Ph.D. (currently at Inotiv)^1,9^
  Kristine L. Witt, M.S. (Retired)^1^
  Mary S. Wolfe, Ph.D. (Retired)^12^
- Pathology Working Group on Two-year Mice (August 3, 2022), National Institute of Environmental Health Sciences, Triangle Park, North Carolina, USA
  Mark F. Cesta, D.V.M., Ph.D., National Institute of Environmental Health Sciences^3^
  Ronald A. Herbert, D.V.M., Ph.D., National Institute of Environmental Health Sciences^3^
- Contract HHSN273201500013C
  Georgette Hill, D.V.M., Ph.D., Inotiv^3^
  Rebecca R. Moore, D.V.M., Inotiv^3^
  Cynthia J. Willson, D.V.M., Ph.D., Inotiv^3^
- Battelle, Columbus, Ohio, USA
  Contract HHSN273201400015C
  Milton R. Hejtmancik, Ph.D., Principal Investigator^5,6^
  Barney R. Sparrow, Ph.D., Principal Investigator^5,6^
  Matthew A. Buccellato, D.V.M., Ph.D.^3^
  Brian L. Burback, Ph.D.^3^
  P. Scott Clemons, Ph.D.^3^
  Dawn M. Fallacara, Ph.D.^3^
  Sam J. Harbo, D.V.M.^3^
  Kathleen H. Mellinger, M.S.^3^
  Eve Mylchreest, Ph.D.^3^
  Michael J. Ryan, D.V.M., Ph.D.^3^
  Jamie S. Richey, M.S.^3^
  Kemla Siddoway, B.S.^3^
- RTI International, Research Triangle Park, North Carolina, USA
  Contract HHSN273201400022C
  Reshan A. Fernando, Ph.D., Principal Investigator^5,6^
  James C. Blake, B.A., Deputy Principal Investigator^5,6^
  Donna B. Browning, B.S.^3^
  Stephen D. Cooper, M.S.^3^
  Jennifer Gilliam, B.S.^3^
- Charles River Laboratories, Inc., Durham, North Carolina, USA
  Contract HHSN273201500012C
  Vivian S. Chen, D.V.M., Ph.D.^3^
  Crystal L. Johnson, D.V.M.^3^
  Ashley M. Talley, D.V.M.^3^
  Erin M. Quist, D.V.M., Ph.D.^5^
- Taconic BioSciences, Inc., Germantown, New York, USA
  Contract HHSN273201600020C
  Jeffrey Lohmiller, D.V.M., Principal Investigator^5,6^
  Emily Hackett^3^
  Jami Southard, A.G.S.^3^
- Instem, Staffordshire, United Kingdom
  Contract HHSN273201300004C
  Mark Handley, Computing H.N.C., Program Manager^2,5,6^
  Pam Reese, B.S.^2^
  Martin Tyszka, M.S.^2^
- ASRC Federal Data Solutions, Beltsville, Maryland, USA
  Contracts 75N96023A00001 and HHSN316201200054W
  Julie Berke, B.S.^2^
  Phyllis Brown, B.S.^2^
  Erik Diffin, B.S.^2^
  Karen Gilbert, B.S.^2^
  Marcus A. Jackson, B.S.^2^
  Christina Myers, M.S.^2^
  Tony Silver, B.S.^2^
  Longlong Yang, Ph.D.^2^
- Integrated Laboratory Systems, LLC, an Inotiv Company, Research Triangle Park, North Carolina, USA
  Contract HHSN273201300009C
  Leslie Recio, Ph.D., Principal Investigator^5,6^
  Cheryl A. Hobbs, Ph.D.^3^
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Contract HHSN273201800006C
  Emily Singletary, B.S.,Manager^3,5,6^
  Michael J. Carden^3^
  Leslie C. Couch, B.S.^3^
  Lorri N. Ezedin, B.S.^3^
  Jami L. Heller, B.S.^3^
- CSS Corporation, Research Triangle Park, North Carolina, USA
  Contract HHSN273201500006C
  Steven Brecher, Ph.D., Principal Investigator^5,6,11^
  Sudha Iyer, B.S.^11^
  Varghese S. Tharakan, D.V.M.^11^
- Social & Scientific Systems, a DLH Holdings Corp Company, Research Triangle Park, North Carolina, USA
  Contract GS-00F-173CA/75N96022F00055 and HHSN273201600011C
  Sandra J. McBride, Ph.D., Principal Investigator^2,5,6^
  Laura J. Betz, M.S.^2^
  Guanhua Xie, Ph.D.^2^
- ICF, Reston, Virginia, USA
  Contracts 75N96025C00003 and GS00Q14OADU417 (Order No. HHSN273201600015U)
  David Burch, M.E.M., Principal Investigator^5,6^
  Tamara Dawson^12^
  Katherine S. Duke, Ph.D.^10^
  Hannah J. Eglinton, B.A.^10^
  Tara Hamilton, M.S.^10^
  Anthony K. Hannani, M.P.H.^10^
  Cary E. Haver, M.P.H.^5^
  Aishwarya Javali, M.S.^12^
  Kevin T. O’Donovan, B.A.^10^
  Jennifer I. Powers, M.A.P.^10^
  Nkoli Ukpabi, M.S.^10^
  Jessica A. Wignall, M.S.P.H.^5,6^

Collaborator and Contributor Roles and Definitions^a^

No. | Role | Definition
1 | Conceptualization | Ideas; formulation or evolution of overarching research goals and aims
2 | Data Curation, Formal Analysis, and Software | Management activities to annotate (produce metadata), scrub, and maintain research data (including software code, when it is necessary for interpreting the data) for initial use and later reuse or Application of statistical, mathematical, computational, or other formal techniques to analyze or synthesize study data or Programming and software development; design of computer programs; implementation of computer code and supporting algorithms; testing of existing code components
3 | Investigation | Conduct of the research/investigation process, specifically the performance of experiments or the collection of data/evidence
4 | Methodology | Development or design of methodology; creation of models
5 | Project Administration | Management and coordination responsibility for research planning and execution
6 | Resources for Study Conduct | Provision of study materials, reagents, patients, laboratory samples, animals, instrumentation, computing resources, or other analysis tools
7 | Validation | Verification, whether as a part of the activity or separately, of the overall replication/reproducibility of results/experiments and other research outputs
8 | Visualization | Preparation, creation, and/or presentation of the published work, specifically visualization/data presentation
9 | Writing: Original | Preparation, creation, and/or presentation of the published work, specifically the writing of the initial draft (including substantive translation)
10 | Writing: Review and Editing | Preparation, creation, and/or presentation of the published work by those from the original research group, specifically provision of substantive critical review, commentary, or revision—including pre- or post-publication stages
11 | Quality Assessment | Conduct of independent assessments of accuracy, consistency, and completeness of various aspects of research products and their components, including data; identification of areas in the conduct and documentation of studies that merit correction or improvement of the description of methodologies
12 | Peer Review and Production | Coordination and management of external peer review and publication, including identification of experts, conflict-of-interest screening, correspondence with reviewers, preparation of review documents, and publication activities

^a^ Developed using the Contributor Roles Taxonomy (CRediT) framework.^1^