# References

1 National Information Standards Organization (NISO). CRediT (Contributor Roles Taxonomy). Baltimore, MD: National Information Standards Organization; 2024. [Accessed: July 26, 2024]. https://credit.niso.org/
2 Waidyanatha S, Black SR, Blystone CR, Patel PR, Watson SL, Snyder RW, Fennell TR. Disposition and metabolism of sulfolane in Harlan Sprague Dawley rats and B6C3F1/N mice and in vitro in hepatocytes from rats, mice, and humans. Xenobiotica. 2020; 50(4):442–453. 10.1080/00498254.2019.1630786 31184953
3 Waidyanatha S, Black SR, Fennell TR, Watson SL, Patel PR, Cooper SD, Blake J, Robinson VG, Fernando RA, Blystone CR. Toxicokinetics and bioavailability of sulfolane, a ground water contaminant, following oral and intravenous administration in rodents: A dose, species, and sex comparison. Toxicol Appl Pharmacol. 2019;379:114690. 10.1016/j.taap.2019.114690 31344372
4 Shipkowski KA, Cora MC, Cesta MF, Robinson VG, Waidyanatha S, Witt KL, Vallant MK, Fallacara DM, Hejtmancik MR, Masten SA, et al. Comparison of sulfolane effects in Sprague Dawley rats, B6C3F1/N mice, and Hartley guinea pigs after 28 days of exposure via oral gavage. Toxicol Rep. 2021;8:581–591. 10.1016/j.toxrep.2021.02.004 33777704
5 Watson ATD, Johnson VJ, Luster MI, Burleson GR, Fallacara DM, Sparrow BR, Cesta MF, Cora MC, Shockley KR, Stout MD, et al. Immunotoxicity studies of sulfolane following developmental exposure in Hsd:Sprague Dawley SD rats and adult exposure in B6C3F1/N mice. J Immunotoxicol. 2021; 18(1):1–12. 10.1080/1547691X.2020.1869355 34357831
6 National Center for Biotechnology Information (NCBI). PubChem compound summary for CID 31347, sulfolane: Computed properties. Bethesda, MD: U.S. Department of Health and Human Services, National Institutes of Health, National Library of Medicine, National Center for Biotechnology Information; 2022. [Accessed: June 28, 2022]. https://pubchem.ncbi.nlm.nih.gov/compound/sulfolane#section=Computed-Properties
7 Kroschwitz JI, Seidel A. Kirk-Othmer encyclopedia of chemical technology. 5th ed. Hoboken, NJ: Wiley-Interscience; 2001. 10.1002/0471238961
8 Andersen ME, Jones RA, Kurlansik L, Mehl RG, Jenkins LJ Jr. Sulfolane-induced convulsions in rodents. Res Commun Chem Pathol Pharmacol. 1976; 15(3):571–580. 825938
9 Brown VKH, Ferrigan LW, Stevenson DE. Acute toxicity and skin irritant properties of sulfolane. Br J Ind Med. 1966; 23(4):302–304. 10.1136/oem.23.4.302 5926894
10 National Center for Biotechnology Information (NCBI). PubChem annotation record for sulfolane, source: Hazardous Substances Data Bank (HSDB). Bethesda, MD: U.S. Department of Health and Human Services, National Institutes of Health, National Library of Medicine, National Center for Biotechnology Information; 2011. HSDB No. 122. [Accessed: June 28, 2022]. https://pubchem.ncbi.nlm.nih.gov/source/hsdb/122
11 U.S. Environmental Protection Agency (USEPA). ChemView: CASRN 126-33-0: 2016 CDR data. Washington, DC: U.S. Environmental Protection Agency; 2016. [Accessed: June 27, 2022]. https://chemview.epa.gov/chemview
12 Greene EA, Fedorak PM. Nutrient stimulation of sulfolane biodegradation in a contaminated soil from a sour natural gas plant and in a pristine soil. Environ Technol. 2001; 22(6):619–629. 10.1080/09593332208618246 11482381
13 Leo T. Uptake and release kinetics of sulfolane by cattail plants [master's thesis]. Logan, UT: Utah State University; 2008. 10.26076/dd9f-d5d0
14 North Pole Utilities. Drinking water quality report. North Pole, AK: City Hall; 2015. [Accessed: June 27, 2022]. https://web.archive.org/web/20150908033354/https://www.northpolealaska.com/sites/default/files/fileattachments/utilities/page/565/water_quality_report_2015.pdf (https://web.archive.org/web/20150908033354/https:/www.northpolealaska.com/sites/default/files/fileattachments/utilities/page/565/water_quality_report_2015.pdf)
15 Alaska Department of Environmental Conservation (DEC). Sulfolane sampling of groundwater on North Pole Refinery for November 2010 through January 2011. Juneau, AK: Alaska Department of Environmental Conservation; 2011. [Accessed: January 25, 2023]. https://dec.alaska.gov/media/7283/2011-onsite-mw-jan.pdf
16 Alaska Department of Environmental Conservation (DEC). Sulfolane sampling of groundwater in off site locations for Nov 2010 through January 2011. Juneau, AK: Alaska Department of Environmental Conservation; 2011. [Accessed: January 25, 2023]. https://dec.alaska.gov/media/7285/2011jan-mon-wells-offsite.pdf
17 Canadian Council of Ministers of the Environment (CCME). Canadian environmental quality guidelines for sulfolane: Water and soil. Winnipeg, Manitoba: Canadian Council of Ministers of the Environment; 2006. [Accessed: January 25, 2023]. https://ccme.ca/en/res/2006-sulfolane-ceqg-ssd-1368-en.pdf
18 Oasis Environmental. Sulfolane technical assistance and evaluation report. Juneau, AK: Alaska Department of Environmental Conservation; 2010. [Accessed: January 25, 2023]. https://dec.alaska.gov/media/6169/sulfolane-tech-assist-report.pdf
19 Eberbach J. Threat of chemical contamination fuels neighbors' ire. Detroit, MI: Detroit Free Press; 2016. [Accessed: January 25, 2023]. https://www.freep.com/story/news/local/michigan/2016/06/28/merit-energy-sulfolane-contamination/86460292/
20 Warnica M. Alberta government admits it knew of earlier sulfolane leak. Toronto, ON: Canadian Broadcasting Corporation; 2014. [Accessed: January 25, 2023]. https://www.cbc.ca/news/canada/edmonton/alberta-government-admits-it-knew-of-earlier-sulfolane-leak-1.2633095
21 Zhu ZH, Sun ML, Li ZS, Yang ZC, Zhang TB, Heng ZC, Xiao BL, Li QY, Peng QY, Dong YH. [An investigation of the maximum allowable concentration of sulfolane in surface water]. Hua Xi Yi Ke da Xue Xue Bao. 1987; 18(4):376–380. 3449430
22 Agency for Toxic Substances and Disease Registry (ATSDR). Health consultation: Sulfolane. Atlanta, GA: U.S. Department of Health and Human Services, Public Health Service, Agency for Toxic Substances and Disease Registry; 2011. [Accessed: June 27, 2022]. https://ntp.niehs.nih.gov/ntp/noms/support_docs/atsdrsulfolanehc_2011_508.pdf
23 U.S. Environmental Protection Agency (USEPA). Provisional peer-reviewed toxicity values for sulfolane (CASRN 126-33-0). Cincinnati, OH: U.S. Environmental Protection Agency, Office of Research and Development, National Center for Environmental Assessment, Superfund Health Risk Technical Support Center; 2012. EPA Report No. EPA/690/R-12/024F. [Accessed: June 27, 2022]. https://cfpub.epa.gov/ncea/pprtv/documents/Sulfolane.pdf
24 Roberts JJ, Warwick GP. The mode of action of alkylating agents—III: The formation of 3-hydroxytetrahydrothiophene-1:1-dioxide from 1:4-dimethanesulphonyloxybutane (Myleran), S-β-L-alanyltetrahydrothiophenium mesylate, tetrahydro-thiophene and tetrahydrothiophene-1:1-dioxide in the rat, rabbit and mouse. Biochem Pharmacol. 1961; 6(4):217–227. 10.1016/0006-2952(61)90133-2
25 Andersen ME, Jones RA, Mehl RG, Hill TA, Kurlansik L, Jenkins LJ Jr. The inhalation toxicity of sulfolane (tetrahydrothiophene-1,1-dioxide). Toxicol Appl Pharmacol. 1977; 40(3):463–472. 10.1016/0041-008X(77)90073-4 407670
26 Organisation for Economic Co-operation and Development (OECD). SIDS initial assessment report for SIAM 19: Tetrahydrothiophene-1,1-dioxide. Paris, France: Organisation for Economic Co-operation and Development; 2004. [Accessed: June 27, 2022]. https://hpvchemicals.oecd.org/UI/handler.axd?id=cbde8e42-6a4f-4112-acf2-09ffcbcf210b
27 Ministry of Health and Welfare (MHW). [Twenty-eight-day repeat dose oral toxicity test of tetrahydrothiophene 1,1-dioxide in rats]. Tokyo, Japan: Ministry of Health and Welfare; 1996. [Accessed: January 25, 2023]. https://dra4.nihs.go.jp/mhlw_data/home/paper/paper126-33-0b.html
28 Huntingdon Life Sciences. Sulfolane toxicity study by oral administration via the drinking water to CD rats for 13 weeks, vol. 1 and 2. Sponsored by Shell Canada; 2001.
29 Ruppert PH, Dyer RS. Acute behavioral toxicity of sulfolane: Influence of hypothermia. Toxicol Lett. 1985; 28(2-3):111–116. 10.1016/0378-4274(85)90018-9 4071560
30 Dyer RS, Boyes WK, Hetzler BE. Acute sulfolane exposure produces temperature-independent and dependent changes in visual evoked potentials. Neurobehav Toxicol Teratol. 1986; 8(6):687–693. 3808184
31 Gordon CJ, Long MD, Dyer RS. Effect of ambient temperature on the hypometabolic and hypothermic effects of sulfolane in rats. Arch Toxicol. 1984; 56(2):123–127. 10.1007/BF00349084 6532377
32 Gordon CJ, Long MD, Fehlner KS, Dyer RS. Sulfolane-induced hypothermia enhances survivability in mice. Environ Res. 1986; 40(1):92–97. 10.1016/S0013-9351(86)80084-6 3709502
33 Ministry of Health and Welfare (MHW). [Preliminary reproduction toxicity screening test of tetrahydrothiophene-1,1-dioxide by oral administration in rats]. Tokyo, Japan: Ministry of Health and Welfare; 1999. [Accessed: January 25, 2023]. https://dra4.nihs.go.jp/mhlw_data/home/paper/paper126-33-0c.html
34 National Cancer Institute (NCI). Bioassay of 3-sulfolene for possible carcinogenicity. Bethesda, MD: U.S. Department of Health, Education, and Welfare, Public Health Service, National Institutes of Health, National Cancer Institute; 1978. DHEW Publication No. (NIH) 78-1352. National Cancer Institute Carcinogenesis Technical Report Series No. 102 (NCI-CG-TR-102). [Accessed: June 28, 2022]. https://ntp.niehs.nih.gov/publications/reports/tr/100s/tr102/index.html
35 Sigma-Aldrich. Product 88965 (Fluka), FTIR008848. [Accessed: June 27, 2022]. https://www.sigmaaldrich.com/
36 Sigma-Aldrich. Product 88965 (Fluka), FNMR011407. [Accessed: June 27, 2022]. https://www.sigmaaldrich.com/
37 National Institute of Advanced Industrial Science and Technology (AIST). Spectral Database for Organic Compounds: SDBS-749: Tetrahydrothiophene 1,1-dioxide. Tokyo, Japan: National Institute of Advanced Industrial Science and Technology; 1999. [Accessed: June 28, 2022]. https://sdbs.db.aist.go.jp/CompoundLanding.aspx?sdbsno=749
38 Wiley. Wiley registry: 8th edition/NIST 2005 mass spectral library. Hoboken, NJ: Wiley; 2006.
39 Silinski MAR, Uenoyama T, Cooper SD, Fernando RA, Robinson VG, Waidyanatha S. Development and validation of an analytical method for quantitation of sulfolane in rat and mouse plasma by GC-MS. J Anal Toxicol. 2019; 43(6):477–481. 10.1093/jat/bkz031 31044244
40 National Toxicology Program (NTP). Specifications for the conduct of studies to evaluate the toxic and carcinogenic potential of chemical, biological and physical agents in laboratory animals for the National Toxicology Program (NTP). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, National Toxicology Program; 2011.
41 Sills RC, Cesta MF, Willson CJ, Brix AE, Berridge BR. National Toxicology Program position statement on informed (“nonblinded”) analysis in toxicologic pathology evaluation. Toxicol Pathol. 2019; 47(7):887–890. 10.1177/0192623319873974 31522628
42 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
43 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
44 Brix AE, Hardisty JF, McConnell EE. Combining neoplasms for evaluation of rodent carcinogenesis studies. In: Hsu CH, Stedeford T, editors. Cancer Risk Assessment: Chemical Carcinogenesis, Hazard Evaluation, and Risk Quantification. Hoboken, NJ: Wiley; 2010. p. 699-715. 10.1002/9780470622728.ch28
45 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481. 10.1080/01621459.1958.10501452
46 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975; 62(3):679–690. 10.1093/biomet/62.3.679
47 Cox DR. Regression models and life‐tables. J R Stat Soc Series B Methodol. 1972; 34(2):187–202. 10.1111/j.2517-6161.1972.tb00899.x
48 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431. 10.2307/2531856 3390507
49 Piegorsch WW, Bailer AJ. Statistics for environmental biology and toxicology: Section 6.3.2. London, UK: Chapman and Hall; 1997.
50 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
51 Portier CJ, Hedges JC, Hoel DG. Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986; 46(9):4372–4378. 3731095
52 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. 10.2307/2532200 8241374
53 Nam JM. A simple approximation for calculating sample sizes for detecting linear trend in proportions. Biometrics. 1987; 43(3):701–705. 10.2307/2532006 3663825
54 Rao JNK, Scott AJ. A simple method for the analysis of clustered binary data. Biometrics. 1992; 48(2):577–585. 10.2307/2532311 1637980
55 Fung KY, Krewski D, Rao JNK, Scott AJ. Tests for trend in developmental toxicity experiments with correlated binary data. Risk Anal. 1994; 14(4):639–648. 10.1111/j.1539-6924.1994.tb00277.x 7972964
56 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 10.1093/jnci/62.4.957 285297
57 Dixon WJ, Massey FJ. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw-Hill; 1957.
58 Tukey JW. Easy summaries--numerical and graphical. In: Exploratory Data Analysis. Reading, MA: Addison-Wesley; 1977. p. 27-56.
59 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
60 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
61 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
62 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
63 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
64 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
65 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. 10.1093/biomet/41.1-2.133
66 Hsu JC. The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992; 1(2):151–168. 10.1080/10618600.1992.10477011
67 Haseman JK. Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992; 26(2):191–200. 10.1177/009286159202600210
68 Haseman JK, Rao GN. Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992; 20(1):52–60. 10.1177/019262339202000107 1411131
69 Haseman JK. Data analysis: Statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995; 21(1):52–59. 10.1006/rtph.1995.1009 7784636
70 U.S. Food and Drug Administration (FDA). 21 CFR Part 58. https://www.ecfr.gov/current/title-21/chapter-I/subchapter-A/part-58
71 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605-627.
72 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981; 67(2):233–241. 10.1093/jnci/67.2.233 7021938
73 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Flamm WG, Lorentzen RJ, editors. Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing; 1985. p. 13-59.
74 Schmid W. The micronucleus test. Mutat Res. 1975; 31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
75 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity: A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983; 123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
76 Shelby MD, Erexson GL, Hook GJ, Tice RR. Evaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ Mol Mutagen. 1993; 21(2):160–179. 10.1002/em.2850210210 8444144
77 Shelby MD, Witt KL. Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995; 25(4):302–313. 10.1002/em.2850250407 7607185
78 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F(1) mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163-194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P 11044899
79 National Toxicology Program (NTP). TR-605: Pathology tables, survival and growth curves from NTP long term studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2026. 10.22427/NTP-DATA-TR-605
80 National Toxicology Program (NTP). NTP historical controls report: All routes and vehicles: Harlan Sprague-Dawley rats. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2022. [Accessed: August 11, 2025]. https://ntp.niehs.nih.gov/sites/default/files/2023-06/r_hcrpt_allrte20221000.pdf
81 Cohen SM, Storer RD, Criswell KA, Doerrer NG, Dellarco VL, Pegg DG, Wojcinski ZW, Malarkey DE, Jacobs AC, Klaunig JE, et al. Hemangiosarcoma in rodents: Mode-of-action evaluation and human relevance. Toxicol Sci. 2009; 111(1):4–18. 10.1093/toxsci/kfp131 19525443
82 National Toxicology Program (NTP). Organ sites with neoplasia. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2023. [Accessed: May 24, 2023]. https://cebs.niehs.nih.gov/organsites/
83 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis studies of 1,3-butadiene (CAS No. 106-99-0) in B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, National Toxicology Program; 1993. NTP Technical Report No. 434. NIH Publication No. 93-3165. [Accessed: January 25, 2023]. https://ntp.niehs.nih.gov/go/tr434abs
84 Parshley L. The pollution plumes of North Pole. Bozeman, MT: Environmental Health News; 2021. [Accessed: January 25, 2023]. https://www.ehn.org/north-pole-alaska-pollution-2651333766.html
85 Thompson CM, Gaylor DW, Tachovsky JA, Perry C, Carakostas MC, Haws LC. Development of a chronic noncancer oral reference dose and drinking water screening level for sulfolane using benchmark dose modeling. J Appl Toxicol. 2013; 33(12):1395–1406. 10.1002/jat.2799 22936336
86 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
87 Dertinger SD, Camphausen K, MacGregor JT, Bishop ME, Torous DK, Avlasevich S, Cairns S, Tometsko CR, Menard C, Muanza T, et al. Three‐color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutagen. 2004; 44(5):427–435. 10.1002/em.20075 15517570
88 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117