# Conclusions

Under the conditions of these 2-year drinking water studies, there was no evidence of carcinogenic activity of sulfolane in male Hsd:Sprague Dawley^®^ SD^®^ rats at exposure concentrations of 30, 100, 300, or 1,000 mg/L. There was equivocal evidence of carcinogenic activity of sulfolane in female Hsd:Sprague Dawley^®^ SD^®^ rats based on the increased incidence of mammary gland adenoma.

There was clear evidence of carcinogenic activity of sulfolane in male B6C3F1/N mice based on the increased incidence of hemangiosarcoma (all organs), which predominately occurred in the liver. There was equivocal evidence of carcinogenic activity of sulfolane in female B6C3F1/N mice based on the increased incidence of hepatocellular carcinoma.

Exposure to sulfolane resulted in increased incidences of nonneoplastic lesions of the liver in male and female mice and the ovary in female mice. Sulfolane exposure also induced a delay in vaginal opening in female rats.