# Discussion

Sulfolane was nominated for study because of exposure concerns for residents surrounding a refinery in North Pole, Alaska. Because of likely long-term exposure and the presence of sulfolane around other similar refineries, these 2-year carcinogenicity studies in rats and mice were conducted. Drinking water was selected as the route of exposure, with 1,000 mg/L as the highest exposure concentration, on the basis of previously published National Toxicology Program (NTP) studies and the literature. The design of this study included several evaluations of potential developmental toxicity in rats and interim evaluations in both rats and mice, including measurements of internal exposure.

Marginal effects were observed following sulfolane exposure during gestation and lactation. Reduced male and female pup weights (up to 11%) in the 1,000 mg/L groups compared to control rats was the only exposure-related finding. This observation is consistent with the OECD 421 study,^26,33^ as maternal exposures of 200 mg/kg/day showed minimal effects. Sulfolane intake in the current study was 126 mg/kg/day during gestation (gestational day [GD] 6–21) and 206 mg/kg/day during lactation (lactational day [LD] 1–14). Vaginal opening was delayed in the 300 and 1,000 mg/L F_1_ female rats, with and without adjustment for body weight at weaning. This observation is suggestive of sulfolane inducing a developmental delay in female rats at these exposure concentrations in a developmental endpoint that has not been evaluated in other sulfolane studies.

The interim evaluation in rats and mice at 3 months showed marginal effects in male rats, with reduced body weights that were <10% different from control values. Clinical chemistry (rats only), hematology, and organ weights were unaffected by sulfolane exposure in rats and mice. In female rats, no effects were observed in lymphocyte counts, whereas a significant decrease in lymphocyte counts was previously observed in female rats exposed to >100 mg/L sulfolane in another 3-month drinking water study.^28^ Although this observation is inconsistent with the Huntingdon Life Sciences (HLS) 2001 drinking water study, marginal to no exposure-related effects on white blood cell counts were observed in other studies within the NTP research program on sulfolane, including in studies that evaluated multiple species after 28 days of exposure to sulfolane^4^ or in immunotoxicity studies of sulfolane.^5^ The reason for this is unclear. Additionally, no exposure-related nonneoplastic lesions in immune tissues were observed in these 3-month interim or 2-year studies.

Kidney pathological observations in previous studies on male rats included hyaline droplet accumulation and/or cortical tubular basophilia and granular casts in multiple exposure groups^4,28^; however, no exposure-related effects in the kidney were observed in this study at the interim or 2-year evaluations. Hyaline droplet accumulation in the NTP 28-day gavage study was significantly increased in all exposed groups (1–800 mg/kg/day), while similar increases were only observed in the higher exposed groups of 400 and 1,600 mg/L (35.0 and 131.7 mg/kg/day, respectively) in the HLS drinking water study. This suggests that the method of administration (e.g., drinking water versus gavage) influences these kidney lesions, likely because of absorption, distribution, metabolism, and exposure (ADME) differences. It is not clear why there was a lack of these findings in the current studies, as chemical intake from weaning to the 3-month interim evaluation (postnatal day [PND] 28–119) averaged 80 mg/kg/day in the 1,000 mg/L male rats, which was within the range of the higher exposure (1,600 mg/L) in the HLS 13-week study. It is possible the difference in findings was due to sensitivity differences between Charles River CD and Hsd Sprague Dawley rats at lower exposure concentrations. Other histopathological findings in the NTP 28-day gavage study that were not observed in the current study were most likely due to the higher doses used in the 28-day study and administration differences (gavage versus drinking water).

In male and female rats, chemical intake (mg/kg/day) increased in proportion to drinking water concentration (mg/L) with consistent sex differences (i.e., increased intake in females in comparison to males) typically found in drinking water studies. However, sulfolane plasma concentrations measured at the 3-month interim timepoint were consistent between the sexes and metabolic saturation occurred at higher exposures. In mice, chemical intake was generally similar between the sexes at 3 months, whereas plasma concentrations were higher in females in the 300 and 1,000 mg/mL groups compared to respective males. Metabolic saturation was evident in females starting at 300 mg/L, but metabolic saturation was not evident in males. When comparing plasma concentrations between this drinking water study and the NTP 28-day toxicity study (gavage),^4^ concentrations in male and female rats exposed to 30 or 100 mg/kg/day sulfolane were 4–9 times higher in the 28-day study (2 hours after the last dose) compared to the 300 and 1,000 mg/L interim data in the current study. Similarly, concentrations in mice exposed to 30 and 100 mg/kg/day sulfolane were 5–9 times higher at the 2-hour time point in the 28-day toxicity study compared to the 300 and 1,000 mg/L concentrations in this study. An exception was the ratio between the 1,000 mg/L male mice in this study and the 100 mg/kg/day male mice in the 28-day study, which showed a considerably higher difference (134×). Previous studies showed evidence of saturation in both male and female mice,^2,4^ but there was no evidence of saturation in male mice in this study, which could be due to differences in the method of administration (drinking water versus gavage) for this sex and species.

In the chronic portion of the rat study, survival was unaffected, while body weights were significantly decreased in male and female rats compared to their respective control groups (up to 11% and 16% in males and females, respectively, in the 1,000 mg/L group). In female rats, the incidence of mammary gland adenoma in the exposed groups was higher than the control group incidence and a significant increase was observed in female rats exposed to 100 mg/L sulfolane, which was outside the historical control range (14% versus 0%–9%). Although not significant, the incidence in the 1,000 mg/L group (10%) also exceeded the historical control range. However, there was no corresponding increase in nonneoplastic lesions or adenocarcinoma within the mammary gland. Given that the statistical significance occurred in a mid-exposure group only, and no increase in corresponding nonneoplastic lesions was observed, the increase in the incidence of mammary gland adenoma was considered equivocal evidence of carcinogenic activity. There was no evidence of carcinogenicity in male rats.

In mice, survival and body weights were not affected by sulfolane exposure. In female mice, the incidence of follicle cysts of the ovary was significantly increased in the 30, 300, and 1,000 mg/L groups. However, the toxicological significance of this lesion is unknown, this finding was not observed in rats, and no other findings in male and female reproductive tissues or estrous cyclicity effects were observed. In male mice, there was a positive trend and significant increase in the incidences of hemangiosarcomas of all organs (systemic) and of the liver in the 1,000 mg/L group compared to the concurrent control group, and the incidence rate was outside the historical control range for all organs (24% versus 2%–10%) and for the liver (22% versus 0%–6%). The incidences of hemangiomas of all organs (systemic) or individual organs was not increased in the exposed groups compared to the concurrent control group, aside from a positive trend observed in the spleen. The combined incidence of hemangioma and hemangiosarcoma of all organs, due to the increase in hemangiosarcoma, was also significantly increased in the 1,000 mg/L group, with a positive trend, and was also well outside the historical range (28% versus 3%–12%). Taken together, the increase in hemangiosarcoma supported clear evidence of carcinogenic activity in male mice.

Hemangiosarcomas are more common in mice than in rats and humans.^81^ Using NTP’s “Organ Sites with Neoplasia” database, 31 chemicals have been found to be positive (“positive,” “clear,” “some”) for hemangiosarcoma or hemangioma and hemangiosarcoma. Of these, 28 were positive in mice, 8 were positive in rats, and 5 were positive in both mice and rats.^82^ In a review by Cohen et al.,^81^ genotoxicity and/or nongenotoxic pathways are suggested as possible mechanisms of action. The relevance and mechanism for inducing these tumors varies with genotoxic chemicals inducing hemangiosarcomas in humans (e.g., vinyl chloride, vinyl bromide, and thorotrast), whereas there is more uncertainty with human relevance for the non-genotoxic pathway. In the current study, there was no evidence for genotoxicity by sulfolane exposure. Most of the hemangiosarcomas in the 1,000 mg/L group occurred in the liver, a common site for this neoplasm. 1,3-Butadiene exposure, which can be used as a precursor in sulfolane production, has been found to increase the incidence of hemangiosarcoma within the heart in male and female mice.^83^ In this study, there was no evidence of 1,3-butadiene contamination in the sulfolane analysis, and no increase in the incidence of hemangiosarcoma in the heart in male or female mice. Although the mechanism is unknown, the finding of an increased incidence of hemangiosarcoma was considered clear evidence of carcinogenic activity in male mice after sulfolane exposure.

A significant increase in the incidence of hepatocellular carcinoma was observed in the highest exposure group in female mice. The incidence (16%) marginally exceeded the historical control range (2%–14%), whereas there was no change in hepatocellular adenoma or preneoplastic lesions relative to control animals. The combined incidence of hepatocellular adenoma and carcinoma was not increased by pairwise comparison to the control group, but there was a positive trend. Taken together, the increase in incidences of hepatocellular carcinoma was considered to be equivocal evidence of carcinogenic activity due to no increase in the incidences of preneoplastic lesions, hepatocellular adenoma, or adenoma or carcinoma (combined) compared to the concurrent control.

Exposure concentrations within this study were higher than has been measured in drinking water wells, which were as high as approximately 100–400 ppb (100–400 µg/L) onsite or offsite the refinery.^15,16,84^ Previously, a chronic reference dose of 10 µg/kg/day was calculated, which was based on the finding of reduced leukocytes within female rats following a 90-day drinking water exposure^28^ and for which a drinking water screening level of 365 ppb was derived.^85^ The data presented here provide context for potential chronic toxicity and carcinogenic activity to support the risk assessment of sulfolane exposures in the general public and for potentially higher worksite exposures.