# Results

## Data Availability

All study data were evaluated. Data relevant for evaluating toxicological findings are presented here. All study data are available in the National Toxicology Program (NTP) Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-605.^79^

## Rats

### Two-year Study (Perinatal Phase)

No effects related to sulfolane exposure were observed for pregnancy status, maternal survival, gestation length, or number of dams that littered (Table 2).

Table 2 Summary of the Disposition of F_0_ Female Rats during Perinatal Exposure and F_1_ Allocation in the Perinatal and Two-year Drinking Water Study of Sulfolane

| 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
Reproductive Performance
Time-mated Females (GD 6) | 53 | 43 | 43 | 43 | 43
Females Pregnant (%)^a^ | 41 (77.4) | 33 (76.7) | 35 (81.4) | 37 (86.0) | 38 (88.4)
Females Not Pregnant (%) | 12 (22.6) | 10 (23.3) | 8 (18.6) | 6 (14.0) | 5 (11.6)
Pregnant Females Removed Prior to Littering (%) | 0 | 0 | 0 | 1 (2.7) | 0
Dams with Litters on LD 0 (%)^a,b^ | 38 (92.7) | 31 (93.9) | 33 (94.3) | 35 (97.2) | 34 (89.5)
Gestation Length (Days)^c,d^ | 22.2 ± 0.1 (38) | 22.3 ± 0.1 (31) | 22.2 ± 0.1 (33) | 22.1 ± 0.1 (35) | 22.1 ± 0.1 (34)
Litters Poststandardization (PND 4)^e^ | 38 | 31 | 32 | 34 | 34
F_1_ Males/Females (PND 28)^f^ | 142/143 | 125/122 | 121/117 | 139/129 | 135/132
Postweaning Allocation
F_1_ Males – Chronic (Litters)^g^ | 50 (27) | 50 (25) | 50 (26) | 50 (25) | 50 (26)
F_1_ Males – Interim (Litters)^h^ | 10 (10) | 10 (10) | 10 (10) | 10 (10) | 10 (10)
F_1_ males – internal concentration assessment (litters)^i^ | 5 (5) | 5 (5) | 5 (5) | 5 (5) | 5 (5)
F_1_ Females – Chronic (Litters)^g^ | 50 (27) | 50 (25) | 50 (26) | 50 (26) | 50 (26)
F_1_ Females – Interim (Litters)^h^ | 10 (10) | 10 (10) | 10 (10) | 10 (10) | 10 (10)
F_1_ females – internal concentration assessment (litters)^i^ | 5 (5) | 5 (5) | 5 (5) | 5 (5) | 5 (5)

GD = gestation day; LD = lactation day; PND = postnatal day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests. No statistically significant findings were noted at p ≤ 0.05.

^b^ Percentage is given as a portion of pregnant dams surviving to littering date.

^c^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests. No statistically significant findings were noted at p ≤ 0.05.

^d^ Gestation length calculated for sperm-positive females that delivered a litter. Data are presented as mean ± standard error (number of dams).

^e^ Standardization to eight pups/litter (four pups/sex).

^f^ Number of males/females surviving until weaning on PND 28.

^g^ Total number of F_1_ rats included in the 2-year study (number of litters from which they originated).

^h^ Number of F_1_ rats included in the 3-month interim evaluation (number of litters from which they originated).

^i^ Number of F_1_ 3-month interim evaluation rats selected for internal concentration assessment (number of litters from which they originated).

Although there were negative trends for dam body weights at some time points during gestation, the body weights of exposed groups remained within 5% of control group values. During lactation, dam body weights were significantly decreased in the 1,000 mg/L group compared to the control group, but these effects were also considered marginal, as weights were within 5% of control group values (Table 3).

Table 3 Summary of Body Weights and Body Weight Gains of F_0_ Female Rats during Gestation and Lactation in the Perinatal and Two-year Drinking Water Study of Sulfolane

Parameter^a,b^ | 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
Gestation Body Weight
Gestation Day
6 | 237.9 ± 2.1 (41) | 236.6 ± 1.8 (33) | 235.0 ± 1.9 (35) | 234.8 ± 1.9 (37) | 236.1 ± 2.0 (38)
9 | 249.8 ± 2.1* (41) | 249.1 ± 1.7 (33) | 247.7 ± 1.9 (35) | 246.0 ± 2.1 (37) | 243.7 ± 1.9 (38)
12 | 263.4 ± 2.2* (41) | 263.2 ± 1.9 (33) | 261.9 ± 2.3 (35) | 259.8 ± 2.2 (37) | 258.1 ± 2.1 (38)
15 | 281.0 ± 2.3* (41) | 282.0 ± 2.1 (33) | 279.4 ± 2.6 (35) | 278.3 ± 2.6 (37) | 274.0 ± 2.4 (38)
18 | 316.6 ± 3.2 (41) | 319.9 ± 3.2 (33) | 315.7 ± 3.8 (35) | 317.1 ± 3.6 (37) | 308.5 ± 3.5 (38)
21 | 357.8 ± 4.5* (41) | 364.9 ± 4.8 (33) | 355.3 ± 5.8 (35) | 358.4 ± 5.8 (37) | 344.1 ± 5.3 (38)
Gestation Weight Change
Gestation Day Interval
6–9 | 11.9 ± 0.6** (41) | 12.4 ± 0.8 (33) | 12.7 ± 0.5 (35) | 11.2 ± 0.5 (37) | 7.6 ± 1.0** (38)
9–12 | 13.5 ± 0.6 (41) | 14.1 ± 0.6 (33) | 14.2 ± 0.7 (35) | 13.8 ± 0.6 (37) | 14.4 ± 1.0 (38)
12–15 | 17.6 ± 0.7 (41) | 18.8 ± 1.0 (33) | 17.5 ± 0.8 (35) | 18.5 ± 0.7 (37) | 15.9 ± 0.9 (38)
15–18 | 35.7 ± 1.6 (41) | 37.9 ± 1.7 (33) | 36.3 ± 1.9 (35) | 38.8 ± 1.8 (37) | 34.5 ± 1.8 (38)
18–21 | 41.2 ± 1.9 (41) | 45.0 ± 2.0 (33) | 39.6 ± 2.4 (35) | 41.2 ± 3.3 (37) | 35.6 ± 3.0 (38)
6–21 | 119.9 ± 4.2* (41) | 128.2 ± 4.8 (33) | 120.3 ± 5.2 (35) | 123.5 ± 5.0 (37) | 108.0 ± 5.2 (38)
Lactation Body Weight
Lactation Day
1 | 272.2 ± 3.0** (38) | 272.1 ± 2.8 (31) | 273.7 ± 2.6 (33) | 267.5 ± 3.0 (34) | 260.3 ± 2.6** (34)
4 | 284.3 ± 2.6** (38) | 283.4 ± 2.4 (31) | 283.2 ± 2.5 (32)^c^ | 280.7 ± 2.7 (34) | 272.4 ± 2.7** (34)
7 | 293.2 ± 2.4** (38) | 292.1 ± 2.3 (31) | 288.4 ± 2.6 (32) | 289.0 ± 2.9 (34) | 282.6 ± 2.5** (34)
10 | 303.7 ± 2.7* (38) | 303.7 ± 2.4 (31) | 301.9 ± 2.9 (31)^c^ | 302.1 ± 3.0 (34) | 293.1 ± 2.8* (34)
14 | 310.4 ± 2.6** (38) | 306.6 ± 2.3 (31) | 308.9 ± 2.7 (31) | 307.3 ± 2.7 (34) | 299.4 ± 2.6** (34)
17 | 306.8 ± 2.6 (38) | 304.4 ± 2.4 (30)^d^ | 305.6 ± 2.6 (30)^d^ | 306.2 ± 3.0 (34) | 300.8 ± 2.8 (34)
21 | 298.1 ± 2.5* (38) | 294.2 ± 2.4 (31) | 295.5 ± 2.7 (31) | 295.4 ± 2.5 (34) | 288.7 ± 2.4* (34)
24 | 288.2 ± 2.5 (38) | 287.1 ± 2.7 (31) | 286.3 ± 2.6 (31) | 286.1 ± 2.7 (34) | 282.9 ± 2.4 (34)
28 | 278.9 ± 2.4 (38) | 277.6 ± 2.5 (31) | 275.2 ± 2.8 (31) | 277.2 ± 2.4 (34) | 274.5 ± 1.9 (34)
Lactation Weight Change
Lactation Day Interval
1–4 | 12.1 ± 1.2 (38) | 11.3 ± 1.6 (31) | 9.5 ± 1.2 (32) | 13.2 ± 1.1 (34) | 12.2 ± 1.9 (34)
4–7 | 8.9 ± 1.1 (38) | 8.7 ± 1.3 (31) | 5.2 ± 1.4 (32) | 8.3 ± 1.3 (34) | 10.2 ± 1.8 (34)
7–10 | 10.4 ± 1.2 (38) | 11.6 ± 1.3 (31) | 13.6 ± 1.8 (31) | 13.1 ± 1.6 (34) | 10.5 ± 1.6 (34)
10–14 | 6.8 ± 1.4 (38) | 2.8 ± 1.7 (31) | 7.0 ± 2.0 (31) | 5.2 ± 1.8 (34) | 6.3 ± 2.1 (34)
14–17 | −3.6 ± 1.5 (38) | −1.6 ± 1.5 (30) | −3.0 ± 1.8 (30) | −1.2 ± 1.9 (34) | 1.3 ± 1.7 (34)
17–21 | −8.7 ± 1.7 (38) | −10.4 ± 1.8 (30) | −10.6 ± 2.0 (30) | −10.8 ± 1.7 (34) | −12.1 ± 1.7 (34)
21–24 | −9.9 ± 1.5 (38) | −7.1 ± 1.4 (31) | −9.2 ± 1.3 (31) | −9.3 ± 1.2 (34) | −5.7 ± 1.3 (34)
24–28 | −9.2 ± 1.3 (38) | −9.4 ± 1.3 (31) | −11.1 ± 1.2 (31) | −8.9 ± 1.6 (34) | −8.5 ± 1.5 (34)
1–28 | 6.8 ± 2.4** (38) | 5.6 ± 2.3 (31) | 1.4 ± 2.2 (31) | 9.7 ± 1.9 (34) | 14.2 ± 2.2* (34)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error (number of dams). Body weight data are presented in grams.

^b^ Each exposed group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^c^ One dam in the 100 mg/L group was removed from analysis on lactation day (LD) 7 and one on LD 11 due to whole litter loss, which occurred on LD 4 and LD 10, respectively.

^d^ One F_0_ LD 17 body weight in each of the 30 mg/L and 100 mg/L groups were excluded as outliers.

Water consumption (g water/kg body weight/day) during gestation was unaffected by sulfolane exposure (Table 4). Average gestational chemical intake was calculated from GD 6–21, and chemical intake generally increased in proportion to exposure concentration. During lactation, water consumption (g/kg/day) from lactation day (LD) 1 through LD 14 was significantly increased (7%–11%) in the exposed groups compared to the control group (Table 4). This result was largely due to significant increases in water consumption that occurred from LD 10 through LD 14. Average lactational chemical intake was calculated from LD 1 through LD 14, and chemical intake generally increased in proportion to exposure concentration.

Table 4 Summary of Water and Sulfolane Consumption by F_0_ Female Rats during Gestation and Lactation in the Perinatal and Two-year Drinking Water Study

Parameter^a^ | 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
Gestation Day Interval (g/kg/day)^b^
6–9 | 113.2 ± 2.5 (41) | 116.8 ± 2.6 (33) | 115.4 ± 2.1 (35) | 113.8 ± 2.2 (37) | 115.2 ± 2.9 (38)
9–12 | 123.4 ± 3.8* (41) | 125.5 ± 2.7 (33) | 125.3 ± 2.8 (35) | 126.8 ± 4.0 (37) | 129.9 ± 3.0 (38)
12–15 | 118.5 ± 2.2 (41) | 122.1 ± 2.5 (33) | 121.1 ± 3.3 (35) | 121.5 ± 2.5 (37) | 121.8 ± 2.8 (38)
15–18 | 133.1 ± 2.5 (41) | 136.8 ± 3.2 (33) | 132.7 ± 2.7 (34) | 136.1 ± 2.5 (37) | 141.3 ± 3.3 (38)
18–21 | 116.5 ± 2.4 (41) | 118.1 ± 3.1 (33) | 118.4 ± 4.0 (35) | 117.1 ± 2.2 (37) | 126.1 ± 4.4 (37)
6–21 | 119.7 ± 2.2 (41) | 122.5 ± 2.4 (33) | 121.9 ± 2.7 (35) | 121.8 ± 1.9 (37) | 126.0 ± 2.6 (38)
Lactation Day Interval (g/kg/day)^b^
1–4 | 164.4 ± 8.7** (38) | 175.6 ± 10.3 (31) | 177.1 ± 13.8 (32) | 166.6 ± 3.3 (34) | 172.9 ± 3.5** (34)
4–7 | 168.2 ± 4.1 (38) | 176.0 ± 3.2 (31) | 167.9 ± 4.3 (32) | 170.2 ± 2.9 (34) | 178.1 ± 3.0 (33)
7–10 | 191.3 ± 4.4 (38) | 211.8 ± 3.7* (30) | 201.2 ± 6.2 (32) | 209.5 ± 3.8 (34) | 208.0 ± 4.6 (34)
10–14 | 206.5 ± 5.7** (38) | 224.9 ± 4.3* (30) | 230.5 ± 6.2** (31) | 227.1 ± 3.6** (34) | 241.8 ± 9.5** (34)
1–14 | 186.0 ± 4.2** (38) | 200.1 ± 3.8* (31) | 201.0 ± 5.4** (31) | 198.1 ± 2.6** (34) | 205.6 ± 4.4** (34)
Chemical Intake (mg/kg/day)^c,d^
GD 6–21 | 0.0 ± 0.0 (41) | 3.7 ± 0.1 (33) | 12.2 ± 0.3 (35) | 36.5 ± 0.6 (37) | 126.0 ± 2.6 (38)
LD 1–14 | 0.0 ± 0.0 (38) | 6.0 ± 0.1 (31) | 20.1 ± 0.5 (31) | 59.4 ± 0.8 (34) | 205.6 ± 4.4 (34)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; LD = lactation day.

^a^ Data are presented as mean ± standard error (number of dams).

^b^ Each exposed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^c^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^d^ No statistical analysis performed on the chemical intake data.

Litter size both prestandardization on postnatal day (PND) 4 and poststandardization was not affected by sulfolane exposure; pup survival was also not affected (Table 5).

Table 5 Summary of Litter Size and Survival Ratio of F_1_ Male and Female Rats during Lactation in the Perinatal and Two-year Drinking Water Study of Sulfolane

Postnatal Day | 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
Total Litter Size^a,b^
0 | 11.6 ± 0.6 (38) | 13.2 ± 0.4 (31) | 11.6 ± 0.7 (33) | 12.4 ± 0.5 (35) | 12.8 ± 0.5 (34)
Live Litter Size^a,b^
0 | 11.3 ± 0.6 (38) | 12.8 ± 0.4 (31) | 11.3 ± 0.6 (33) | 12.6 ± 0.4 (34)^c^ | 12.4 ± 0.5 (34)
1 | 11.1 ± 0.6 (38) | 12.8 ± 0.4 (31) | 11.2 ± 0.6 (33) | 12.5 ± 0.4 (34) | 12.4 ± 0.5 (34)
4 (Prestandardization) | 11.1 ± 0.6 (38) | 12.7 ± 0.4 (31) | 11.5 ± 0.6 (32)^d^ | 12.4 ± 0.4 (34) | 12.3 ± 0.5 (34)
4 (Poststandardization) | 7.5 ± 0.2 (38) | 8.0 ± 0.0 (31) | 7.5 ± 0.3 (32) | 7.9 ± 0.1 (34) | 7.9 ± 0.1 (34)
7 | 7.5 ± 0.2 (38) | 8.0 ± 0.0 (31) | 7.5 ± 0.3 (32) | 7.9 ± 0.1 (34) | 7.9 ± 0.1 (34)
10 | 7.5 ± 0.2 (38) | 8.0 ± 0.0 (31) | 7.7 ± 0.2 (31)^d^ | 7.9 ± 0.1 (34) | 7.9 ± 0.1 (34)
14 | 7.5 ± 0.2 (38) | 8.0 ± 0.0 (31) | 7.7 ± 0.2 (31) | 7.9 ± 0.1 (34) | 7.9 ± 0.1 (34)
17 | 7.5 ± 0.2 (38) | 8.0 ± 0.0 (31) | 7.7 ± 0.2 (31) | 7.9 ± 0.1 (34) | 7.9 ± 0.1 (34)
21 | 7.5 ± 0.2 (38) | 8.0 ± 0.0 (31) | 7.7 ± 0.2 (31) | 7.9 ± 0.1 (34) | 7.9 ± 0.1 (34)
28 | 7.5 ± 0.2 (38) | 8.0 ± 0.0 (31) | 7.7 ± 0.2 (31) | 7.9 ± 0.1 (34) | 7.9 ± 0.1 (34)
% Live Male per Litter^a,b,e^
0 | 51.59 ± 3.26 (38) | 52.51 ± 2.4 (31) | 53.14 ± 3.02 (33) | 52.1 ± 2.84 (34) | 53.44 ± 2.57 (34)
No. of Dead Pups (Litters)^f,g^
0 | 10 (8) | 10 (8) | 10 (7) | 6 (5) | 12 (8)
1–4 | 8 (4) | 3 (3) | 4 (3) | 6 (6) | 6 (5)
5–28 | 0 (0) | 1 (1) | 3 (3) | 1 (1) | 1 (1)
Dead per Litter^a,b^
0 | 0.26 ± 0.09 (38) | 0.32 ± 0.11 (31) | 0.30 ± 0.12 (33) | 0.17 ± 0.08 (35) | 0.35 ± 0.13 (34)
1–4 | 0.21 ± 0.14 (38) | 0.10 ± 0.05 (31) | 0.12 ± 0.07 (33) | 0.18 ± 0.07 (34) | 0.18 ± 0.08 (34)
5–28 | 0.00 ± 0.00 (38) | 0.03 ± 0.03 (31) | 0.09 ± 0.05 (32) | 0.03 ± 0.03 (34) | 0.03 ± 0.03 (34)
Survival Ratio^a,b^
0^h^ | 0.98 ± 0.01 (38) | 0.98 ± 0.01 (31) | 0.98 ± 0.01 (33) | 0.96 ± 0.03 (35) | 0.97 ± 0.01 (34)
1–4^i^ | 0.98 ± 0.01 (38) | 0.99 ± 0.00 (31) | 0.96 ± 0.03 (33) | 0.99 ± 0.00 (34) | 0.99 ± 0.01 (34)
5–28^j^ | 1.00 ± 0.00 (38) | 1.00 ± 0.00 (31) | 0.95 ± 0.03 (32) | 1.00 ± 0.00 (34) | 1.00 ± 0.00 (34)

^a^ Data are presented as mean ± standard error (number of litters).

^b^ Each exposed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present. No statistically significant findings were noted at p ≤ 0.05.

^c^ One dam in the 300 mg/L group was removed due to whole litter loss on lactation day (LD) 9 due to whole litter loss, which occurred on LD 0.

^d^ One dam in the 100 mg/L group was removed from analysis on LD 7 and one on LD 11 due to whole litter loss, which occurred on LD 4 and LD 10, respectively.

^e^ 100 × [number of live males in exposure group]/[number of live males and females in exposure group](number of pups).

^f^ Total number of dead pups in exposure group (number of litters contributing dead pups).

^g^ No statistical analysis performed on this endpoint.

^h^ Survival per litter: Number of pups on postnatal day (PND) 0/total number of pups upon completion of parturition.

^i^ Survival per litter: Number of pups prestandardization on PND 4/total live pups on PND 0.

^j^ Survival per litter: Number of live pups on PND 28/number of live pups poststandardization on PND 4.

Male and female pup body weights were significantly decreased in the 1,000 mg/L groups relative to the control groups at all time points during lactation. Male pup body weights were 6%–9% lower, and female pup body weights were 5%–11% lower compared to the respective control groups, with the greatest difference occurring on PND 10 for both sexes (Table 6).

Table 6 Summary of Preweaning F_1_ Male and Female Rat Pup Body Weights Following Perinatal Exposure to Sulfolane

Postnatal Day^a,b^ | 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
Male
1^c^ | 7.16 ± 0.07** (216/38) | 7.16 ± 0.10 (207/31) | 6.99 ± 0.12 (199/32) | 7.04 ± 0.07 (220/34) | 6.74 ± 0.08** (222/34)
4^c,d^ | 10.58 ± 0.15** (215/38) | 10.52 ± 0.16 (206/31) | 10.13 ± 0.28 (197/32) | 10.48 ± 0.13 (219/34) | 9.86 ± 0.13* (220/34)
7^e^ | 16.80 ± 0.29* (142/38) | 16.26 ± 0.33 (126/31) | 15.88 ± 0.60 (122/32) | 16.17 ± 0.27 (139/34) | 15.41 ± 0.28* (135/34)
10^e^ | 23.99 ± 0.34** (142/38) | 23.35 ± 0.41 (126/31) | 23.18 ± 0.41 (121/31) | 23.19 ± 0.37 (139/34) | 21.76 ± 0.36** (135/34)
14^e^ | 33.57 ± 0.41** (142/38) | 32.90 ± 0.50 (125/31) | 32.85 ± 0.47 (121/31) | 32.87 ± 0.45 (139/34) | 31.22 ± 0.45** (135/34)
17^e^ | 40.47 ± 0.49** (142/38) | 39.18 ± 0.58 (125/31) | 39.40 ± 0.57 (121/31) | 39.90 ± 0.51 (139/34) | 38.07 ± 0.55** (135/34)
21^e^ | 55.30 ± 0.71** (142/38) | 53.66 ± 0.78 (125/31) | 53.28 ± 0.91 (121/31) | 54.48 ± 0.73 (139/34) | 51.89 ± 0.74** (135/34)
24^e^ | 68.77 ± 0.81** (142/38) | 66.90 ± 0.95 (125/31) | 66.87 ± 0.90 (121/31) | 68.22 ± 0.89 (139/34) | 64.64 ± 0.83** (135/34)
28^e^ | 87.91 ± 0.97** (142/38) | 86.80 ± 1.30 (125/31) | 86.51 ± 1.33 (121/31) | 87.04 ± 1.13 (139/34) | 82.54 ± 1.11** (135/34)
Female
1 | 6.85 ± 0.08** (206/38) | 6.89 ± 0.10 (189/31) | 6.68 ± 0.13 (171/32) | 6.61 ± 0.10 (205/34) | 6.42 ± 0.08** (197/34)
4 | 10.15 ± 0.15** (206/38) | 10.08 ± 0.15 (189/31) | 9.94 ± 0.16 (170/31) | 9.85 ± 0.16 (204/34) | 9.36 ± 0.16** (197/34)
7 | 16.18 ± 0.28** (143/38) | 15.77 ± 0.31 (122/31) | 15.78 ± 0.28 (119/31) | 15.22 ± 0.29 (129/34) | 14.66 ± 0.26** (132/34)
10 | 23.35 ± 0.35** (143/38) | 22.70 ± 0.40 (122/31) | 22.31 ± 0.40 (119/31) | 22.05 ± 0.40 (129/34) | 20.85 ± 0.33** (132/34)
14 | 32.50 ± 0.42** (143/38) | 31.95 ± 0.51 (122/31) | 32.16 ± 0.38 (117/31) | 31.52 ± 0.43 (129/34) | 30.0 ± 0.41** (132/34)
17 | 38.99 ± 0.51** (143/38) | 38.04 ± 0.61 (122/31) | 38.36 ± 0.44 (117/31) | 38.04 ± 0.47 (129/34) | 36.33 ± 0.48** (132/34)
21 | 52.56 ± 0.65** (143/38) | 51.26 ± 0.75 (122/31) | 51.08 ± 0.70 (117/31) | 51.36 ± 0.66 (129/34) | 49.05 ± 0.61** (132/34)
24 | 64.36 ± 0.83** (143/38) | 62.68 ± 0.88 (122/31) | 63.12 ± 0.67 (117/31) | 62.90 ± 0.76 (129/34) | 59.93 ± 0.72** (132/34)
28 | 80.12 ± 0.78** (143/38) | 79.00 ± 1.02 (122/31) | 79.37 ± 1.01 (117/31) | 78.58 ± 0.95 (129/34) | 75.72 ± 0.83** (132/34)
Male and Female
1 | 7.02 ± 0.07** (422/38) | 7.04 ± 0.09 (396/31) | 6.78 ± 0.14 (370/33) | 6.84 ± 0.08 (425/34) | 6.59 ± 0.07** (419/34)
4 | 10.40 ± 0.14** (421/38) | 10.32 ± 0.14 (395/31) | 9.95 ± 0.26 (367/32) | 10.20 ± 0.13 (423/34) | 9.63 ± 0.14** (417/34)
7 | 16.53 ± 0.28** (285/38) | 16.01 ± 0.31 (248/31) | 15.57 ± 0.58 (241/32) | 15.74 ± 0.27 (268/34) | 15.05 ± 0.25** (267/34)
10 | 23.68 ± 0.34** (285/38) | 23.03 ± 0.39 (248/31) | 22.71 ± 0.39 (240/31) | 22.66 ± 0.37 (268/34) | 21.31 ± 0.32** (267/34)
14 | 33.04 ± 0.41** (285/38) | 32.43 ± 0.48 (247/31) | 32.50 ± 0.40 (238/31) | 32.25 ± 0.43 (268/34) | 30.63 ± 0.40** (267/34)
17 | 39.71 ± 0.48** (285/38) | 38.61 ± 0.57 (247/31) | 38.89 ± 0.47 (238/31) | 39.04 ± 0.47 (268/34) | 37.22 ± 0.49** (267/34)
21 | 53.92 ± 0.67** (285/38) | 52.47 ± 0.74 (247/31) | 52.20 ± 0.77 (238/31) | 53.05 ± 0.66 (268/34) | 50.49 ± 0.62** (267/34)
24 | 66.48 ± 0.80** (285/38) | 64.80 ± 0.88 (247/31) | 65.02 ± 0.75 (238/31) | 65.77 ± 0.81 (268/34) | 62.32 ± 0.71** (267/34)
28 | 83.83 ± 0.92** (285/38) | 82.94 ± 1.11 (247/31) | 82.98 ± 1.14 (238/31) | 83.06 ± 0.99 (268/34) | 79.20 ± 0.92** (267/34)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed using mixed models with random litter effect for both trend and pairwise tests, using the Dunnett-Hsu adjustment for multiple comparisons.

^b^ Data are presented as mean of litter means ± standard error (number of pups/number of litters). Body weight data are presented in grams.

^c^ Individual pup weights first adjusted for live litter size on postnatal day (PND) 1.

^d^ PND 4 prestandardization.

^e^ Individual pup weights first adjusted for live litter size on PND 4 poststandardization.

Anogenital distance (AGD) was increased in both males and females in the 300 mg/L groups compared to the control groups, but no effects were observed in the 1,000 mg/L groups for either sex (Appendix G). Although this effect occurred in both sexes, the increase in AGD was considered sporadic and not related to sulfolane exposure.

Pubertal development, including balanopreputial separation (BPS) and vaginal opening (VO), was assessed in male and female rats. A significant positive trend in day of attainment for BPS was observed in males, but when adjusted for body weight at weaning, this trend was not present, suggesting the effect was secondarily related to body weight differences (Table 7). Male body weight at attainment was marginally but significantly decreased (3%) in the 1,000 mg/L group compared to the control group. In female rats, a significant delay in VO occurred in both the 300 and 1,000 mg/L groups (Table 8). The delay was also significant after adjustment for weaning body weight. There were no effects on body weight at attainment in female rats.

Table 7 Summary of Balanopreputial Separation of F_1_ Male Rats Following Perinatal Exposure to Sulfolane

Parameter^a^ | 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
No. Examined^b^ | 120 (38) | 120 (31) | 120 (31) | 120 (29) | 120 (31)
No. Not Attaining^c^ | 0 (0) | 0 (0) | 1 (1) | 0 (0) | 1 (1)
Day of BPS
Litter mean^d,e^ | 44.6 ± 0.2* | 44.5 ± 0.4 | 44.5 ± 0.2 | 44.5 ± 0.3 | 45.4 ± 0.4
Adjusted litter mean^d,f,g^ | 44.8 ± 0.2 | 44.5 ± 0.3 | 44.6 ± 0.2 | 44.5 ± 0.2 | 45.1 ± 0.4
Body Weight at Attainment (g)^h^ | 192.2 ± 1.7 | 187.0 ± 1.9 | 189.6 ± 1.7 | 189.5 ± 1.8 | 186.2 ± 2.1*
Body Weight at Weaning (g)^h^ | 89.1 ± 1.4** | 86.2 ± 1.3 | 86.9 ± 1.3 | 86.7 ± 1.3 | 83.0 ± 1.2**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BPS = balanopreputial separation.

^a^ Data are displayed as mean ± standard error unless otherwise noted; values are based on litter means, not individual pup values.

^b^ No. Examined = number of pups examined (number of litters).

^c^ No. Not Attaining = number of pups that survived to the end of the observation period without attaining BPS (number of litters).

^d^ Summary statistics and mixed model results are presented for animals that attained BPS during the observation period.

^e^ Statistical analysis performed using mixed effects models with exposure as a covariate for both trend and pairwise tests and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^f^ Adjusted based on body weight at weaning.

^g^ Statistical analysis performed using mixed effects models with exposure and weaning weight as covariates for both trend and pairwise tests and a Dunnett-Hsu adjustment for multiple pairwise comparisons. No statistically significant findings were noted at p ≤ 0.05.

^h^ Analysis of body weight at acquisition and body weight at weaning for both linear trend and pairwise comparisons performed using mixed effects models with exposure as a covariate and litter as a random effect and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

Table 8 Summary of Vaginal Opening of F_1_ Female Rats Following Perinatal Exposure to Sulfolane

Parameter^a^ | 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
No. Examined^b^ | 120 (33) | 120 (31) | 117 (31) | 120 (32) | 120 (32)
No. Not Attaining^c^ | 0 (0) | 0 (0) | 0 (0) | 0 (0) | 0 (0)
Day of VO
Litter mean^d,e^ | 36.2 ± 0.3** | 37.1 ± 0.3 | 36.5 ± 0.3 | 37.4 ± 0.3* | 38.4 ± 0.3**
Adjusted litter mean^d,f,g^ | 36.4 ± 0.3** | 37.1 ± 0.3 | 36.6 ± 0.3 | 37.4 ± 0.3* | 38.2 ± 0.3**
Body Weight at Attainment (g)^h^ | 115.7 ± 1.3 | 116.1 ± 1.4 | 115.0 ± 1.3 | 116.3 ± 1.6 | 116.4 ± 1.5
Body Weight at Weaning (g)^h^ | 81.6 ± 1.2** | 78.7 ± 1.0 | 79.9 ± 1.0 | 78.3 ± 1.0 | 76.0 ± 0.8**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

VO = vaginal opening.

^a^ Data are displayed as mean ± standard error unless otherwise noted; values are based on litter means, not individual pup values.

^b^ No. Examined = the number of pups examined (number of litters).

^c^ No. Not Attaining = number of pups that survived to the end of the observation period without attaining VO (number of litters).

^d^ Summary statistics and mixed model results are presented for animals that attained VO during the observation period.

^e^ Statistical analysis performed using mixed effects models with exposure as a covariate for both trend and pairwise tests and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^f^ Adjusted based on body weight at weaning.

^g^ Statistical analysis performed using mixed effects models with exposure and weaning weight as covariates for both trend and pairwise tests and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^h^ Analysis of body weight at acquisition and body weight at weaning for both linear trend and pairwise comparisons performed using mixed effects models with exposure as a covariate and litter as a random effect and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

### Two-year Study (Three-month Interim Evaluation)

There were no exposure-related effects on survival or on clinical observations in male and female rats at the 3-month interim evaluation (Appendix G). There were significant decreases (6%–9%) in terminal body weights of male rats in the 100, 300, and 1,000 mg/L groups compared to the control group, but these differences did not exceed 10% (Table 9, Table 10; Figure 2). There were no effects on body weights of female rats at the 3-month interim evaluation.

Table 9 Summary of Survival and Body Weights of Male Rats in the Three-month Interim Evaluation during the Perinatal and Two-year Drinking Water Study of Sulfolane

Postnatal Day | 0 mg/L | | 30 mg/L | | | 100 mg/L | | | 300 mg/L | | | 1,000 mg/L
Postnatal Day | Wt. (g)^a,b^ | No. of Litters | Wt. (g) | Wt. (% of Controls) | No. of Litters | Wt. (g) | Wt. (% of Controls) | No. of Litters | Wt. (g) | Wt. (% of Controls) | No. of Litters | Wt. (g) | Wt. (% of Controls) | No. of Litters
28^c^ | 94.9 ± 2.9* | 10 | 87.2 ± 2.1* | 91.9 | 10 | 89.3 ± 1.7 | 94.1 | 10 | 89.9 ± 1.9 | 94.8 | 10 | 84.2 ± 1.5** | 88.8 | 10
35 | 135.3 ± 3.3 | 10 | 126.2 ± 3.2 | 93.3 | 10 | 128.2 ± 2.1 | 94.7 | 10 | 132.8 ± 2.4 | 98.1 | 10 | 124.5 ± 2.2* | 92.0 | 10
42 | 185.3 ± 3.9* | 10 | 174.1 ± 4.1 | 94.0 | 10 | 175.1 ± 2.8 | 94.5 | 10 | 178.3 ± 4.0 | 96.2 | 10 | 167.2 ± 2.4** | 90.2 | 10
49 | 233.0 ± 4.5** | 10 | 221.3 ± 4.9 | 95.0 | 10 | 222.1 ± 3.1 | 95.3 | 10 | 223.7 ± 4.8 | 96.0 | 10 | 209.8 ± 2.5** | 90.1 | 10
56 | 283.2 ± 5.8** | 10 | 268.7 ± 4.9 | 94.9 | 10 | 269.8 ± 4.2 | 95.3 | 10 | 268.4 ± 5.4* | 94.8 | 10 | 256.7 ± 3.8** | 90.6 | 10
63 | 322.0 ± 6.4** | 10 | 306.5 ± 5.0 | 95.2 | 10 | 305.6 ± 3.8 | 94.9 | 10 | 294.9 ± 13.1* | 91.6 | 10 | 292.5 ± 4.3** | 90.9 | 10
70 | 349.5 ± 6.1** | 10 | 335.4 ± 4.8 | 96.0 | 10 | 332.6 ± 3.8* | 95.2 | 10 | 333.0 ± 6.4* | 95.3 | 10 | 320.2 ± 4.5** | 91.6 | 10
77 | 374.5 ± 6.6** | 10 | 356.9 ± 5.1* | 95.3 | 10 | 353.3 ± 4.0* | 94.3 | 10 | 354.0 ± 6.6* | 94.5 | 10 | 342.0 ± 4.9** | 91.3 | 10
84 | 394.4 ± 7.7** | 10 | 377.8 ± 5.1 | 95.8 | 10 | 376.7 ± 4.8 | 95.5 | 10 | 374.4 ± 8.4* | 94.9 | 10 | 359.2 ± 6.0** | 91.1 | 10
91 | 409.4 ± 7.3** | 10 | 394.7 ± 5.3 | 96.4 | 10 | 391.4 ± 5.2 | 95.6 | 10 | 394.1 ± 8.4 | 96.3 | 10 | 377.6 ± 6.7** | 92.2 | 10
98 | 431.7 ± 8.3** | 10 | 411.0 ± 6.5 | 95.2 | 10 | 404.2 ± 5.3* | 93.6 | 10 | 400.0 ± 9.9** | 92.7 | 10 | 391.1 ± 7.4** | 90.6 | 10
105 | 442.9 ± 8.4** | 10 | 420.1 ± 6.9* | 94.8 | 10 | 414.4 ± 5.1* | 93.6 | 10 | 415.8 ± 10.5* | 93.9 | 10 | 406.3 ± 6.9** | 91.7 | 10
112 | 459.6 ± 9.0** | 10 | 431.4 ± 7.9* | 93.9 | 10 | 426.8 ± 5.0** | 92.9 | 10 | 425.4 ± 10.8** | 92.6 | 10 | 416.9 ± 7.7** | 90.7 | 10
119 | 467.7 ± 8.6** | 10 | 450.6 ± 6.4 | 96.4 | 10 | 438.2 ± 5.6* | 93.7 | 10 | 438.5 ± 11.8* | 93.8 | 10 | 430.4 ± 8.3** | 92.0 | 10

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed by Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^b^ Weights shown are mean ± standard error.

^c^ Postnatal day 28 is the day animals were placed on study after pups were weaned.

Table 10 Summary of Survival and Body Weights of Female Rats in the Three-month Interim Evaluation during the Perinatal and Two-year Drinking Water Study of Sulfolane

Postnatal Day | 0 mg/L | | 30 mg/L | | | 100 mg/L | | | 300 mg/L | | | 1,000 mg/L
Postnatal Day | Wt. (g)^a,b^ | No. of Litters | Wt. (g) | Wt. (% of Controls) | No. of Litters | Wt. (g) | Wt. (% of Controls) | No. of Litters | Wt. (g) | Wt. (% of Controls) | No. of Litters | Wt. (g) | Wt. (% of Controls) | No. of Litters
28^c^ | 77.6 ± 2.0 | 10 | 78.9 ± 1.7 | 101.8 | 10 | 81.7 ± 1.5 | 105.3 | 10 | 82.5 ± 1.4 | 106.3 | 10 | 76.3 ± 1.6 | 98.4 | 10
35 | 109.4 ± 2.4 | 10 | 109.7 ± 2.1 | 100.3 | 10 | 112.7 ± 1.8 | 103.1 | 10 | 117.6 ± 2.4 | 107.5 | 10 | 108.5 ± 2.7 | 99.2 | 10
42 | 141.7 ± 3.2 | 10 | 138.6 ± 2.7 | 97.9 | 10 | 143.2 ± 2.2 | 101.1 | 10 | 145.1 ± 2.3 | 102.5 | 9^d^ | 135.4 ± 3.3 | 95.6 | 10
49 | 163.2 ± 3.1 | 10 | 163.8 ± 2.8 | 100.4 | 10 | 167.1 ± 2.6 | 102.4 | 10 | 167.3 ± 3.2 | 102.6 | 10 | 162.5 ± 3.7 | 99.6 | 10
56 | 183.8 ± 4.2 | 10 | 185.9 ± 3.6 | 101.1 | 10 | 187.8 ± 2.9 | 102.2 | 10 | 191.4 ± 2.3 | 104.1 | 10 | 178.3 ± 3.9 | 97.0 | 10
63 | 202.1 ± 4.3 | 10 | 203.5 ± 3.2 | 100.7 | 10 | 208.3 ± 4.0 | 103.1 | 10 | 206.8 ± 2.8 | 102.4 | 10 | 198.5 ± 4.7 | 98.2 | 10
70 | 217.6 ± 5.5 | 10 | 220.3 ± 4.5 | 101.3 | 10 | 221.6 ± 5.2 | 101.9 | 10 | 218.5 ± 3.2 | 100.4 | 10 | 209.8 ± 5.5 | 96.4 | 10
77 | 226.8 ± 5.5 | 10 | 233.3 ± 4.5 | 102.8 | 10 | 234.1 ± 5.5 | 103.2 | 10 | 235.3 ± 3.7 | 103.7 | 10 | 221.0 ± 6.2 | 97.4 | 10
84 | 236.4 ± 5.7 | 10 | 239.0 ± 5.2 | 101.1 | 10 | 245.3 ± 5.6 | 103.8 | 10 | 242.1 ± 3.4 | 102.4 | 10 | 226.0 ± 5.4 | 95.6 | 10
91 | 244.1 ± 4.6 | 10 | 246.6 ± 5.0 | 101.0 | 10 | 247.8 ± 4.9 | 101.5 | 10 | 247.7 ± 3.3 | 101.5 | 10 | 235.1 ± 6.6 | 96.3 | 10
98 | 250.0 ± 5.6 | 10 | 256.0 ± 5.7 | 102.4 | 9^d^ | 257.4 ± 5.4 | 102.9 | 10 | 256.7 ± 3.7 | 102.6 | 10 | 244.1 ± 6.9 | 97.6 | 10
105 | 253.5 ± 5.3 | 10 | 260.1 ± 4.9 | 102.6 | 10 | 260.3 ± 5.6 | 102.7 | 10 | 261.0 ± 6.0 | 103.0 | 10 | 244.0 ± 6.3 | 96.3 | 10
112 | 259.5 ± 4.9 | 10 | 266.0 ± 5.6 | 102.5 | 10 | 272.0 ± 6.1 | 104.8 | 10 | 270.9 ± 3.5 | 104.4 | 10 | 252.8 ± 6.0 | 97.4 | 10
119 | 263.9 ± 5.9 | 10 | 270.2 ± 5.7 | 102.4 | 10 | 278.0 ± 6.3 | 105.3 | 10 | 274.1 ± 3.8 | 103.9 | 10 | 255.1 ± 6.1 | 96.7 | 10

^a^ Statistical analysis performed by Jonckheere (trend) and Williams or Dunnett (pairwise) tests. No statistically significant findings were noted at p ≤ 0.05.

^b^ Weights shown are mean ± standard error.

^c^ Postnatal day 28 is the day animals were placed on study after pups were weaned.

^d^ One animal weight was excluded from analysis on the indicated study day.

Figure 2

Growth Curves for Male and Female Rats in the Three-month Interim Evaluation during the Perinatal and Two-year Drinking Water Study of Sulfolane

Growth curves are shown for (A) males and (B) females.

Water consumption by F_1_ rats postweaning to the interim necropsy (PND 28–119) was unaffected by sulfolane exposure (Table 11). In males, sporadic but significant differences compared to the control group were observed that were not considered exposure related, and no differences were observed in females (Appendix G). Average chemical intake was calculated from study day 28 through study day 119. Generally, chemical intake increased in proportion to exposure concentration; however, female chemical intake was marginally higher (average of approximately 1.3-fold) than that of males.

Table 11 Summary of Water and Sulfolane Consumption by Male and Female Rats in the Three-month Interim Evaluation during the Perinatal and Two-year Drinking Water Study

Postnatal Day Interval^a^ | 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
Male (g/kg/day)^b^
28–35 | 160.5 ± 6.2 (6) | 157 ± 6.1 (5) | 167.9 ± 13.1 (6) | 153.9 ± 2.7 (5) | 155.7 ± 5.3 (5)
49–56 | 116.5 ± 2.6 (6) | 117.9 ± 3.1 (5) | 116.4 ± 2.4 (6) | 118.1 ± 4.3 (5) | 111.8 ± 6.6 (5)
70–77 | 74.1 ± 2.6 (6) | 80.3 ± 2.8 (5) | 78.7 ± 2.5 (6) | 79.3 ± 1.0 (5) | 76.6 ± 4.7 (5)
112–119 | 55.8 ± 1.5 (6) | 59.8 ± 1.6 (5) | 58.3 ± 2.1 (6) | 57.3 ± 2.4 (5) | 56.6 ± 3.4 (5)
28–119 | 83.3 ± 2.0 (6) | 85.0 ± 2.0 (5) | 83.5 ± 2.2 (6) | 83.8 ± 1.7 (5) | 79.9 ± 3.5 (5)
Chemical Intake (mg/kg/day)^c,d^
28–119 | 0.0 ± 0.0 (6) | 2.5 ± 0.1 (5) | 8.3 ± 0.2 (6) | 25.1 ± 0.5 (5) | 79.9 ± 3.5 (5)
Female (g/kg/day)
28–35 | 151.9 ± 8.2 (3) | 171.1 ± 8.6 (4) | 147.4 ± 21.6 (4) | 147.2 ± 9.5 (3) | 117.7 ± 27.4 (4)
49–56 | 114.8 ± 4.0 (3) | 126.1 ± 7.7 (4) | 125.2 ± 9.3 (4) | 119.8 ± 10.9 (3) | 120.8 ± 7.8 (4)
70–77 | 92.9 ± 2.9 (3) | 107.0 ± 5.7 (4) | 97.2 ± 7.8 (4) | 101.9 ± 3.8 (3) | 103.6 ± 12.5 (4)
112–119 | 80.9 ± 4.4 (3) | 88.0 ± 8.3 (4) | 83.6 ± 5.5 (4) | 79.0 ± 4.2 (3) | 87.6 ± 9.4 (4)
28–119 | 101.2 ± 4.3 (3) | 109.7 ± 8.5 (4) | 106.1 ± 8.5 (4) | 103.8 ± 3.8 (3) | 103.8 ± 5.4 (4)
Chemical Intake (mg/kg/day)
28–119 | 0.0 ± 0.0 (3) | 3.3 ± 0.3 (4) | 10.6 ± 0.9 (4) | 31.1 ± 1.2 (3) | 103.8 ± 5.4 (4)

^a^ Data are presented as mean ± standard error (number of cages).

^b^ Each exposed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present. No statistically significant findings were noted at p ≤ 0.05.

^c^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^d^ No statistical analysis performed on the chemical intake data.

There were no exposure-related effects on absolute or relative organ weights of males or females; organ weight changes noted in male rats were considered secondary to body weight changes (Appendix G). There were no exposure-related effects observed on clinical chemistry or hematology and no exposure-related gross or microscopic lesions (Appendix G).

Sperm count analysis was not conducted because of clumping during the measurement of sperm parameters. No lesions were observed in the testis or epididymis after microscopic evaluation, and sulfolane exposure did not affect estrous cyclicity parameters (Appendix G).

Plasma sulfolane concentrations were quantified in all exposed groups and were below the limit of detection (LOD) for the control group (Table 12). Average chemical intake (PND 28–119) by males and females in the internal concentration assessment groups was calculated to be 3, 8, 26, and 80 mg/kg/day and 3, 11, 30, and 96 mg/kg/day, respectively (Appendix G). Sulfolane plasma concentrations were generally consistent between male and female rats. The proportional increase in sulfolane plasma concentrations relative to exposure concentration was much higher in the 1,000 mg/L groups, indicating a saturation in metabolism occurs between 300 and 1,000 mg/L.

Table 12 Summary of Internal Concentration Data for Male and Female Rats in the Three-month Interim Evaluation during the Perinatal and Two-year Drinking Water Study of Sulfolane

| 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
n | 5 | 5 | 5 | 5 | 5
Sulfolane Plasma Concentration (ng/mL)^a,b^
Male | BD^c^ | 342 ± 26.9 | 1,020 ± 160 | 4,300 ± 399 | 27,300 ± 6,090
Female | BD | 213 ± 36.3 | 1,110 ± 312 | 3,350 ± 410 | 25,200 ± 5,280

BD = below detection; group did not have over 20% of its values above the limit of detection (LOD).

^a^ Data are presented as mean ± standard error.

^b^ If over 20% of the animals in a group were above the limit of LOD, one-half of the LOD value was substituted for values below the LOD. LOD for plasma = 0.516 ng/mL.

^c^ When the vehicle control group did not have over 20% of its values above the LOD, no mean or standard error was calculated, and no statistical analysis was performed.

### Two-year Study (Postweaning Phase)

Chronic exposure to sulfolane did not affect the survival of female rats (Table 13; Figure 3), and no clinical observations were attributable to exposure. There was a significant negative trend for survival in male rats; however, no clinical findings or histological lesions explained the lower survival. Survival in the highest exposure group was marginally outside the NTP historical control range of 24%–64% in male Sprague Dawley rats across 10 studies.^80^ It is not clear if the survival of male rats was affected by sulfolane exposure. In males exposed to 1,000 mg/L, significant decreases (<11%) in body weights compared to the control group were observed. In females exposed to 1,000 mg/L, significant decreases in body weight compared to the control group (5%–16%) were observed throughout the study and were not associated with clinical observations. (Table 14, Table 15; Figure 4).

Table 13 Summary of Survival of Male and Female Rats in the Perinatal and Two-year Drinking Water Study of Sulfolane

| 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
Male
Animals Initially in Study | 50 | 50 | 50 | 50 | 50
Euthanized Moribund | 24 | 22 | 22 | 22 | 20
Found Dead | 10 | 11 | 13 | 11 | 20
Animals Surviving to Study Termination^a^ | 16^b^ | 17^c^ | 15 | 17 | 10^d^
Percent Probability of Survival at Study Termination^e^ | 32.0 | 34.0 | 30.0 | 34.0 | 20.0
Survival (Days)^f^ | 650.1 ± 18.9 | 619.8 ± 18.8 | 636.1 ± 18.2 | 647.5 ± 16.8 | 603.4 ± 18.7
Survival Analysis^g^ | p = 0.034 | p = 0.835 | p = 0.835 | p = 0.835N | p = 0.158
Female
Animals Initially in Study | 50 | 50 | 50 | 50 | 50
Euthanized Moribund | 19 | 18 | 19 | 16 | 22
Found Dead | 10 | 6 | 5 | 7 | 9
Animals Surviving to Study Termination | 21 | 26 | 26 | 27^h^ | 19^c^
Percent Probability of Survival at Study Termination | 42.0 | 52.0 | 52.0 | 54.0 | 38.0
Survival (Days) | 670.5 ± 14.7 | 679.6 ± 14.5 | 668.3 ± 13.2 | 654.4 ± 19.5 | 651.2 ± 17.1
Survival Analysis | p = 0.204 | p = 0.567N | p = 0.567N | p = 0.567N | p = 0.567

^a^ Any animal that reached the age of the youngest animal euthanized at study termination is considered as surviving to study termination.

^b^ Includes one animal that was found dead and one animal that was euthanized moribund; both were older than the youngest animal euthanized at study termination.

^c^ Includes one animal that was euthanized moribund, which was older than the youngest animal euthanized at study termination.

^d^ Includes two animals that were found dead; both were older than the youngest animal euthanized at study termination.

^e^ Kaplan-Meier determinations.

^f^ Mean of litter means of all deaths (uncensored, censored, and study termination) ± standard error.

^g^ The result of the Cox proportional hazards trend test with random litter effect is in the vehicle control group column, and the results of the Cox proportional hazards pairwise comparisons, with a Hommel adjustment for multiple comparisons, to the vehicle control group are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

^h^ Includes one animal that was found dead, which was older than the youngest animal euthanized at study termination.

Figure 3

Kaplan-Meier Survival Curves for Male and Female Rats in the Perinatal and Two-year Drinking Water Study of Sulfolane

Survival curves are shown for (A) males and (B) females.

Table 14 Summary of Survival and Body Weights of Male Rats in the Perinatal and Two-year Drinking Water Study of Sulfolane

Study Day^a^ | 0 mg/L | | 30 mg/L | | | 100 mg/L | | | 300 mg/L | | | 1,000 mg/L
Study Day^a^ | Wt. (g)^b,c^ | n^d^ | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n
0 | 454.3 ± 4.2 | 50 (27) | 443.3 ± 5.1 | 97.6 | 50 (25) | 441.0 ± 4.9 | 97.1 | 50 (26) | 451.8 ± 5.5 | 99.4 | 50 (25) | 438.8 ± 4.6 | 96.6 | 50 (26)
28 | 488.1 ± 5.4 | 50 (27) | 471.7 ± 5.5 | 96.6 | 50 (25) | 472.3 ± 4.7 | 96.8 | 50 (26) | 480.2 ± 6.1 | 98.4 | 50 (25) | 467.8 ± 5.4 | 95.9 | 50 (26)
56 | 514.6 ± 6.0 | 50 (27) | 496.3 ± 5.8 | 96.4 | 50 (25) | 497.0 ± 5.7 | 96.6 | 50 (26) | 509.6 ± 6.3 | 99.0 | 50 (25) | 494.4 ± 5.9 | 96.1 | 50 (26)
84 | 526.1 ± 6.4 | 50 (27) | 508.3 ± 6.1 | 96.6 | 50 (25) | 511.6 ± 5.5 | 97.2 | 50 (26) | 521.9 ± 6.8 | 99.2 | 50 (25) | 509.1 ± 6.2 | 96.8 | 50 (26)
112 | 544.8 ± 6.9 | 50 (27) | 526.4 ± 7.0 | 96.6 | 49 (25) | 527.9 ± 5.9 | 96.9 | 49 (26) | 542.0 ± 7.0 | 99.5 | 50 (25) | 526.5 ± 7.1 | 96.6 | 50 (26)
140 | 565.8 ± 6.9 | 50 (27) | 545.7 ± 7.1 | 96.4 | 49 (25) | 548.6 ± 6.5 | 96.9 | 49 (26) | 563.0 ± 7.6 | 99.5 | 50 (25) | 543.1 ± 7.7 | 96.0 | 50 (26)
168 | 587.4 ± 7.6 | 50 (27) | 567.7 ± 8.1 | 96.6 | 49 (25) | 571.8 ± 6.8 | 97.3 | 48 (26) | 584.4 ± 8.3 | 99.5 | 50 (25) | 562.1 ± 7.5 | 95.7 | 50 (26)
196 | 605.6 ± 8.5* | 49 (26) | 579.4 ± 8.5 | 95.7 | 49 (25) | 586.6 ± 7.4 | 96.9 | 48 (26) | 598.9 ± 8.3 | 98.9 | 50 (25) | 569.9 ± 7.6* | 94.1 | 50 (26)
224 | 612.1 ± 8.7 | 49 (26) | 587.2 ± 8.7 | 95.9 | 49 (25) | 597.8 ± 7.7 | 97.7 | 48 (26) | 607.3 ± 8.8 | 99.2 | 50 (25) | 580.7 ± 8.1 | 94.9 | 49 (26)
252 | 625.7 ± 9.1* | 49 (26) | 602.4 ± 9.0 | 96.3 | 48 (25) | 613.0 ± 8.7 | 98.0 | 46 (26) | 618.9 ± 9.1 | 98.9 | 49 (25) | 589.0 ± 8.7* | 94.1 | 49 (26)
280 | 638.6 ± 9.8* | 49 (26) | 612.5 ± 9.4 | 95.9 | 48 (25) | 629.2 ± 8.9 | 98.5 | 45 (26) | 632.7 ± 9.6 | 99.1 | 49 (25) | 598.8 ± 9.6* | 93.8 | 48 (26)
308 | 646.4 ± 10.2* | 48 (26) | 619.4 ± 10.2 | 95.8 | 48 (25) | 638.8 ± 9.2 | 98.8 | 45 (26) | 639.2 ± 10.6 | 98.9 | 49 (25) | 604.9 ± 9.8* | 93.6 | 47 (26)
336 | 655.9 ± 10.9** | 47 (26) | 625.3 ± 11.1 | 95.3 | 48 (25) | 647.5 ± 9.4 | 98.7 | 45 (26) | 653.9 ± 10.5 | 99.7 | 48 (25) | 609.8 ± 9.8** | 93.0 | 45 (26)
364 | 657.1 ± 11.5** | 46 (26) | 620.8 ± 12.1 | 94.5 | 47 (25) | 650.3 ± 9.2 | 99.0 | 45 (26) | 653.7 ± 11.8 | 99.5 | 48 (25) | 606.0 ± 11.0** | 92.2 | 43 (25)
392 | 654.4 ± 12.8* | 45 (26) | 628.4 ± 13.7 | 96.0 | 43 (25) | 646.3 ± 9.5 | 98.8 | 45 (26) | 652.1 ± 10.5 | 99.7 | 45 (24) | 606.0 ± 11.7* | 92.6 | 39 (25)
420 | 647.9 ± 13.9** | 45 (26) | 634.9 ± 13.7 | 98.0 | 41 (24) | 643.7 ± 10.1 | 99.3 | 44 (26) | 658.7 ± 9.9 | 101.7 | 42 (23) | 600.4 ± 13.9* | 92.7 | 36 (25)
448 | 654.0 ± 12.7** | 43 (25) | 629.2 ± 17.1 | 96.2 | 38 (23) | 645.1 ± 11.2 | 98.6 | 41 (24) | 660.9 ± 10.0 | 101.1 | 39 (23) | 584.8 ± 19.3** | 89.4 | 32 (23)
476 | 651.5 ± 12.9* | 41 (25) | 630.2 ± 13.0 | 96.7 | 34 (22) | 641.2 ± 11.4 | 98.4 | 40 (24) | 652.0 ± 12.2 | 100.1 | 39 (23) | 598.8 ± 17.0* | 91.9 | 29 (21)
504 | 643.3 ± 13.5 | 40 (25) | 616.6 ± 16.2 | 95.9 | 32 (20) | 634.6 ± 14.5 | 98.6 | 39 (24) | 644.0 ± 13.9 | 100.1 | 37 (22) | 604.0 ± 14.5 | 93.9 | 25 (18)
532 | 639.6 ± 13.4* | 36 (24) | 625.8 ± 15.0 | 97.8 | 27 (19) | 633.4 ± 14.9 | 99.0 | 36 (23) | 630.2 ± 18.2 | 98.5 | 35 (21) | 589.2 ± 14.5 | 92.1 | 24 (17)
560 | 610.6 ± 17.4* | 33 (23) | 632.8 ± 10.3 | 103.6 | 22 (16) | 606.1 ± 18.0 | 99.3 | 30 (23) | 621.9 ± 16.8 | 101.9 | 31 (18) | 565.6 ± 18.5 | 92.6 | 20 (13)
588 | 608.5 ± 18.4* | 25 (19) | 608.0 ± 15.2 | 99.9 | 20 (16) | 602.9 ± 21.3 | 99.1 | 24 (19) | 607.2 ± 26.8 | 99.8 | 26 (16) | 546.6 ± 23.0 | 89.8 | 18 (13)
616 | 595.4 ± 25.4 | 21 (16) | 597.9 ± 13.8 | 100.4 | 18 (15) | 599.4 ± 16.8 | 100.7 | 17 (14) | 625.7 ± 24.3 | 105.1 | 20 (14) | 539.1 ± 29.4 | 90.5 | 13 (12)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Study day 0 is the day the 3-month interim animals were removed, at which time animals were between 123 and 128 days of age.

^b^ Statistical analysis was performed using mixed models with litter as a random effect for both trend and pairwise tests, using Dunnett-Hsu adjustment for multiple comparisons.

^c^ Weights shown are mean of litter means ± standard error.

^d^ Number of individual animals (number of litters).

Table 15 Summary of Survival and Body Weights of Female Rats in the Perinatal and Two-year Drinking Water Study of Sulfolane

Study Day^a^ | 0 mg/L | | 30 mg/L | | | 100 mg/L | | | 300 mg/L | | | 1,000 mg/L
Study Day^a^ | Wt. (g)^b,c^ | n^d^ | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n
0 | 276.4 ± 2.8** | 50 (27) | 275.0 ± 2.8 | 99.5 | 50 (25) | 275.9 ± 3.2 | 99.8 | 50 (26) | 272.3 ± 3.5 | 98.5 | 50 (26) | 263.7 ± 2.4* | 95.4 | 50 (26)
28 | 292.8 ± 3.6** | 50 (27) | 286.3 ± 3.2 | 97.8 | 50 (25) | 288.9 ± 3.7 | 98.7 | 50 (26) | 285.3 ± 3.3 | 97.4 | 50 (26) | 276.1 ± 2.7** | 94.3 | 50 (26)
56 | 303.8 ± 3.6** | 50 (27) | 299.5 ± 3.4 | 98.6 | 50 (25) | 299.7 ± 3.7 | 98.7 | 50 (26) | 296.8 ± 3.8 | 97.7 | 50 (26) | 286.2 ± 3.1** | 94.2 | 50 (26)
84 | 314.0 ± 4.1** | 50 (27) | 309.8 ± 3.5 | 98.7 | 50 (25) | 310.0 ± 4.4 | 98.7 | 50 (26) | 307.5 ± 3.9 | 97.9 | 50 (26) | 294.4 ± 2.9** | 93.8 | 50 (26)
112 | 322.8 ± 4.1** | 50 (27) | 316.0 ± 3.9 | 97.9 | 50 (25) | 321.6 ± 5.2 | 99.6 | 50 (26) | 318.7 ± 4.1 | 98.7 | 50 (26) | 301.5 ± 3.5** | 93.4 | 50 (26)
140 | 334.0 ± 4.8** | 50 (27) | 326.4 ± 4.3 | 97.7 | 50 (25) | 328.8 ± 6.0 | 98.4 | 50 (26) | 327.6 ± 4.8 | 98.1 | 49 (26) | 308.5 ± 3.8** | 92.4 | 49 (26)
168 | 338.8 ± 5.5** | 49 (27) | 331.3 ± 4.8 | 97.8 | 50 (25) | 336.6 ± 6.5 | 99.3 | 50 (26) | 334.5 ± 5.3 | 98.7 | 49 (26) | 311.1 ± 5.6** | 91.8 | 49 (26)
196 | 345.9 ± 6.0** | 49 (27) | 335.6 ± 5.0 | 97.0 | 50 (25) | 338.5 ± 6.3 | 97.8 | 50 (26) | 340.6 ± 6.4 | 98.5 | 49 (26) | 316.0 ± 5.1** | 91.4 | 49 (26)
224 | 349.1 ± 6.4** | 49 (27) | 345.8 ± 5.4 | 99.1 | 50 (25) | 346.8 ± 6.8 | 99.3 | 50 (26) | 346.4 ± 5.8 | 99.2 | 48 (26) | 323.7 ± 5.2* | 92.7 | 49 (26)
252 | 353.2 ± 7.4** | 49 (27) | 350.5 ± 6.9 | 99.2 | 49 (25) | 353.3 ± 8.0 | 100.0 | 50 (26) | 352.3 ± 6.8 | 99.7 | 47 (26) | 326.1 ± 6.0 | 92.3 | 48 (26)
280 | 366.8 ± 7.1** | 49 (27) | 356.7 ± 7.5 | 97.3 | 48 (25) | 364.9 ± 8.1 | 99.5 | 50 (26) | 365.1 ± 8.0 | 99.5 | 46 (25) | 337.5 ± 6.2* | 92.0 | 47 (26)
308 | 379.2 ± 7.8** | 47 (27) | 364.8 ± 8.5 | 96.2 | 48 (25) | 373.0 ± 8.7 | 98.4 | 50 (26) | 375.2 ± 8.9 | 98.9 | 46 (25) | 345.2 ± 6.8* | 91.0 | 47 (26)
336 | 390.9 ± 8.8* | 47 (27) | 372.4 ± 9.7 | 95.3 | 48 (25) | 378.2 ± 9.4 | 96.7 | 49 (26) | 377.6 ± 8.2 | 96.6 | 44 (25) | 355.5 ± 7.5* | 90.9 | 47 (26)
364 | 398.3 ± 9.2* | 47 (27) | 373.3 ± 9.7 | 93.9 | 48 (25) | 377.3 ± 9.1 | 94.7 | 47 (26) | 383.3 ± 8.2 | 96.2 | 44 (25) | 359.2 ± 7.6* | 90.2 | 47 (26)
392 | 405.8 ± 9.7** | 47 (27) | 379.5 ± 10.1 | 93.5 | 47 (25) | 391.5 ± 9.7 | 96.5 | 46 (26) | 388.8 ± 8.8 | 95.8 | 44 (25) | 360.7 ± 8.8** | 88.9 | 46 (26)
420 | 416.8 ± 10.3** | 47 (27) | 390.5 ± 10.3 | 93.7 | 47 (25) | 406.1 ± 10.7 | 97.4 | 45 (26) | 400.4 ± 9.4 | 96.1 | 44 (25) | 360.4 ± 8.8** | 86.5 | 45 (26)
448 | 425.3 ± 11.8** | 47 (27) | 398.4 ± 11.3 | 93.7 | 47 (25) | 412.2 ± 13.8 | 96.9 | 44 (26) | 403.7 ± 9.5 | 94.9 | 42 (25) | 366.4 ± 9.5** | 86.2 | 42 (25)
476 | 423.0 ± 12.0** | 44 (26) | 400.4 ± 11.5 | 94.7 | 45 (25) | 411.2 ± 11.6 | 97.2 | 40 (25) | 415.7 ± 12.4 | 98.3 | 41 (25) | 371.9 ± 10.5* | 87.9 | 40 (24)
504 | 421.6 ± 10.4** | 43 (25) | 398.4 ± 9.3 | 94.5 | 43 (24) | 418.9 ± 12.5 | 99.4 | 38 (24) | 417.7 ± 13.1 | 99.1 | 39 (25) | 367.7 ± 11.0** | 87.2 | 38 (24)
532 | 429.4 ± 12.9** | 41 (24) | 408.8 ± 11.2 | 95.2 | 40 (23) | 434.4 ± 16.1 | 101.2 | 36 (24) | 415.4 ± 11.2 | 96.7 | 37 (24) | 373.3 ± 12.5* | 86.9 | 36 (23)
560 | 426.6 ± 12.9** | 35 (23) | 424.1 ± 13.1 | 99.4 | 37 (22) | 428.7 ± 15.2 | 100.5 | 33 (22) | 425.7 ± 14.4 | 99.8 | 31 (23) | 366.0 ± 12.7* | 85.8 | 31 (22)
588 | 435.7 ± 15.3** | 28 (21) | 427.6 ± 13.7 | 98.2 | 35 (21) | 425.3 ± 17.0 | 97.6 | 31 (22) | 407.8 ± 13.3 | 93.6 | 29 (22) | 364.8 ± 16.9** | 83.7 | 28 (19)
616 | 438.1 ± 14.5** | 25 (20) | 415.1 ± 12.8 | 94.8 | 26 (17) | 414.0 ± 12.8 | 94.5 | 30 (21) | 408.8 ± 14.7 | 93.3 | 27 (21) | 372.2 ± 17.4** | 85.0 | 21 (15)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Study day 0 is the day the 3-month interim animals were removed, at which time animals were between 123 and 128 days of age.

^b^ Statistical analysis was performed using mixed models with litter as a random effect for both trend and pairwise tests, using Dunnett-Hsu adjustment for multiple comparisons.

^c^ Weights shown are mean of litter means ± standard error.

^d^ Number of individual animals (number of litters).

Figure 4

Growth Curves for Male and Female Rats in the Perinatal and Two-year Drinking Water Study of Sulfolane

Growth curves are shown for (A) males and (B) females. Study day 0 is the day the 3-month interim animals were removed, at which time animals were between 123 and 128 days of age.

Water consumption by exposed groups was generally not statistically different from that of the control groups throughout the 2-year period, although water consumption (g/kg/day) by the 1,000 mg/L groups was somewhat higher than that of the control groups. Average chemical intake was calculated over the study day 21–616 interval (corresponding to PND 144–149 through PND 739–744). Generally, chemical intake (mg/kg/day) increased in proportion to exposure concentration. Additionally, intake by males was consistently lower than that of females throughout the 2-year study period (Table 16), which is consistent with findings from other drinking water studies.

Table 16 Summary of Water and Sulfolane Consumption by Male and Female Rats in the Perinatal and Two-year Drinking Water Study

Study Day Interval^a,b^ | 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
Male (g/kg/day)^c^
21–28 | 50.3 ± 0.8 (27) | 50.6 ± 0.9 (25) | 50.1 ± 1.1 (26) | 49.1 ± 1.1 (25) | 52.9 ± 1.4 (26)
217–224 | 38.6 ± 0.9 (27) | 42.3 ± 1.7 (25) | 39.1 ± 1.3 (26) | 39.1 ± 1.1 (25) | 41.6 ± 1.1 (26)
413–420 | 49.6 ± 3.5 (27) | 49.7 ± 4.4 (22) | 49.8 ± 2.9 (26) | 44.8 ± 2.4 (22) | 60.6 ± 5.6 (24)
609–616 | 73.7 ± 5.3 (16) | 69.5 ± 5.4 (15) | 74.3 ± 6.1 (14) | 77.3 ± 8.4 (14) | 83.4 ± 12.8 (12)
21–616 | 45.5 ± 1.4 (16) | 44.0 ± 1.3 (15) | 46.4 ± 2.4 (14) | 42.4 ± 1.6 (14) | 49.4 ± 4.0 (12)
Chemical Intake (mg/kg/day)^d,e^
21–616 | 0.0 ± 0.0 (16) | 1.3 ± 0.0 (15) | 4.6 ± 0.2 (14) | 12.7 ± 0.5 (14) | 49.4 ± 4.0 (12)
Female (g/kg/day)
21–28 | 69.7 ± 1.8* (14) | 74.3 ± 2.0 (14) | 73.9 ± 1.7 (13) | 74.3 ± 1.6 (13) | 74.7 ± 1.5 (15)
217–224 | 71.7 ± 3.4 (14) | 72.0 ± 1.4 (14) | 75.0 ± 2.3 (13) | 67.6 ± 2.0 (13) | 74.0 ± 3.0 (15)
413–420 | 71.1 ± 2.1 (14) | 86.8 ± 3.7** (16) | 80.6 ± 4.4 (13) | 75.0 ± 2.7 (13) | 83.7 ± 5.2 (15)
609–616 | 74.6 ± 3.4 (12) | 83.9 ± 5.4 (14) | 92.5 ± 8.8 (12) | 82.8 ± 5.6 (11) | 105.8 ± 22.0 (12)
21–616 | 66.3 ± 1.6 (12) | 75.4 ± 1.7 (13) | 76.5 ± 3.4 (12) | 71.1 ± 2.9 (11) | 79.9 ± 6.8 (12)
Chemical Intake (mg/kg/day)
21–616 | 0.0 ± 0.0 (12) | 2.3 ± 0.1 (13) | 7.7 ± 0.3 (12) | 21.3 ± 0.9 (11) | 79.9 ± 6.8 (12)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error (number of cages).

^b^ Study day 0 is the day the 3-month interim animals were removed, at which time animals were between 123 and 128 days of age.

^c^ Each exposure group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^d^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^e^ No statistical analysis performed on the chemical intake data.

#### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms of the mammary gland.

Mammary gland: In female rats, there were significant increases in the incidences of adenoma and adenoma or carcinoma (combined) in the 100 mg/L group compared to the control group (Table 17). The incidences of these lesions in all other exposed groups were also higher than that in the control group but were not significant following pairwise or trend tests. The incidences of adenoma and adenoma or carcinoma (combined) in the 100 mg/L group exceeded the historical control range for all routes of exposure. Though not significant, the incidence of mammary gland adenoma in the 1,000 mg/L group also exceeded the historical control range for all routes of exposure.

Table 17 Incidences of Neoplasms of the Mammary Glands in Female Rats in the Perinatal and Two-year Drinking Water Study of Sulfolane

| 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
n^a^ | 50 | 50 | 50 | 50 | 50
Adenoma^b^
Overall rate^c^ | 1/50 (2%) | 4/50 (8%) | 7/50 (14%) | 2/50 (4%) | 5/50 (10%)
Rate/litters^d^ | 1/27 (4%) | 4/25 (16%) | 7/26 (27%) | 2/26 (8%) | 5/26 (19%)
Adjusted rate^e^ | 2.49% | 9.52% | 17.54% | 5.19% | 12.75%
Terminal rate^f^ | 0/21 (0%) | 2/26 (8%) | 6/26 (23%) | 2/26 (8%) | 1/18 (6%)
First incidence (days) | 661 | 651 | 690 | 734 (T) | 527
Rao-Scott-adjusted poly-3 test^g^ | p = 0.316 | p = 0.198 | p = 0.036 | p = 0.461 | p = 0.102
Adenocarcinoma^h^
Overall rate | 1/50 (2%) | 1/50 (2%) | 2/50 (4%) | 1/50 (2%) | 1/50 (2%)
Rate/litters | 1/27 (4%) | 1/25 (4%) | 2/26 (8%) | 1/26 (4%) | 1/26 (4%)
Adjusted rate | 2.49% | 2.38% | 4.95% | 2.56% | 2.62%
Terminal rate | 0/21 (0%) | 0/26 (0%) | 1/26 (4%) | 0/26 (0%) | 0/18 (0%)
First incidence (days) | 671 | 580 | 501 | 584 | 521
Rao-Scott-adjusted poly-3 test | p = 0.675 | p = 0.743 | p = 0.479 | p = 0.718 | p = 0.711
Adenoma or Adenocarcinoma (Combined)^i^
Overall rate | 2/50 (4%) | 5/50 (10%) | 9/50 (18%) | 3/50 (6%) | 6/50 (12%)
Rate/litters | 2/27 (7%) | 5/25 (20%) | 9/26 (35%) | 3/26 (12%) | 5/26 (19%)
Adjusted rate | 4.94% | 11.76% | 22.18% | 7.69% | 15.05%
Terminal rate | 0/21 (0%) | 2/26 (8%) | 7/26 (27%) | 2/26 (8%) | 1/18 (6%)
First incidence (days) | 661 | 580 | 501 | 584 | 521
Rao-Scott-adjusted poly-3 test | p = 0.373 | p = 0.244 | p = 0.033 | p = 0.469 | p = 0.137

(T) = terminal euthanasia.

^a^ Number of animals with tissue examined microscopically.

^b^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 19/590 (2.81% ± 3.29%); range: 0% to 9%.

^c^ Number of animals with neoplasm/number of animals necropsied.

^d^ Number of litters with neoplasm-bearing animals/number of litters examined at site.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at study termination.

^g^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence is the p value corresponding to pairwise comparisons between the control group and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach study termination) for within-litter correlation. All trend and pairwise p values are reported as one-sided.

^h^ Historical control incidence: 44/590 (7.19% ± 5%); range: 2% to 16%.

^i^ Historical control incidence: 61/590 (9.8% ± 5.8%); range: 2% to 18%.

Other lesions: In the lung of male rats, there were slight but significant increases in the incidences of alveolar histiocytic infiltration (1,000 mg/L group) and chronic interstitial inflammation (100 and 300 mg/L groups) compared to the control group (Appendix G). A positive trend was also observed in the incidence of cellular infiltration. There was a slight increase in the severity of cellular infiltration in the 30 and 1,000 mg/L groups compared to the control group, but the increase was negligible. This lesion was characterized by a slight increase in the number of macrophages in the alveoli of the lungs. The chronic inflammation was characterized by mild, multifocal thickening of the alveolar septa associated with an increase in the number of alveolar macrophages and scattered lymphocytes. Because these findings are very common in laboratory rodents, their incidence varies, and the severity was relatively low, the above lesions were not considered to be related to sulfolane exposure.

## Mice

### Two-year Study (Three-month Interim Evaluation)

There were no exposure-related effects on survival or on clinical observations in male and female mice at the 3-month interim evaluation (Appendix G). Body weights of both male and female mice remained similar to those of the control groups throughout the 3-month study period (Table 18, Table 19; Figure 5).

Table 18 Summary of Survival and Body Weights of Male Mice in the Three-month Interim Evaluation during the Two-year Drinking Water Study of Sulfolane

Study Day^a^ | 0 mg/L | | 30 mg/L | | | 100 mg/L | | | 300 mg/L | | | 1,000 mg/L
Study Day^a^ | Wt. (g)^b,c^ | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n
0 | 22.4 ± 0.2 | 10 | 22.5 ± 0.4 | 100.4 | 10 | 22.1 ± 0.2 | 98.4 | 10 | 22.4 ± 0.3 | 100.0 | 10 | 22.4 ± 0.3 | 100.2 | 10
7 | 24.4 ± 0.3 | 10 | 24.7 ± 0.4 | 101.4 | 10 | 24.0 ± 0.2 | 98.4 | 10 | 24.3 ± 0.3 | 99.8 | 10 | 24.3 ± 0.4 | 99.5 | 10
14 | 25.5 ± 0.7 | 10 | 25.8 ± 0.4 | 101.2 | 10 | 25.6 ± 0.2 | 100.2 | 10 | 25.8 ± 0.3 | 100.9 | 10 | 25.8 ± 0.4 | 100.9 | 10
21 | 26.4 ± 0.3 | 10 | 27.2 ± 0.4 | 103.0 | 10 | 26.5 ± 0.3 | 100.4 | 10 | 26.9 ± 0.4 | 102.1 | 10 | 27.0 ± 0.5 | 102.3 | 10
28 | 27.7 ±0.3 | 10 | 28.3 ± 0.5 | 102.2 | 10 | 27.5 ± 0.4 | 99.1 | 10 | 27.9 ± 0.4 | 100.7 | 10 | 28.2 ± 0.6 | 101.8 | 10
35 | 29.0 ± 0.4 | 10 | 28.4 ± 1.0 | 97.8 | 10 | 29.0 ± 0.4 | 99.8 | 10 | 29.0 ± 0.4 | 100.0 | 10 | 29.5 ± 0.7 | 101.7 | 10
42 | 30.2 ± 0.5 | 10 | 30.9 ± 0.6 | 102.1 | 10 | 30.2 ± 0.5 | 99.9 | 10 | 30.5 ± 0.5 | 101.0 | 10 | 31.3 ± 0.8 | 103.5 | 10
49 | 32.1 ± 0.7 | 10 | 32.6 ± 0.8 | 101.7 | 10 | 32.1 ± 0.5 | 100.1 | 10 | 32.2 ± 0.7 | 100.6 | 10 | 32.7 ± 0.9 | 102.0 | 10
56 | 33.0 ± 0.8 | 10 | 33.5 ± 0.7 | 101.7 | 10 | 32.7 ± 0.5 | 99.0 | 10 | 33.0 ± 0.5 | 100.1 | 10 | 33.6 ± 0.8 | 101.9 | 10
63 | 34.1 ± 0.8 | 10 | 34.9 ± 0.8 | 102.1 | 10 | 34.2 ± 0.6 | 100.1 | 10 | 34.3 ± 0.6 | 100.6 | 10 | 34.8 ± 0.8 | 101.8 | 10
70 | 35.2 ± 0.9 | 10 | 36.5 ± 0.8 | 103.7 | 10 | 35.6 ± 0.7 | 101.1 | 10 | 35.8 ± 0.6 | 101.6 | 10 | 35.8 ± 0.9 | 101.7 | 10
77 | 36.6 ± 0.9 | 10 | 37.6 ± 0.9 | 102.7 | 10 | 36.6 ± 0.7 | 100.1 | 10 | 36.8 ± 0.7 | 100.7 | 10 | 37.1 ± 0.9 | 101.5 | 10
84 | 37.8 ± 0.9 | 10 | 38.6 ± 0.9 | 102.1 | 10 | 37.9 ± 0.8 | 100.2 | 10 | 38.1 ± 0.7 | 101.0 | 10 | 37.8 ± 0.9 | 99.9 | 10
91 | 39.0 ± 0.8 | 10 | 40.0 ± 1.0 | 102.5 | 10 | 39.2 ± 0.7 | 100.6 | 10 | 38.6 ± 0.9 | 99.0 | 10 | 39.1 ± 0.9 | 100.3 | 10

^a^ Study day 0 is the day animals were placed on study.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests. No statistically significant findings were noted at p ≤ 0.05.

^c^ Weights shown are mean ± standard error.

Table 19 Summary of Survival and Body Weights of Female Mice in the Three-month Interim Evaluation during the Two-year Drinking Water Study of Sulfolane

Study Day^a^ | 0 mg/L | | 30 mg/L | | | 100 mg/L | | | 300 mg/L | | | 1,000 mg/L
Study Day^a^ | Wt. (g)^b,c^ | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n
0 | 16.7 ± 0.3 | 10 | 16.9 ± 0.4 | 101.4 | 10 | 17.8 ± 0.3 | 106.6 | 10 | 17.0 ± 0.4 | 101.9 | 10 | 16.8 ± 0.6 | 100.6 | 10
7 | 18.2 ± 0.3 | 10 | 18.0 ± 0.4 | 99.1 | 10 | 18.8 ± 0.2 | 103.5 | 10 | 18.1 ± 0.4 | 99.3 | 10 | 17.9 ± 0.4 | 98.4 | 10
14 | 19.3 ± 0.3 | 10 | 19.5 ± 0.4 | 101.3 | 10 | 20.2 ± 0.3 | 104.6 | 10 | 19.7 ± 0.4 | 102.3 | 10 | 19.2 ± 0.4 | 99.5 | 10
21 | 20.1 ± 0.3 | 10 | 20.3 ± 0.4 | 100.9 | 10 | 20.9 ± 0.3 | 103.9 | 10 | 20.2 ± 0.5 | 100.2 | 10 | 19.9 ± 0.3 | 98.7 | 10
28 | 21.0 ± 0.2 | 10 | 21.5 ± 0.6 | 102.5 | 10 | 22.0 ± 0.4 | 105.0 | 10 | 21.3 ± 0.5 | 101.7 | 10 | 21.3 ± 0.4 | 101.5 | 10
35 | 21.5 ± 0.4 | 10 | 22.7 ± 0.5 | 105.4 | 10 | 22.9 ± 0.4 | 106.2 | 10 | 22.2 ± 0.5 | 103.0 | 10 | 22.0 ± 0.3 | 102.4 | 10
42 | 22.9 ± 0.3 | 10 | 23.8 ± 0.5 | 104.2 | 10 | 24.3 ± 0.5 | 106.5 | 10 | 23.8 ± 0.6 | 104.0 | 10 | 23.1 ± 0.4 | 101.1 | 10
49 | 23.8 ± 0.4 | 10 | 24.9 ± 0.8 | 104.7 | 10 | 25.2 ± 0.4 | 105.9 | 10 | 24.2 ± 0.7 | 101.8 | 10 | 24.3 ± 0.4 | 102.1 | 10
56 | 24.6 ± 0.6 | 10 | 25.6 ± 0.8 | 104.2 | 10 | 26.1 ± 0.5 | 106.1 | 10 | 24.5 ± 0.6 | 99.6 | 10 | 23.8 ± 0.7 | 96.9 | 10
63 | 25.1 ± 0.5 | 10 | 26.7 ± 1.2 | 106.1 | 10 | 26.9 ± 0.6 | 107.1 | 10 | 25.7 ± 0.8 | 102.5 | 10 | 24.6 ± 0.9 | 98.1 | 10
70 | 25.5 ± 0.6 | 10 | 27.6 ± 1.3 | 107.9 | 10 | 28.1 ± 0.7 | 110.1 | 10 | 26.8 ± 1.0 | 104.8 | 10 | 26.5 ± 0.6 | 103.9 | 10
77 | 25.6 ± 0.7 | 10 | 28.6 ± 1.5 | 111.9 | 10 | 28.3 ± 0.7 | 110.5 | 10 | 27.1 ± 1.1 | 106.0 | 10 | 27.5 ± 0.8 | 107.6 | 10
84 | 27.0 ± 0.6 | 10 | 29.7 ± 1.7 | 109.8 | 10 | 28.8 ± 0.8 | 106.6 | 10 | 27.4 ± 0.8 | 101.3 | 10 | 28.2 ± 0.8 | 104.1 | 10
91 | 27.9 ± 0.7 | 10 | 31.4 ± 1.5 | 112.7 | 10 | 30.0 ± 0.8 | 107.5 | 10 | 28.7 ± 1.0 | 102.9 | 10 | 29.7 ± 1.1 | 106.7 | 10

^a^ Study day 0 is the day animals were placed on study.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests. No statistically significant findings were noted at p ≤ 0.05.

^c^ Weights shown are mean ± standard error.

Figure 5

Growth Curves for Male and Female Mice in the Three-month Interim Evaluation during the Two-year Drinking Water Study of Sulfolane

Growth curves are shown for (A) males and (B) females.

Water consumption by male and female mice in the interim evaluation was unaffected by exposure (Table 20). Average chemical intake was calculated from study day 0 through study day 91, and chemical intake generally increased in proportion to exposure concentration and was similar between males and females (Table 20).

Table 20 Summary of Water and Sulfolane Consumption by Male and Female Mice in the Three-month Interim Evaluation during the Two-year Drinking Water Study

Study Day Interval^a,b^ | 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
Male (g/kg/day)^c,d^
0–7 | 135.4 ± 4.5 (10) | 146.3 ± 4.5 (10) | 148.9 ± 5.2 (10) | 148.1 ± 4.9 (10) | 143.9 ± 4.6 (10)
21–28 | 131.7 ± 3.0 (10) | 122.8 ± 3.4 (8) | 131.4 ± 2.8 (6) | 126.1 ± 4.1 (10) | 124.3 ± 6.6 (8)
84–91 | 95.9 ± 5.3** (10) | 97.2 ± 7.9 (10) | 89.9 ± 3.1 (10) | 80.4 ± 2.5* (9) | 82.7 ± 3.2* (10)
0–91 | 117.9 ± 6.5 (10) | 112.6 ± 3.6 (10) | 117.1 ± 4.7 (10) | 109.9 ± 3.2 (10) | 109.3 ± 3.4 (10)
Chemical Intake (mg/kg/day)^e,f^
0–91 | 0.0 ± 0.0 (10) | 3.4 ± 0.1 (10) | 11.7 ± 0.5 (10) | 33.0 ± 1.0 (10) | 109.3 ± 3.4 (10)
Female (g/kg/day)
0–7 | 126.0 ± 5.3 (10) | 129.3 ± 5.3 (10) | 119.5 ± 4.4 (10) | 127.5 ± 5.5 (10) | 123.9 ± 3.1 (10)
21–28 | 127.5 ± 5.8 (10) | 125.5 ± 5.5 (10) | 120.2 ± 3.6 (10) | 125.1 ± 6.3 (10) | 121.0 ± 3.5 (10)
84–91 | 99.6 ± 2.7 (10) | 92.9 ± 4.8 (10) | 91.3 ± 2.5 (10) | 94.8 ± 3.6 (10) | 93.7 ± 3.4 (10)
0–91 | 119.9 ± 2.7 (10) | 115.0 ± 4.3 (10) | 113.6 ± 1.9 (10) | 116.2 ± 4.1 (10) | 117.9 ± 4.0 (10)
Chemical Intake (mg/kg/day)
0–91 | 0.0 ± 0.0 (10) | 3.4 ± 0.1 (10) | 11.4 ± 0.2 (10) | 34.9 ± 1.2 (10) | 117.9 ± 4.0 (10)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error (number of animals).

^b^ Study day 0 is the day animals were placed on study.

^c^ Each exposed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^d^ Excludes water consumption data not collected for all animals at certain time points.

^e^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^f^ No statistical analysis performed on the chemical intake data.

There were no exposure-related effects observed in hematology or relative organ weights of males or females (Appendix G). In both males and females, there were no exposure-related gross or microscopic lesions.

Sperm count analysis was not conducted because of clumping during the measurement of sperm parameters. No lesions were observed in the testis or epididymis after microscopic evaluation, and sulfolane exposure did not affect estrous cyclicity parameters (Appendix G).

Plasma sulfolane concentrations were quantified in all exposed groups and were below the LOD for the control group (Table 21). Average chemical intake in the internal concentration assessment groups was calculated to be 3, 11, 32, and 103 mg/kg/day for males and 4, 12, 34, and 112 mg/kg/day for females (Appendix G). Sulfolane concentrations were generally consistent between male and female mice in the 30 and 100 mg/L groups, but plasma concentrations were approximately 2-fold and 13-fold higher in females than in males in the 300 and 1,000 mg/L groups, respectively. The proportional increase in sulfolane plasma concentrations relative to exposure concentration was much higher in the female 300 and 1,000 mg/L groups, indicating a saturation in metabolism occurs at exposure concentrations between 100 and 300 mg/L in females.

Table 21 Summary of Internal Concentration Data for Male and Female Mice in the Three-month Interim Evaluation during the Two-year Drinking Water Study of Sulfolane

| 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
n | 5 | 5 | 5 | 5 | 5
Sulfolane Plasma Concentration (ng/mL)^a, b^
Male | BD^c^ | 31.1 ± 13.5 | 184 ± 83.1 | 597 ± 286 | 624 ± 284
Female | BD | 24.4 ± 8.48 | 198 ± 51.3 | 1,350 ± 770 | 8,020 ± 1,900

BD = below detection; group did not have over 20% of its values above the limit of detection (LOD).

^a^ Data are presented as mean ± standard error.

^b^ If over 20% of the animals in a group were above the LOD, one-half of the LOD value was substituted for values below the LOD. LOD for plasma = 0.516 ng/mL.

^c^ When the vehicle control group did not have over 20% of its values above the LOD, no mean or standard error was calculated, and no statistical analysis was performed.

### Two-year Study

Chronic exposure to sulfolane did not affect the survival of male and female mice (Table 22; Figure 6), and no clinical observations were attributable to exposure. There were no significant effects on body weight attributed to sulfolane exposure (Table 23, Table 24; Figure 7).

Table 22 Summary of Survival of Male and Female Mice in the Two-year Drinking Water Study of Sulfolane

| 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
Male
Animals Initially in Study | 50 | 50 | 50 | 50 | 50
Euthanized Moribund | 5 | 12 | 5 | 4 | 7
Found Dead | 11 | 10 | 10 | 14 | 13
Animals Surviving to Study Termination | 34 | 28 | 35 | 32 | 30^a^
Percent Probability of Survival at Study Termination^b^ | 68.0 | 56.0 | 70.0 | 64.0 | 60.0
Survival (Days)^c^ | 700.6 ± 8.0 | 691.1 ± 8.5 | 690.9 ± 11.2 | 688.1 ± 11.3 | 688.5 ± 10.1
Survival Analysis^d^ | p = 0.641 | p = 0.972 | p = 1.000N | p = 1.000 | p = 1.000
Female
Animals Initially in Study | 50 | 50 | 50 | 50 | 50
Euthanized Moribund | 2 | 2 | 5 | 8 | 2
Found Dead | 13 | 9 | 11 | 8 | 11
Animals Surviving to Study Termination | 35 | 39 | 34 | 34 | 37
Percent Probability of Survival at Study Termination | 70.0 | 78.0 | 68.0 | 68.0 | 74.0
Survival (Days) | 702.2 ± 8.1 | 703.6 ± 9.6 | 695.7 ± 10.7 | 689.5 ± 12.5 | 690.1 ± 13.8
Survival Analysis | p = 0.969N | p = 0.945N | p = 0.945 | p = 0.945 | p = 0.945N

^a^ Includes one animal that was euthanized moribund after the first day of necropsy.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored, censored, and study termination) ± standard error.

^d^ The result of the Tarone trend test is in the vehicle control group column, and the results of the Cox proportional hazards pairwise comparisons to the vehicle control group are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

Figure 6

Kaplan-Meier Survival Curves for Male and Female Mice in the Two-year Drinking Water Study of Sulfolane

Survival curves are shown for (A) males and (B) females.

Table 23 Summary of Survival and Body Weights of Male Mice in the Two-year Drinking Water Study of Sulfolane

Study Day^a^ | 0 mg/L | | 30 mg/L | | | 100 mg/L | | | 300 mg/L | | | 1,000 mg/L
Study Day^a^ | Wt. (g)^b,c^ | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors
0 | 22.5 ± 0.1 | 50 | 22.6 ± 0.1 | 100.1 | 50 | 22.7 ± 0.1 | 100.6 | 50 | 22.6 ± 0.1 | 100.1 | 50 | 22.5 ± 0.1 | 99.7 | 50
7 | 24.6 ± 0.1 | 50 | 24.6 ± 0.1 | 99.9 | 50 | 24.6 ± 0.1 | 99.8 | 50 | 24.4 ± 0.1 | 99.1 | 50 | 24.4 ± 0.1 | 99.2 | 50
14 | 26.2 ± 0.1 | 50 | 25.9 ± 0.1 | 98.9 | 50 | 26.0 ± 0.1 | 99.2 | 50 | 25.9 ± 0.2 | 98.8 | 50 | 25.9 ± 0.2 | 98.8 | 50
21 | 26.6 ± 0.1 | 50 | 26.9 ± 0.2 | 101.2 | 50 | 26.9 ± 0.2 | 101.2 | 50 | 27.1 ± 0.2 | 102.0 | 50 | 26.9 ± 0.2 | 101.3 | 50
28 | 28.0 ± 0.2 | 50 | 28.1 ± 0.2 | 100.2 | 50 | 27.9 ± 0.2 | 99.8 | 50 | 28.2 ± 0.2 | 100.9 | 50 | 28.0 ± 0.2 | 100.0 | 50
35 | 29.6 ± 0.2 | 50 | 29.3 ± 0.2 | 99.2 | 50 | 29.2 ± 0.2 | 98.7 | 50 | 29.5 ± 0.3 | 99.9 | 50 | 29.3 ± 0.2 | 99.0 | 50
42 | 30.8 ± 0.3 | 50 | 30.7 ± 0.3 | 99.7 | 50 | 30.8 ± 0.3 | 99.7 | 50 | 30.9 ± 0.3 | 100.3 | 50 | 30.8 ± 0.3 | 99.8 | 50
49 | 32.5 ± 0.3 | 50 | 32.5 ± 0.3 | 99.8 | 50 | 32.5 ± 0.3 | 99.9 | 50 | 32.7 ± 0.3 | 100.6 | 50 | 32.5 ± 0.3 | 99.8 | 50
56 | 33.6 ± 0.3 | 50 | 33.3 ± 0.3 | 99.1 | 50 | 33.0 ± 0.3 | 98.4 | 50 | 33.5 ± 0.3 | 99.9 | 50 | 33.2 ± 0.3 | 99.0 | 50
63 | 34.9 ± 0.3 | 50 | 34.4 ± 0.3 | 98.7 | 50 | 34.4 ± 0.3 | 98.6 | 50 | 34.7 ± 0.4 | 99.5 | 50 | 34.5 ± 0.4 | 99.0 | 50
70 | 36.2 ± 0.4 | 50 | 35.7 ± 0.3 | 98.8 | 50 | 35.8 ± 0.4 | 99.0 | 50 | 36.1 ± 0.4 | 99.8 | 50 | 35.7 ± 0.4 | 98.7 | 50
77 | 37.5 ± 0.4 | 50 | 36.9 ± 0.4 | 98.6 | 50 | 36.9 ± 0.4 | 98.5 | 50 | 37.2 ± 0.4 | 99.2 | 50 | 36.9 ± 0.4 | 98.5 | 50
84 | 38.5 ± 0.4 | 50 | 38.3 ± 0.4 | 99.3 | 50 | 38.2 ± 0.4 | 99.2 | 50 | 38.6 ± 0.4 | 100.3 | 50 | 38.3 ± 0.4 | 99.3 | 50
91 | 39.9 ± 0.5 | 50 | 39.5 ± 0.4 | 99.1 | 50 | 39.6 ± 0.4 | 99.3 | 50 | 39.8 ± 0.4 | 99.8 | 50 | 39.6 ± 0.4 | 99.4 | 50
119 | 44.2 ± 0.5 | 50 | 44.0 ± 0.4 | 99.5 | 50 | 43.9 ± 0.5 | 99.2 | 50 | 44.3 ± 0.5 | 100.2 | 50 | 43.8 ± 0.5 | 99.1 | 50
147 | 47.3 ± 0.5 | 50 | 47.0 ± 0.4 | 99.4 | 50 | 46.5 ± 0.4 | 98.4 | 50 | 46.6 ± 0.5 | 98.5 | 49^d^ | 46.7 ± 0.4 | 98.8 | 50
175 | 48.8 ± 0.4 | 50 | 49.0 ± 0.4 | 100.4 | 50 | 48.7 ± 0.3 | 99.9 | 50 | 48.7 ± 0.3 | 99.8 | 50 | 48.8 ± 0.4 | 100.1 | 50
203 | 50.0 ± 0.4 | 50 | 50.2 ± 0.3 | 100.3 | 50 | 49.8 ± 0.3 | 99.5 | 50 | 50.1 ± 0.3 | 100.1 | 50 | 50.1 ± 0.3 | 100.1 | 50
231 | 50.5 ± 0.6 | 50 | 51.9 ± 0.4 | 102.7 | 50 | 51.0 ± 0.3 | 100.9 | 50 | 51.3 ± 0.3 | 101.6 | 49^e^ | 51.1 ± 0.3 | 101.1 | 50
259 | 52.8 ± 0.4 | 50 | 52.9 ± 0.4 | 100.0 | 50 | 52.4 ± 0.3 | 99.2 | 50 | 52.7 ± 0.4 | 99.6 | 50 | 52.6 ± 0.3 | 99.6 | 50
287 | 53.7 ± 0.4 | 50 | 53.6 ± 0.4 | 99.9 | 50 | 53.3 ± 0.3 | 99.2 | 50 | 53.3 ± 0.4 | 99.2 | 50 | 53.6 ± 0.4 | 99.7 | 50
315 | 54.9 ± 0.4* | 50 | 54.5 ± 0.4 | 99.4 | 50 | 53.8 ± 0.4 | 98.1 | 50 | 53.9 ± 0.4 | 98.3 | 50 | 54.0 ± 0.4 | 98.4 | 50
343 | 55.4 ± 0.4* | 50 | 55.0 ± 0.4 | 99.3 | 50 | 54.1 ± 0.4 | 97.7 | 50 | 54.5 ± 0.4 | 98.4 | 50 | 54.6 ± 0.4 | 98.7 | 50
371 | 55.4 ± 0.4 | 50 | 55.2 ± 0.5 | 99.6 | 50 | 54.4 ± 0.5 | 98.3 | 50 | 54.7 ± 0.5 | 98.8 | 50 | 55.1 ± 0.4 | 99.4 | 50
399 | 55.2 ± 0.4 | 50 | 55.2 ± 0.5 | 100.0 | 50 | 54.4 ± 0.4 | 98.5 | 49 | 55.0 ± 0.5 | 99.5 | 50 | 55.0 ± 0.4 | 99.5 | 49
427 | 55.5 ± 0.5 | 50 | 55.3 ± 0.5 | 99.7 | 50 | 54.5 ± 0.5 | 98.2 | 49 | 55.2 ± 0.5 | 99.4 | 48 | 55.3 ± 0.4 | 99.7 | 49
455 | 55.7 ± 0.6 | 50 | 55.3 ± 0.6 | 99.2 | 50 | 54.9 ± 0.5 | 98.4 | 49 | 55.3 ± 0.5 | 99.2 | 48 | 55.3 ± 0.5 | 99.2 | 49
483 | 55.9 ± 0.6 | 49 | 55.8 ± 0.6 | 99.8 | 50 | 54.3 ± 0.7 | 97.0 | 49 | 55.5 ± 0.6 | 99.1 | 48 | 55.3 ± 0.6 | 98.8 | 49
511 | 56.1 ± 0.7 | 49 | 55.0 ± 0.8 | 98.0 | 49^e^ | 53.8 ± 0.8 | 95.8 | 48 | 55.1 ± 0.7 | 98.2 | 48 | 54.6 ± 0.8 | 97.2 | 49
539 | 55.3 ± 0.8 | 48 | 54.4 ± 0.8 | 98.5 | 49 | 53.6 ± 0.9 | 97.0 | 47 | 54.9 ± 0.8 | 99.3 | 46 | 53.9 ± 1.0 | 97.5 | 49
567 | 54.3 ± 0.9 | 48 | 53.5 ± 0.9 | 98.5 | 46 | 52.7 ± 0.9 | 97.0 | 44 | 53.5 ± 0.9 | 98.4 | 46 | 53.7 ± 1.0 | 98.8 | 45
595 | 52.8 ± 1.1 | 48 | 51.6 ± 1.1 | 97.8 | 43 | 50.5 ± 1.1 | 95.7 | 42 | 52.6 ± 1.0 | 99.6 | 43 | 53.1 ± 1.1 | 100.6 | 44
623 | 52.9 ± 1.2 | 45 | 50.7 ± 1.3 | 95.8 | 42 | 49.2 ± 1.3 | 93.0 | 41 | 51.3 ± 1.2 | 97.0 | 42 | 52.6 ± 1.3 | 99.4 | 43
651 | 49.7 ± 1.4 | 43 | 48.5 ± 1.4 | 97.5 | 38 | 48.1 ± 1.4 | 96.8 | 40 | 49.4 ± 1.3 | 99.4 | 38 | 53.3 ± 1.4 | 107.1 | 38
679 | 49.2 ± 1.5 | 37 | 46.2 ± 1.7 | 93.9 | 35 | 46.6 ± 1.6 | 94.8 | 39 | 47.4 ± 1.5 | 96.3 | 37 | 51.8 ± 1.5 | 105.2 | 36
707 | 49.2 ± 1.4 | 36 | 45.5 ± 1.9 | 92.6 | 32 | 45.1 ± 1.7 | 91.8 | 37 | 45.9 ± 1.7 | 93.3 | 36 | 51.8 ± 1.5 | 105.3 | 32

Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

^a^ Study day 0 is the day animals were placed on study.

^b^ Statistical analysis performed by Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Weights shown are mean ± standard error.

^d^ One animal weight was excluded from analysis on the indicated study day.

^e^ One animal weight was excluded as an outlier and thus excluded from analysis on the indicated study day.

Table 24 Summary of Survival and Body Weights of Female Mice in the Two-year Drinking Water Study of Sulfolane

Study Day^a^ | 0 mg/L | | 30 mg/L | | | 100 mg/L | | | 300 mg/L | | | 1,000 mg/L
Study Day^a^ | Wt. (g)^b,c^ | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors | Wt. (g) | Wt. (% of Controls) | No. of Survivors
0 | 17.5 ± 0.2 | 50 | 17.5 ± 0.1 | 100.1 | 50 | 17.4 ± 0.2 | 99.2 | 50 | 17.5 ± 0.2 | 99.8 | 50 | 17.6 ± 0.2 | 100.3 | 50
7 | 18.6 ± 0.2 | 50 | 18.6 ± 0.1 | 99.7 | 50 | 18.4 ± 0.2 | 98.8 | 50 | 18.7 ± 0.1 | 100.3 | 50 | 18.5 ± 0.1 | 99.2 | 50
14 | 19.9 ± 0.2 | 50 | 19.8 ± 0.1 | 99.3 | 50 | 19.8 ± 0.2 | 99.6 | 50 | 19.7 ± 0.2 | 99.0 | 50 | 19.7 ± 0.2 | 98.8 | 50
21 | 20.7 ± 0.2 | 50 | 20.6 ± 0.2 | 99.2 | 50 | 20.8 ± 0.2 | 100.2 | 50 | 20.6 ± 0.2 | 99.1 | 50 | 20.7 ± 0.2 | 99.9 | 50
28 | 21.7 ± 0.2 | 50 | 21.3 ± 0.2 | 98.3 | 50 | 21.8 ± 0.2 | 100.4 | 50 | 21.5 ± 0.2 | 99.2 | 50 | 21.6 ± 0.2 | 99.6 | 50
35 | 22.3 ± 0.2 | 50 | 22.2 ± 0.2 | 99.5 | 50 | 22.3 ± 0.2 | 99.7 | 50 | 22.2 ± 0.2 | 99.5 | 50 | 22.3 ± 0.2 | 99.8 | 50
42 | 23.8 ± 0.2 | 50 | 23.5 ± 0.2 | 99.0 | 50 | 23.6 ± 0.3 | 99.1 | 50 | 23.7 ± 0.2 | 99.5 | 50 | 23.6 ± 0.2 | 99.1 | 50
49 | 24.6 ± 0.3 | 50 | 24.6 ± 0.2 | 100.1 | 50 | 24.5 ± 0.3 | 99.7 | 50 | 24.7 ± 0.2 | 100.4 | 50 | 24.8 ± 0.3 | 100.9 | 50
56 | 25.3 ± 0.3 | 50 | 25.2 ± 0.3 | 99.9 | 50 | 25.3 ± 0.3 | 100.1 | 50 | 25.3 ± 0.3 | 100.3 | 50 | 24.9 ± 0.3 | 98.8 | 50
63 | 26.5 ± 0.4 | 50 | 25.9 ± 0.3 | 97.8 | 50 | 26.4 ± 0.3 | 99.6 | 50 | 26.2 ± 0.3 | 99.1 | 50 | 26.2 ± 0.3 | 98.9 | 50
70 | 27.2 ± 0.4 | 50 | 27.0 ± 0.4 | 99.1 | 50 | 26.9 ± 0.4 | 98.8 | 50 | 27.0 ± 0.3 | 99.2 | 50 | 26.9 ± 0.3 | 98.8 | 50
77 | 28.2 ± 0.5 | 50 | 27.9 ± 0.4 | 99.0 | 50 | 27.5 ± 0.4 | 97.5 | 50 | 28.2 ± 0.4 | 100.1 | 50 | 28.1 ± 0.4 | 99.7 | 50
84 | 29.0 ± 0.5 | 50 | 29.3 ± 0.4 | 100.8 | 50 | 28.5 ± 0.4 | 98.3 | 50 | 29.0 ± 0.4 | 100.0 | 50 | 29.0 ± 0.4 | 99.8 | 50
91 | 30.2 ± 0.5 | 50 | 30.1 ± 0.5 | 99.6 | 50 | 29.7 ± 0.5 | 98.5 | 50 | 29.8 ± 0.4 | 98.8 | 50 | 29.9 ± 0.4 | 99.0 | 50
119 | 34.7 ± 0.6 | 50 | 34.3 ± 0.6 | 99.0 | 50 | 34.3 ± 0.6 | 98.9 | 50 | 35.0 ± 0.5 | 100.9 | 50 | 34.3 ± 0.5 | 98.9 | 50
147 | 38.6 ± 0.7 | 50 | 37.6 ± 0.6 | 97.4 | 50 | 38.2 ± 0.7 | 98.8 | 50 | 39.1 ± 0.6 | 101.4 | 50 | 38.6 ± 0.6 | 100.0 | 50
175 | 42.4 ± 0.7* | 50 | 41.8 ± 0.6 | 98.6 | 50 | 41.9 ± 0.8 | 98.8 | 50 | 43.7 ± 0.7 | 103.2 | 50 | 43.2 ± 0.6 | 101.9 | 50
203 | 45.1 ± 0.7 | 50 | 45.1 ± 0.7 | 100.0 | 50 | 45.3 ± 0.8 | 100.4 | 50 | 46.8 ± 0.7 | 103.8 | 50 | 46.0 ± 0.7 | 101.9 | 50
231 | 48.5 ± 0.7* | 50 | 48.7 ± 0.7 | 100.4 | 50 | 48.7 ± 0.8 | 100.4 | 50 | 50.6 ± 0.8 | 104.2 | 50 | 50.0 ± 0.7 | 103.1 | 50
259 | 52.3 ± 0.7 | 50 | 52.3 ± 0.7 | 99.8 | 50 | 52.2 ± 0.9 | 99.7 | 50 | 53.4 ± 0.8 | 102.0 | 50 | 53.6 ± 0.8 | 102.5 | 50
287 | 54.3 ± 0.6* | 50 | 54.4 ± 0.7 | 100.2 | 50 | 54.5 ± 0.9 | 100.3 | 50 | 56.0 ± 0.7 | 103.2 | 50 | 55.4 ± 0.7 | 102.0 | 50
315 | 56.0 ± 0.6 | 50 | 56.2 ± 0.7 | 100.5 | 50 | 55.8 ± 0.8 | 99.8 | 49 | 57.0 ± 0.6 | 101.8 | 49 | 56.3 ± 0.7 | 100.6 | 49
343 | 57.8 ± 0.6 | 50 | 58.0 ± 0.6 | 100.3 | 50 | 58.1 ± 0.7 | 100.5 | 49 | 58.6 ± 0.6 | 101.4 | 49 | 57.8 ± 0.7 | 99.9 | 49
371 | 59.1 ± 0.5 | 50 | 59.2 ± 0.6 | 100.2 | 50 | 59.3 ± 0.7 | 100.4 | 49 | 59.7 ± 0.6 | 101.0 | 49 | 59.0 ± 0.6 | 99.8 | 47^d^
399 | 58.6 ± 0.5 | 50 | 59.3 ± 0.6 | 101.2 | 49 | 59.6 ± 0.7 | 101.8 | 49 | 59.2 ± 0.7 | 101.1 | 49 | 58.4 ± 0.8 | 99.7 | 48
427 | 59.1 ± 0.6 | 50 | 60.0 ± 0.6 | 101.5 | 49 | 60.7 ± 0.7 | 102.8 | 49 | 60.5 ± 0.7 | 102.4 | 48 | 60.0 ± 0.8 | 101.5 | 47
455 | 60.7 ± 0.6* | 50 | 60.4 ± 0.7 | 99.5 | 49 | 61.5 ± 0.8 | 101.3 | 49 | 62.0 ± 0.6 | 102.1 | 48 | 61.2 ± 1.0 | 100.7 | 47
483 | 61.8 ± 0.7 | 50 | 61.4 ± 0.7 | 99.3 | 49 | 61.9 ± 0.9 | 100.1 | 49 | 62.9 ± 0.8 | 101.9 | 48 | 62.1 ± 1.1 | 100.6 | 46
511 | 60.9 ± 0.9* | 48 | 60.8 ± 0.8 | 99.9 | 48 | 61.4 ± 1.1 | 100.8 | 49 | 62.2 ± 0.8 | 102.2 | 48 | 62.3 ± 1.1 | 102.3 | 46
539 | 60.0 ± 1.2* | 48 | 60.7 ± 0.9 | 101.1 | 48 | 60.4 ± 1.3 | 100.5 | 48 | 62.2 ± 0.9 | 103.6 | 45 | 62.0 ± 1.1 | 103.3 | 46
567 | 59.9 ± 1.2 | 47 | 61.4 ± 0.8 | 102.5 | 46 | 61.3 ± 1.2 | 102.4 | 46 | 61.1 ± 1.1 | 102.0 | 45 | 62.2 ± 1.1 | 103.9 | 46
595 | 59.3 ± 1.2* | 45 | 60.6 ± 0.8 | 102.0 | 46 | 60.1 ± 1.3 | 101.2 | 46 | 60.8 ± 1.1 | 102.5 | 44 | 61.9 ± 1.2 | 104.4 | 44
623 | 58.9 ± 1.2 | 45 | 60.5 ± 1.0 | 102.7 | 46 | 60.1 ± 1.5 | 102.1 | 44 | 59.8 ± 1.4 | 101.5 | 44 | 60.7 ± 1.3 | 103.0 | 44
651 | 58.3 ± 1.3 | 44 | 60.7 ± 1.0 | 104.1 | 45 | 59.1 ± 1.6 | 101.3 | 44 | 59.9 ± 1.6 | 102.7 | 42 | 59.9 ± 1.3 | 102.8 | 43
679 | 56.7 ± 1.5 | 41 | 58.8 ± 1.1 | 103.7 | 43 | 58.6 ± 1.7 | 103.4 | 40 | 60.1 ± 1.3 | 106.1 | 40 | 58.8 ± 1.2 | 103.8 | 43
707 | 56.3 ± 1.4 | 38 | 56.8 ± 1.1 | 100.9 | 42 | 56.7 ± 1.8 | 100.6 | 37 | 55.8 ± 1.4 | 99.0 | 39 | 55.8 ± 1.5 | 99.1 | 39

Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

^a^ Study day 0 is the day animals were placed on study.

^b^ Statistical analysis performed by Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Weights shown are mean ± standard error.

^d^ One animal weight was excluded as an outlier and thus excluded from analysis on the indicated study day.

Figure 7

Growth Curves for Male and Female Mice in the Two-year Drinking Water Study of Sulfolane

Growth curves are shown for (A) males and (B) females.

Water consumption by male and female mice over the 2-year study period was unaffected by exposure (Table 25). Although slight differences in consumption between exposed groups and control groups were noted, these changes were intermittent and likely due to variability in body weights. Average chemical intake was calculated over the study day 0–707 interval. Generally, chemical intake increased in proportion to exposure concentration; additionally, intake by females was consistently lower than that of males throughout the 2-year study period (Table 25).

Table 25 Summary of Water and Sulfolane Consumption by Male and Female Mice in the Two-year Drinking Water Study

Study Day Interval^a,b^ | 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
Male (g/kg/day)^c^
0–7 | 156.5 ± 4.1 (50) | 148.5 ± 2.0 (49) | 151.7 ± 3.3 (49) | 149.4 ± 3.2 (50) | 150.2 ± 2.4 (50)
84–91 | 86.3 ± 2.1 (45) | 85.2 ± 1.4 (47) | 86.4 ± 1.6 (47) | 83.1 ± 1.6 (48) | 83.4 ± 1.3 (45)
392–399 | 78.5 ± 1.6 (45) | 82.3 ± 2.4 (49) | 81.0 ± 2.1 (48) | 80.6 ± 2.0 (50) | 76.6 ± 1.7 (49)
700–707 | 109.2 ± 6.7 (35) | 136.5 ± 13.0 (32) | 145.2 ± 14.2 (36) | 133.4 ± 12.9 (36) | 97.7 ± 7.5 (32)
0–707 | 93.6 ± 1.7* (36) | 92.4 ± 1.3 (32) | 94.0 ± 1.5 (37) | 93.4 ± 1.8 (36) | 88.7 ± 1.5 (32)
Chemical Intake (mg/kg/day)^d,e^
0–707 | 0.0 ± 0.0 (36) | 2.8 ± 0.0 (32) | 9.4 ± 0.2 (37) | 28.0 ± 0.6 (36) | 88.7 ± 1.5 (32)
Female (g/kg/day)
0–7 | 125.4 ± 3.5 (17) | 126.6 ± 3.1 (17) | 123.9 ± 7.3 (17) | 124.9 ± 4.4 (17) | 125.4 ± 3.4 (17)
84–91 | 94.0 ± 3.0 (17) | 95.0 ± 2.2 (17) | 101.4 ± 5.4 (17) | 91.6 ± 2.3 (17) | 97.8 ± 4.4 (17)
392–399 | 44.2 ± 1.3 (17) | 43.1 ± 1.1 (17) | 45.4 ± 1.2 (17) | 45.4 ± 1.6 (17) | 47.8 ± 2.1 (17)
700–707 | 62.2 ± 4.4 (16) | 61.1 ± 3.6 (17) | 67.5 ± 4.6 (16) | 75.9 ± 8.5 (17) | 67.8 ± 5.6 (17)
0–707 | 65.4 ± 1.8 (16) | 64.3 ± 1.0 (17) | 66.2 ± 1.3 (16) | 64.9 ± 1.3 (17) | 65.3 ± 1.3 (17)
Chemical Intake (mg/kg/day)
0–707 | 0.0 ± 0.0 (16) | 1.9 ± 0.0 (17) | 6.6 ± 0.1 (16) | 19.5 ± 0.4 (17) | 65.3 ± 1.3 (17)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

^a^ Data are presented as mean ± standard error (number of cages).

^b^ Study day 0 is the day animals were placed on study.

^c^ Each exposure group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^d^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^e^ No statistical analysis performed on the chemical intake data.

#### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of all organs (systemic), liver, and ovary.

All organs (systemic): In male mice, the incidence of hemangioma in all organs was higher in the 100 mg/L group relative to the control group; the incidence of hemangiosarcoma in all organs was higher in the 30, 100, and 1,000 mg/L groups relative to the control group; and the incidence of hemangioma or hemangiosarcoma (combined) in all organs was higher in the 30, 100, and 1,000 mg/L groups relative to the control group (Table 26). Only the incidences of hemangiosarcoma alone and hemangioma or hemangiosarcoma (combined) exhibited positive trends and were significantly increased in the 1,000 mg/L group, using pairwise comparisons to the control group. The incidence of hemangioma in all organs exceeded the historical control range for all routes of exposure in the 100 mg/L group. The incidence of hemangiosarcoma exceeded the historical control range for all routes in the 30 and 1,000 mg/L groups, and the incidence of hemangioma or hemangiosarcoma (combined) exceeded the historical control range in the 30, 100, and 1,000 mg/L groups. There were no corresponding increases in lesion incidences observed in sulfolane-exposed female mice.

Table 26 Incidences of Hemangioma or Hemangiosarcoma of All Organs (Systemic) and Select Organs in Male and Female Mice in the Two-year Drinking Water Study of Sulfolane

| | 0 mg/L | | 30 mg/L | | 100 mg/L | | 300 mg/L | | 1,000 mg/L
n^a^ | | 50 | | 50 | | 50 | | 50 | | 50
Male
All Organs
Hemangioma^b^
Overall rate^c^ | | 2/50 (4%) | | 1/50 (2%) | | 3/50 (6%) | | 1/50 (2%) | | 2/50 (4%)
Adjusted rate^d^ | | 4.44% | | 2.31% | | 6.8% | | 2.3% | | 4.56%
Terminal rate^e^ | | 2/34 (6%) | | 1/28 (4%) | | 2/35 (6%) | | 1/32 (3%) | | 0/29 (0%)
First incidence (days) | | 730 (T) | | 730 (T) | | 675 | | 730 (T) | | 565
Poly-3 test^f^ | | p = 0.603 | | p = 0.871 | | p = 0.491 | | p = 0.872 | | p = 0.685
Hemangiosarcoma^g^
Overall rate | | 3/50 (6%) | | 6/50 (12%) | | 4/50 (8%) | | 3/50 (6%) | | 12/50 (24%)
Adjusted rate | | 6.67% | | 13.32% | | 8.91% | | 6.8% | | 26.8%
Terminal rate | | 3/34 (9%) | | 2/28 (7%) | | 2/35 (6%) | | 1/32 (3%) | | 6/29 (21%)
First incidence (days) | | 730 (T) | | 552 | | 523 | | 626 | | 567
Poly-3 test | | p = 0.002 | | p = 0.242 | | p = 0.498 | | p = 0.653 | | p = 0.010
Hemangiosarcoma or Hemangioma (Combined)^h^
Overall rate | | 4/50 (8%) | | 7/50 (14%) | | 7/50 (14%) | | 4/50 (8%) | | 14/50 (28%)
Adjusted rate | | 8.89% | | 15.54% | | 15.53% | | 9.07% | | 30.79%
Terminal rate | | 4/34 (12%) | | 3/28 (11%) | | 4/35 (11%) | | 2/32 (6%) | | 6/29 (21%)
First incidence (days) | | 730 (T) | | 552 | | 523 | | 626 | | 565
Poly-3 test | | p = 0.003 | | p = 0.261 | | p = 0.261 | | p = 0.632 | | p = 0.008
Liver
Hemangioma^i^
Overall rate | | 2/50 (4%) | | 1/50 (2%) | | 0/50 (0%) | | 1/50 (2%) | | 0/50 (0%)
Adjusted rate | | 4.44% | | 2.31% | | 0% | | 2.3% | | 0%
Terminal rate | | 2/34 (6%) | | 1/28 (4%) | | 0/35 (0%) | | 1/32 (3%) | | 0/29 (0%)
First incidence (days) | | 730 (T) | | 730 (T) | | –^j^ | | 730 (T) | | –
Poly-3 test | | p = 0.941 | | p = 0.871 | | p = 0.983 | | p = 0.872 | | p = 0.983
Hemangiosarcoma^k^
Overall rate | | 3/50 (6%) | | 5/50 (10%) | | 3/50 (6%) | | 2/50 (4%) | | 11/50 (22%)
Adjusted rate | | 6.67% | | 11.24% | | 6.69% | | 4.57% | | 24.57%
Terminal rate | | 3/34 (9%) | | 2/28 (7%) | | 1/35 (0%) | | 1/32 (3%) | | 5/29 (17%)
First incidence (days) | | 730 (T) | | 566 | | 523 | | 626 | | 567
Poly-3 test | | p = 0.002 | | p = 0.350 | | p = 0.661 | | p = 0.811 | | p = 0.018
Spleen
Hemangioma^l^
Overall rate | | 0/49 (0%) | | 0/50 (0%) | | 0/50 (0%) | | 0/50 (0%) | | 2/50 (4%)
Adjusted rate | | 0% | | 0% | | 0% | | 0% | | 4.56%
Terminal rate | | 0/34 (0%) | | 0/28 (0%) | | 0/35 (0%) | | 0/32 (0%) | | 0/29 (0%)
First incidence (days) | | – | | – | | – | | – | | 565
Poly-3 test | | p = 0.019 | | (e) | | (e) | | (e) | | p = 0.234
Hemangiosarcoma^m^
Overall rate | | 0/49 (0%) | | 5/50 (10%) | | 1/50 (2%) | | 1/50 (2%) | | 3/50 (6%)
Adjusted rate | | 0% | | 11.17% | | 2.25% | | 2.3% | | 6.88%
Terminal rate | | 0/34 (0%) | | 2/28 (7%) | | 0/35 (0%) | | 1/32 (3%) | | 1/29 (3%)
First incidence (days) | | – | | 552 | | 523 | | 730 (T) | | 666
Poly-3 test | | p = 0.371 | | p = 0.031 | | p = 0.500 | | p = 0.495 | | p = 0.115
Bone Marrow
Hemangiosarcoma^c,n,o^ | | 0/50 (0%) | | 2/50 (4%) | | 0/50 (0%) | | 0/50 (0%) | | 1/50 (2%)
Heart
Hemangiosarcoma^c,p,q^ | | 0/50 (0%) | | 0/50 (0%) | | 0/50 (0%) | | 1/50 (2%) | | 0/50 (0%)
Mesenteric Lymph Node
Hemangioma^c,p,r^ | | 0/50 (0%) | | 0/48 (0%) | | 1/47 (2%) | | 0/49 (0%) | | 0/47 (0%)
Hemangiosarcoma^c,p,q^ | | 0/50 (0%) | | 0/48 (0%) | | 1/47 (2%) | | 0/49 (0%) | | 0/47 (0%)
Prostate
Hemangioma^c,p,q^ | | 0/50 (0%) | | 0/50 (0%) | | 1/50 (2%) | | 0/50 (0%) | | 0/50 (0%)
Skeletal Muscle
Hemangiosarcoma^s,t,u^ | | 0/2 (0%) | | 0/2 (0%) | | 0/1 (0%) | | 0/0 (0%) | | 2/3 (67%)
Skin
Hemangioma^c,p,q^ | | 0/50 (0%) | | 0/50 (0%) | | 1/50 (2%) | | 0/50 (0%) | | 0/50 (0%)
Hemangiosarcoma^c,o,v^ | | 0/50 (0%) | | 2/50 (4%) | | 0/50 (0%) | | 1/50 (2%) | | 1/50 (2%)
Female
All Organs
Hemangioma^w^
Overall rate | | 3/50 (6%) | | 2/50 (4%) | | 3/50 (6%) | | 4/50 (8%) | | 3/50 (6%)
Adjusted rate | | 6.52% | | 4.32% | | 6.59% | | 9.03% | | 6.7%
Terminal rate | | 2/35 (6%) | | 2/39 (5%) | | 2/34 (6%) | | 4/34 (12%) | | 3/37 (8%)
First incidence (days) | | 630 | | 728 (T) | | 560 | | 728 (T) | | 728 (T)
Poly-3 test | | p = 0.504 | | p = 0.821 | | p = 0.657 | | p = 0.479 | | p = 0.649
Hemangiosarcoma^x^
Overall rate | | 1/50 (2%) | | 2/50 (4%) | | 3/50 (6%) | | 2/50 (4%) | | 3/50 (6%)
Adjusted rate | | 2.19% | | 4.32% | | 6.57% | | 4.49% | | 6.63%
Terminal rate | | 1/35 (3%) | | 2/39 (5%) | | 0/34 (0%) | | 1/34 (3%) | | 2/37 (5%)
First incidence (days) | | 728 (T) | | 728 (T) | | 598 | | 651 | | 574
Poly-3 test | | p = 0.344 | | p = 0.504 | | p = 0.305 | | p = 0.491 | | p = 0.302
Hemangiosarcoma or Hemangioma (Combined)^y^
Overall rate | 4/50 (8%) | | 4/50 (8%) | | 6/50 (12%) | | 6/50 (12%) | | 6/50 (12%)
Adjusted rate | 8.69% | | 8.65% | | 12.99% | | 13.46% | | 13.25%
Terminal rate | 3/35 (9%) | | 4/39 (10%) | | 2/34 (6%) | | 5/34 (15%) | | 5/37 (14%)
First incidence (days) | 630 | | 728 (T) | | 560 | | 651 | | 574
Poly-3 test | p = 0.325 | | p = 0.646 | | p = 0.371 | | p = 0.349 | | p = 0.359

(T) = terminal euthanasia; (e) = value of statistic could not be computed.

^a^ Number of animals with tissue examined microscopically.

^b^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 6/439 (1.39% ± 1.41%); range 0% to 4%.

^c^ Number of animals with neoplasm/number of animals necropsied.

^d^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^e^ Observed incidence at study termination.

^f^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence is the p value corresponding to pairwise comparisons between the control group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. All trend and pairwise p values are reported as one-sided.

^g^ Historical control incidence: 21/439 (5.03% ± 2.58%); range: 2% to 10%.

^h^ Historical control incidence: 26/439 (6.18% ± 2.79%); range: 3% to 12%.

^i^ Historical control incidence: 4/439 (1% ± 1.51%); range: 0% to 4%.

^j^ Not applicable; no neoplasms in group.

^k^ Historical control incidence: 10/439 (2.39% ± 2.61%); range: 0% to 6%.

^l^ Historical control incidence: 0/433 (0% ± 0%); range: 0%.

^m^ Historical control incidence: 9/433 (2.28% ± 2.76%); range: 0% to 8%.

^n^ Historical control incidence: 2/437 (0.5% ± 1.41%); range: 0% to 4%.

^o^ Statistical analysis performed by Poly-3 test. No statistically significant findings were noted at p ≤ 0.05.

^p^ No trend or pairwise statistical tests were performed on these data. A Poly-3 analysis was conducted only if the incidence in at least one of the groups was ≥2.

^q^ Historical control incidence: 0/439 (0% ± 0%); range: 0%.

^r^ Historical control incidence: 1/439 (0.14% ± 0.39%); range: 0% to 1%.

^s^ Number of animals with neoplasm/number of tissues examined microscopically.

^t^ No trend or pairwise statistical tests were performed on these data. A Poly-3 analysis was not conducted in tissues when histopathological evaluation was conducted only because a gross lesion was found.

^u^ Historical control incidence: 1/439 (0.25% ± 0.71%); range: 0% to 2%.

^v^ Historical control incidence: 3/439 (0.64% ± 1.41%); range: 0% to 4%.

^w^ Historical control incidence: 11/490 (2.05% ± 2.29%); range: 0% to 6%.

^x^ Historical control incidence: 13/490 (2.69% ± 1.99%); range: 0% to 6%.

^y^ Historical control incidence: 24/490 (4.74% ± 2.5%); range: 2% to 8%.

Hemangiomas and/or hemangiosarcomas were observed in the liver, spleen, bone marrow, heart, mesenteric lymph node, prostate, skeletal muscle, and skin. Significantly increased incidences of hemangiosarcoma, using a pairwise comparison to the control group, were seen in the spleen of males exposed to 30 mg/L and in the liver of males exposed to 1,000 mg/L sulfolane. Positive trends were observed for hemangiosarcoma in the liver and for hemangioma in the spleen. In the liver, the incidence of hemangiosarcoma in the 30 and 1,000 mg/L groups exceeded the historical control range for all routes of exposure. The incidences of hemangioma in the mesenteric lymph node in the 100 mg/L group and in the spleen in the 1,000 mg/L group also exceeded the historical control range for all routes of exposure. The incidences of hemangiosarcoma in the spleen in the 30 mg/L group and in the mesenteric lymph node in the 100 mg/L group exceeded the historical control range for all routes of exposure.

Liver: In female mice, the incidence of hepatocellular carcinoma in the liver was significantly increased in the 1,000 mg/L group, with a positive trend (Table 27). These are relatively common neoplasms in B6C3F1/N mice, and the incidence in all exposure groups, with the exception of the 1,000 mg/L group, was within the historical control range for all routes of exposure. The incidence of hepatocellular adenoma or carcinoma (combined) exhibited a positive trend, but all groups were within the historical control range for all routes of exposure. The incidences of other hepatocellular neoplasms in female mice were not considered exposure related.

Table 27 Incidences of Neoplastic and Nonneoplastic Lesions of the Liver in Male and Female Mice in the Two-year Drinking Water Study of Sulfolane

| 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
n^a^ | 50 | 50 | 50 | 50 | 50
Male
Mixed Cell Focus (Includes Multiple)^b^ | 6 | 18** | 15* | 13* | 7
Female
Clear Cell Focus (Includes Multiple)^b^ | 4* | 4 | 6 | 4 | 10
Fatty Change, Focal^b^ | 1 (1.0)^c^ | 5 (1.2) | 8* (1.1) | 11** (1.1) | 2 (1.0)
Hepatocellular Adenoma^d^
Overall rate^e^ | 10/50 (20%) | 5/50 (10%) | 6/50 (12%) | 11/50 (22%) | 11/50 (22%)
Adjusted rate^f^ | 21.57% | 10.81% | 13.23% | 24.5% | 24.54%
Terminal rate^g^ | 7/35 (20%) | 5/39 (13%) | 5/34 (15%) | 10/34 (29%) | 10/37 (27%)
First incidence (days) | 567 | 728 (T) | 623 | 529 | 713
Poly-3 test^h^ | p = 0.119 | p = 0.955 | p = 0.908 | p = 0.466 | p = 0.465
Hepatocellular Carcinoma^i^
Overall rate | 2/50 (4%) | 3/50 (6%) | 5/50 (10%) | 5/50 (10%) | 8/50 (16%)
Adjusted rate | 4.38% | 6.47% | 10.99% | 11.23% | 17.51%
Terminal rate | 2/35 (6%) | 2/39 (5%) | 3/34 (9%) | 4/34 (12%) | 5/37 (14%)
First incidence (days) | 728 (T) | 706 | 653 | 664 | 592
Poly-3 test | p = 0.030 | p = 0.507 | p = 0.214 | p = 0.205 | p = 0.045
Hepatocellular Adenoma or Carcinoma (Combined)^j^
Overall rate | 11/50 (22%) | 8/50 (16%) | 10/50 (20%) | 16/50 (32%) | 18/50 (36%)
Adjusted rate | 23.72% | 17.26% | 21.79% | 35.45% | 39.34%
Terminal rate | 8/35 (23%) | 7/39 (18%) | 7/34 (21%) | 14/34 (41%) | 14/37 (38%)
First incidence (days) | 576 | 706 | 623 | 529 | 592
Poly-3 test | p = 0.010 | p = 0.847 | p = 0.680 | p = 0.157 | p = 0.080

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

(T) = terminal euthanasia.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion. For nonneoplastic lesions, each exposed group was compared to the vehicle control group using the Poly-3 test.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 83/489 (16.59% ± 7.01%); range: 6% to 24%.

^e^ Number of animals with neoplasm/number of animals necropsied.

^f^ Poly-3-estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal euthanasia.

^h^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence is the p value corresponding to pairwise comparisons between the control group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. All trend and pairwise p values are reported as one-sided.

^i^ Historical control incidence: 28/489 (5.44% ± 3.97%); range 2% to 14%.

^j^ Historical control incidence: 104/489 (20.68% ± 9.23%); range: 8% to 36%.

In male mice, the incidence of mixed cell focus was significantly increased in the 30, 100, and 300 mg/L groups relative to the control group (Table 27). In female mice, the incidence of clear cell focus exhibited a positive trend, and the incidence of focal fatty change was significantly increased in the 100 and 300 mg/L groups relative to the control group.

Ovary: In female mice, the incidence of follicular cysts was significantly increased in the 30, 300, and 1,000 mg/L groups compared to the control group (Table 28). The toxicological significance of this finding is unknown.

Table 28 Incidences of Nonneoplastic Lesions of the Ovary in Female Mice in the Two-year Drinking Water Study of Sulfolane

| 0 mg/L | 30 mg/L | 100 mg/L | 300 mg/L | 1,000 mg/L
n^a^ | 48 | 46 | 47 | 48 | 49
Follicles, Cyst^b^ | 2 | 9* | 3 | 11** | 9*

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion. Each exposed group was compared to the vehicle control group using the Poly-3 test.

## Genetic Toxicology

The genetic toxicity of sulfolane was evaluated in the peripheral blood micronucleus tests in rats and mice after exposure to sulfolane via drinking water. Micronucleated reticulocytes were not increased in male and female rats exposed to sulfolane for 3 months via drinking water (0, 30, 100, 300, 1,000 mg/L) (Table E-1), and there were no increases in micronucleated reticulocytes and micronucleated erythrocytes in male and female mice exposed to sulfolane for 3 months via drinking water (0, 30, 100, 300, 1,000 mg/L) (Table E-2). A positive trend in the percentage of reticulocytes was observed in female rats in the 3-month study, but the increase was within the historical control 95% confidence interval. Data from all NTP genetic toxicity tests with sulfolane are available in the NTP Chemical Effects in Biological Systems database: https://doi.org/10.22427/NTP-DATA-TR-605.^79^