# Materials and Methods

## Procurement and Characterization of Sulfolane

Sulfolane was obtained from Sigma-Aldrich (Milwaukee, WI) in a single lot (MKBN9784V). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at RTI International (Research Triangle Park, NC) and the study laboratory at Battelle (Columbus, OH). Reports on analyses performed in support of the sulfolane studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot MKBN9784V was a solid to a gel at room temperature and formed a colorless liquid upon warming. The identity of the test lot was confirmed using infrared (IR) spectroscopy, ^1^H nuclear magnetic resonance (NMR) spectroscopy, ^13^C NMR spectroscopy, and ultra-high-performance liquid chromatography with high resolution mass spectrometry (MS). The IR, ^1^H NMR, and ^13^C NMR spectra cohered with the structure of sulfolane and were consistent with reference spectra from the Sigma-Aldrich library (IR and ^1^H NMR)^35,36^ and the Spectral Database for Organic Compounds (^13^C NMR).^37^ Elemental analyses were performed by Galbraith Laboratory (Knoxville, TN) to aid in identification. The relative amounts of carbon (39.51%), hydrogen (7.08%), and sulfur (26.34%) were within 6% of the theoretical values. An accurate determination of oxygen could not be made because of interference from the high elemental sulfur content. The boiling point (285°C) and density (1.31 g/cm^3^ at 21.9°C) measured by Galbraith Laboratory were consistent with literature values from the Hazardous Substance Data Bank.^10^

Purity evaluation was conducted using gas chromatography (GC) with flame ionization detection (FID) (Table A-1, System A) and GC with MS detection (Table A-1, System B). No impurities with peak areas ≥0.1% of the total integrated peak area were detected using GC/FID. The GC/MS spectrum for the major component was consistent with the library spectrum for sulfolane.^38^ Karl Fischer titration yielded a water content of 0.22%. The overall purity of the test lot was determined to be >99%. Because butadiene is a precursor of sulfolane synthesis, additional GC/MS analysis was conducted to determine whether butadiene was present at trace levels (Table A-1, System C). Butadiene was not present at ≥0.05% of the total ion chromatogram, with an analytical system limit of detection (LOD) of butadiene at 12 ng/mL.

An accelerated stability study was previously conducted using a different lot (MKBH1265V, Sigma-Aldrich [Milwaukee, WI]) and was not repeated using lot MKBN9784V. The stability of lot MKBH1265V was confirmed for 14 days at frozen (−20°C), refrigerated (5°C), room (25°C), and elevated (60°C) temperatures when stored in amber glass vials sealed with Teflon^®^-lined caps.

One 30-gallon drum of lot MKBN9784V was warmed for 2.5 hours to liquify the contents. Once the chemical was liquified, the drum was rolled for approximately 5 minutes to homogenize the contents. A spigot was screwed into the drum, and it was placed on a drum cradle. The chemical was transferred to thirty 80-ounce amber glass bottles. Reanalysis of the bulk chemical was performed by the study laboratory prior to and after the 2-year study; no degradation was detected by GC/FID (Table A-1, System D).

## Preparation and Analysis of Dose Formulations

Dose formulations of sulfolane (lot MKBN9784V) in tap water (West Jefferson, OH municipal supply) were prepared approximately monthly at the study laboratory following the protocols outlined in Table A-2. Formulations were prepared at 0, 30, 100, 300, and 1,000 mg/L for both rats and mice. The formulations were stored refrigerated (5°C) in amber glass bottles sealed with Teflon-lined lids and were used within 42 days of preparation.

The stability of sulfolane formulations in tap water was determined by the analytical laboratory at RTI International using GC/FID (Table A-1, System E). Stability of the 30 mg/L formulation was confirmed for 42 days at both refrigerated (5°C) and room (25°C) temperatures. Under simulated dosing conditions, the 30 mg/L formulation was stable for 8 days.

Periodic analyses of the preadministration and postadministration dose formulations of sulfolane were conducted by the Battelle analytical laboratory using GC/FID (Table A-1, System F). Postadministration samples were collected from the animal rooms and formulation carboys. A 1,000 mg/L formulation was prepared on August 12, 2015, to replace the original preparation from July 23, 2015, which did not meet acceptance criteria and was deemed not suitable for use. With that exception, all other preadministration dose formulations were within 10% of the target concentrations (Table A-3). All postadministration samples were within 10% of the target concentrations with the following exceptions: The carboy samples of the 30 and 1,000 mg/L formulations prepared on May 4, 2015, were 10.9% and 10.2% below the target concentrations, respectively. The carboy samples of the 300 and 1,000 mg/L formulations prepared on September 21, 2015, were 10.2% and 13.0% below the target concentrations, respectively. The rat animal room sample of the 30 mg/L formulation prepared on July 23, 2015, was 10.5% below the target concentration, and the mouse animal room sample of the 300 mg/L formulation prepared on May 4, 2015, was 12.4% below the target concentration. These marginal deviations in postadministration dose formulations were not considered to have affected the study outcome.

## Animal Source

Time-mated (F_0_) female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Envigo (Haslett, MI). Male and female B6C3F1/N mice were obtained from the National Toxicology Program (NTP) colony maintained by Taconic Biosciences, Inc. (Germantown, NY).

## Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Battelle (West Jefferson, OH) Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health (NIH) and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Two-year Studies

### Exposure Concentration Selection Rationale

Exposure concentrations were selected using data from 28-day gavage studies in mice and rats,^4^ a gavage developmental and reproductive toxicity (DART) screening study in rats^26,33^ that followed the OECD 421 guideline, a 90-day drinking water rat study,^28^ and estimated exposure derived from drinking water consumption from previous NTP studies. The 28-day NTP gavage study showed evidence of overt toxicity following administration of 800 mg/kg/day, whereas in the 90-day drinking water study, rats exposed to 1,600 mg/L (132 mg/kg/day for males, 191 mg/kg/day for females) did not show chronic dose limiting effects (i.e., evidence of overt toxicity that would be concerning with chronic exposure). However, the gavage DART study showed developmental toxicity at doses ≥200 mg/kg/day. Given these toxicity data, differences in kinetics between gavage and drinking water and drinking water consumption and exposure estimates, the highest exposure concentration of 1,000 mg/L was selected for the 2-year studies for rats and mice (i.e., average exposure to approximately 50–200 mg/kg/day for each species), with a half-log dose spacing to the lowest exposure concentration of 30 mg/L to characterize the dose response. An interim necropsy at 3 months was included to evaluate subchronic toxicity.

### Study Design for Rats

F_0_ female rats were 12 to 13 weeks old upon receipt. Evidence of mating is defined as gestational day (GD) 1; F_0_ females were received on GD 2 and held for 4 days. F_0_ females were randomly assigned to one of five exposure groups on GD 5. Randomization was stratified by body weight that produced similar group mean weights using NTP Provantis software (Instem, Stone, UK).

F_0_ females were quarantined for 11 to 15 days after receipt. Ten nonmated females received with the time-mated females were designated for disease monitoring 3 days after arrival; samples were collected for serological analyses, and the rats were euthanized, necropsied, and examined for the presence of disease or parasites. The health of the F_1_ rats was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Beginning on GD 6, groups of 53 (0 mg/L) or 43 (30, 100, 300, and 1,000 mg/L) F_0_ time-mated female rats were exposed to sulfolane in drinking water throughout gestation and lactation at the following concentrations: 0, 30, 100, 300, or 1,000 mg/L. Tap water served as the 0 mg/L control. Feed and dosed water were available ad libitum.

F_0_ female rats were housed individually during gestation and with their respective litters during lactation. Cages were changed weekly for pregnant dams before delivery and twice weekly for dams and their litters after postnatal day (PND) 4. F_0_ females were observed twice daily for signs of mortality or moribundity. Body weights were recorded upon receipt, on GD 5 (for randomization), and on GDs 6, 9, 12, 15, 18, and 21. Clinical observations were recorded every 3 days from GD 6 through GD 21. Water consumption data were recorded on GDs 6, 9, 12, 15, 18, and 21. Details of the study design and animal maintenance are summarized in Table 1.

Table 1 Experimental Design and Materials and Methods in the Perinatal and Two-year Drinking Water Studies of Sulfolane

Rats | Mice
Study Laboratory
Battelle (West Jefferson, OH) | Same as rat study
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) | B6C3F1/N
Animal Source
Envigo (Haslett, MI) | Taconic Biosciences, Inc. (Germantown, NY)
Time Held Before Studies
F_0_ female rats: 4 days | 11 (females) or 12 (males) days
Average Age When Studies Began
F_0_ female rats: 12–13 weeks | 6 weeks
Date of First Exposure
F_0_ female rats: May 22–26, 2015 | May 18 (females) or 19 (males), 2015
F_1_ rats: July 5–10, 2015
Duration of Exposure
F_0_ female rats: GD 6 through LD 28 | 3 months (interim) or 2 years
F_1_ rats (3-month interim): Perinatal plus 3 months (interim)
F_1_ rats (2-year study): Perinatal plus 2 years
Date of Last Exposure
F_0_ female rats: July 5–10, 2015 | 3-month interim evaluation: August 16 (females) or 17 (males), 2015
F_1_ rats (3-month interim): October 12–13, 2015 | 2-year study: May 15–18 (females) or 18–21 (males), 2017
F_1_ rats (2-year study): July 10–12 (males) or 12–14 (females), 2017
Necropsy Dates
F_1_ rats (3-month interim): October 12 (males) or 13 (females), 2015 | 3-month interim evaluation: August 17 (females) or 18 (males), 2015
F_1_ rats (2-year study): July 10–12 (males) or 12–14 (females), 2017 | 2-year study: May 15–18 (females) or 18–21 (males), 2017
Size of Study Groups
F_0_ female rats: 53 (0 mg/L) or 43 (30, 100, 300, 1,000 mg/L) | 3-month interim evaluation: 10/sex
F_1_ rats (3-month interim): 10/sex | Internal concentration: 5/sex
F_1_ rats (internal concentration): 5/sex | 2-year study: 50/sex
F_1_ rats (2-year study): 50/sex
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights using NTP Provantis (Instem, Stone, UK). | Same as in rat study
Animals per Cage
F_0_ females: 1 (with litter) | 1 (males) or up to 4 (females)
F_1_ rats: up to 2 (males) or up to 4 (females)
Method of Animal Identification
F_0_ females: Cage card and tail marking | Tail tattoo or ear tag
F_1_ rats (pups): Limb tattoo until PND 28, then cage card and tail tattoo or ear tag
F_1_ rats (3-month interim): Cage card and tail tattoo
F_1_ rats (2-year study): Cage card and tail tattoo or ear tag
Diet
Irradiated NIH-07 wafer feed (perinatal phase) or irradiated NTP-2000 wafer feed (postweaning) (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed at least weekly | Irradiated NTP-2000 wafer feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed at least weekly
Water
Tap water (Village of West Jefferson, OH municipal supply), either untreated or containing a formulation of sulfolane via water bottles, available ad libitum, changed at least twice weekly | Tap water (Village of West Jefferson, OH municipal supply), either untreated or containing a formulation of sulfolane via water bottles, available ad libitum, changed weekly (males) or at least twice weekly (females)
Cages
Solid polycarbonate (Lab Products, Inc., Seaford, DE), changed at least weekly through PND 4, then twice weekly, rotated every 2 weeks | Solid polycarbonate (Lab Products, Inc., Seaford, DE), changed at least weekly, rotated at least every 2 weeks
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corporation, Montville, NJ), changed with cage changes | Same as in rat study
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks | Same as in rat study
Rack Filters
Spun-bonded polyester (National Filter Media Corporation, Olive Branch, MS), changed at least every 2 weeks | Same as in rat study
Animal Room Environment
Temperature: 70°F–78°F Relative humidity: 18%–77% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Temperature: 70°F–77°F Relative humidity: 30%–80% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
Exposure Concentrations
0, 30, 100, 300, or 1,000 mg/L in drinking water | Same as in rat study
Type and Frequency of Observation
F_0_ females: Observed twice daily. Weighed GDs 5, 6, 9, 12, 15, 18, and 21 and on LDs 1, 4, 7, 10, 14, 17, 21, 24, and 28. Clinical observations were recorded every 3 days from GD 6 through GD 21 and on LDs 1, 4, 7, 17, and 24. Water consumption was measured on GDs 6, 9, 12, 15, 18, and 21 and on LDs 1, 4, 7, 10, 14, 17, 21, 24, and 28. | Observed twice daily. Animals were weighed and clinical observations were recorded prior to exposure on day 0, weekly for 13 weeks, every 4 weeks thereafter, and at study termination. Water consumption was measured weekly (males) or twice weekly (females). Water consumption was reported weekly for the first 13 weeks and at 4-week intervals thereafter.
F_1_ rats: Observed twice daily. Pups were weighed individually. Clinical observations were recorded on PNDs 1, 4, 7, 10, 14, 17, and 24, and detailed clinical observations were conducted on PNDs 10, 14, 21, 28, and 35. Clinical observations were then recorded weekly for 13 weeks, every 4 weeks thereafter, and at study termination. Water consumption was measured at least twice weekly and reported weekly for the first 13 weeks and at 4-week intervals thereafter. Anogenital distance was measured on PND 1. Vaginal opening (and concomitant body weight) was evaluated daily beginning on PND 25 until the day of attainment, and balanopreputial separation (and concomitant body weight) was evaluated beginning on PND 35 until the day of attainment.
Method of Euthanasia
Carbon dioxide | Same as in rat study
Necropsy
Necropsies were performed on all 3-month interim evaluation and 2-year study F_1_ rats. Organs weighed at the 3-month interim evaluation were the left and right epididymis, heart, left and right kidneys, liver, lungs, left and right ovaries, left and right testes, and thymus. | Necropsies were performed on all mice. Organs weighed at the 3-month interim evaluation were the left and right epididymis, heart, left and right kidneys, liver, lungs, left and right ovaries, left and right testes, and thymus.
Clinical Pathology
At the 3-month interim evaluation, blood was collected from the retroorbital plexus of F_1_ rats for hematology, clinical chemistry, and erythrocyte micronuclei determinations. | At the 3-month interim evaluation, blood was collected from the retroorbital sinus for hematology and erythrocyte micronuclei determinations.
Hematology: Red blood cell count, hemoglobin, hematocrit, manual hematocrit, mean corpuscular volume, mean corpuscular hemoglobin, mean corpuscular hemoglobin concentration, white blood cell count, absolute differential leukocyte count, absolute reticulocyte count, platelet count, and qualitative evaluation of morphological features in all cellular components. | Hematology: Same as in rat study
Clinical chemistry: Urea nitrogen, creatinine, glucose, total protein, albumin, cholesterol, triglycerides, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and total bile acids. | Clinical chemistry: None
Histopathology
Complete histopathology was performed on all F_1_ rats in the 0 mg/L and 1,000 mg/L groups at the 3-month interim evaluation. The kidney was identified as a target organ and examined to a no-effect level. Complete histopathology was performed on all F_1_ rats in the 2-year study. In addition to gross lesions and tissue masses (if observed), the following tissues were examined: adrenal glands, brain (seven sections including (1) olfactory bulbs, (2) fronto-parietal cortex and basal ganglia, (3) mid-parietal cortex and thalamus, (4) mid-brain with substantia nigra and red nucleus, (5) posterior colliculi, (6) mid-cerebellum including cranial nerve VIII, and (7) posterior medulla), cervix/vagina, clitoral glands, esophagus, eyes, femur (including diaphysis with marrow cavity and epiphysis [femoral condyle with epiphyseal cartilage plate, articular cartilage, and articular surface]), Harderian glands, heart and aorta, kidneys, large intestine (cecum, colon, rectum), liver (two sections including left lateral lobe and median lobe), lungs and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland with adjacent (inguinal) skin, muscle (thigh, if neuromuscular signs were present), nasal cavity and nasal turbinates (three sections), nerve (sciatic, tibial, and trigeminal with ganglion, if neurological signs were present), ovaries, pancreas, parathyroid glands, pituitary gland, preputial glands, prostate, salivary glands, seminal vesicles, small intestine (duodenum, jejunum, ileum), spinal cord (three sections, if neurological signs were present), spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus. | Complete histopathology was performed on all mice in the 0 mg/L and 1,000 mg/L groups at the 3-month interim evaluation and on all mice in the 2-year study. In addition to gross lesions and tissue masses (if observed), the following tissues were examined: adrenal glands, brain (seven sections including (1) olfactory bulbs, (2) fronto-parietal cortex and basal ganglia, (3) mid-parietal cortex and thalamus, (4) mid-brain with substantia nigra and red nucleus, (5) posterior colliculi, (6) mid-cerebellum including cranial nerve VIII, and (7) posterior medulla), cervix/vagina, clitoral glands, esophagus, eyes, femur (including diaphysis with marrow cavity and epiphysis [femoral condyle with epiphyseal cartilage plate, articular cartilage, and articular surface]), gallbladder, Harderian glands, heart and aorta, kidneys, large intestine (cecum, colon, rectum), liver (two sections including left lateral lobe and median lobe), lungs and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland with adjacent (inguinal) skin, muscle (thigh, if neuromuscular signs were present), nasal cavity and nasal turbinates (three sections), nerve (sciatic, tibial, and trigeminal with ganglion, if neurological signs were present), ovaries, pancreas, parathyroid glands, pituitary gland, preputial glands, prostate, salivary glands, seminal vesicles, small intestine (duodenum, jejunum, ileum), spinal cord (three sections, if neurological signs were present), spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus.
Sperm Motility and Vaginal Cytology
At the 3-month interim evaluation, sperm samples were collected from F_1_ male rats in the 0, 100, 300, and 1,000 mg/L groups for sperm motility evaluations. Sperm motility and sperm/spermatid concentration data were not analyzed or reported because of artifacts identified during analysis. The left cauda, left epididymis, and left testis were weighed. Vaginal smears were collected for 16 consecutive days before the 3-month interim necropsy from F_1_ female rats in the 0, 100, 300, and 1,000 mg/L groups for vaginal cytology evaluations. | Same as in rat study
Internal Concentration Assessment
At the 3-month interim evaluation, blood samples were collected from the retroorbital plexus of five randomly selected F_1_ rats/sex/group (Appendix D). Plasma sulfolane concentrations were measured using a validated analytical method.^39^ | At the 3-month interim evaluation, blood samples were collected from the heart of five randomly selected mice/sex/group (Appendix D). Plasma sulfolane concentrations were measured using a validated analytical method.^39^

GD = gestation day; LD = lactation day; PND = postnatal day.

The day of parturition was considered lactation day (LD) 0 for dams and PND 0 for pups. On apparent GD 27, all time-mated female rats that failed to deliver were euthanized, and the uteri were examined and stained for evidence of implantation and resorption. Body weights were recorded for littered F_0_ females on LDs 1, 4, 7, 10, 14, 17, 21, 24, and 28. Clinical observations were recorded on LDs 1, 4, 7, 17, and 24. Water consumption data were recorded on LDs 1, 4, 7, 10, 14, 17, 21, 24, and 28. Individual F_1_ pup weights were recorded on PNDs 1, 4, 7, 10, 14, 17, 21, 24, and 28. Formal clinical observations were recorded for F_1_ pups on PNDs 1, 4, 7, 17, and 24, and detailed clinical observations (formal clinical observations with the addition of an open-field assessment) were recorded on PNDs 10, 14, 21, 28, and 35.

F_1_ litters were standardized on PND 4 to eight pups per litter, with four males and four females each. Weaning occurred on PND 28. One male and one female from 10 litters per exposure group were randomly selected for use in the 3-month interim evaluation, and 5 animals/sex/group were chosen from the interim group for internal concentration assessment. One or two pups per sex per litter from 25 to 27 litters per exposure group were randomly selected for use in the 2-year study. Twenty additional pups per sex (from control litters) were designated for disease monitoring. Following weaning, ≤60 pups/sex/group were selected for an immunotoxicity evaluation,^5^ and all F_0_ females and unselected pups were humanely euthanized with carbon dioxide. Weaning marked the beginning of the 3-month interim evaluation and 2-year study.

After weaning, groups of 50 male and 50 female F_1_ pups were administered 0, 30, 100, 300, or 1,000 mg/L sulfolane in drinking water for 2 years. Separate groups of 10 male and 10 female F_1_ pups per exposure group were included in the 3-month interim evaluation, which was conducted to evaluate potential subchronic toxicity, assess internal exposure, and allow for comparison to the Huntingdon Life Sciences (HLS) 2001 90-day drinking water study.^28^ Tap water served as the 0 mg/L control. Feed and dosed water were available ad libitum. Two diets were used in the rat studies: (1) NIH-07 during the perinatal phase and (2) NTP-2000 during the postweaning phase. The NIH-07 diet is a higher protein diet that supports reproduction and lactation in rodents, whereas the NTP-2000 diet is a lower protein diet that decreases the incidence of chronic nephropathy in adult rats. F_1_ rats were housed up to two (males) or up to four (females) per cage. Water consumption was measured at least twice weekly and was reported weekly for the first 13 weeks and at 4-week intervals thereafter. Cages were changed at least once weekly, and racks were changed and rotated at least every 2 weeks. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is provided in Appendix B.

### Study Design for Mice

Male and female B6C3F1/N mice were approximately 4 weeks old upon receipt and were quarantined for 11 days before study start. Mice were randomly assigned to one of five exposure groups (n = 50 mice/sex/exposure group). Randomization was stratified by body weight that produced similar group mean weights using NTP Provantis software (Instem, Stone, UK). Groups of 50 male and 50 female mice were administered 0, 30, 100, 300, or 1,000 mg/L sulfolane in drinking water for 2 years. Separate groups of 10 male and 10 female mice per exposure group were included in the 3-month interim evaluation, and separate groups of 5 male and 5 female mice per exposure group were included for internal concentration assessment. Tap water served as the 0 mg/L control. Twenty-three male and 25 female mice were randomly selected for parasite evaluation and gross observation of disease. The health of the mice was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Mice were housed individually (males) or up to four (females) per cage. Feed and dosed water were available ad libitum. Water consumption was measured weekly (males) or biweekly (females) and was reported weekly for the first 13 weeks and at 4-week intervals thereafter. Cages were changed at least once weekly and rotated at least every 2 weeks. Racks were changed and rotated every 2 weeks. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is given in Appendix B.

### Clinical Examinations and Pathology

In the 2-year studies in rats and mice, animals were observed twice daily for signs of morbidity and moribundity. Animals were weighed and clinical observations were recorded prior to exposure on study day 0, weekly for the next 13 weeks, every 4 weeks thereafter, and at study termination.

In all F_1_ male and female rats, anogenital distance (AGD) was measured on PND 1 using a calibrated caliper. Attainment of balanopreputial separation (BPS), defined as complete retraction of the prepuce from the glans penis, was evaluated in all F_1_ male rats beginning on PND 35 until the day of attainment; body weight was recorded upon BPS attainment. The attainment of vaginal opening (VO) was evaluated in all F_1_ female rats beginning on PND 25 until the day of attainment, and the corresponding body weight recorded upon VO attainment.

At the 3-month interim evaluations, blood was collected from the retroorbital plexus (rats) or retroorbital sinus (mice) for hematology, clinical chemistry (rats), and erythrocyte micronuclei determinations. Rats and mice were anesthetized with a carbon dioxide/oxygen mixture and bled in a random order. Blood for hematology, micronuclei determinations, and internal concentration assessment was collected into tubes containing tripotassium ethylenediaminetetraacetic acid (K_3_ EDTA). Blood for clinical chemistry was collected into serum separator tubes and centrifuged, and the serum was harvested. Hematology parameters were analyzed using an Advia^®^ 120 system (Bayer Diagnostics Division, Tarrytown, NY). Clinical chemistry parameters were analyzed using a Roche cobas^®^ c311 chemistry analyzer (Roche, Indianapolis, IN). The parameters measured are listed in Table 1. Samples for erythrocyte micronuclei determination were refrigerated immediately after collection and shipped to Integrated Laboratory Systems, LLC (ILS, Durham, NC) for analysis. For internal concentration assessment, plasma was isolated from red blood cells, and plasma samples were stored at −60°C to −85°C until they were shipped to RTI International for chemical analysis (Research Triangle Park, NC), as described in Appendix D. Plasma samples were analyzed using a previously validated method.^39^

Samples were collected for sperm motility and vaginal cytology evaluations from 3-month interim F_1_ male and female rats and male and female mice in the 0, 100, 300, and 1,000 mg/L groups. For 16 consecutive days before the scheduled 3-month interim termination, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were collected and subsequently stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male rats and mice were evaluated for sperm count and motility. An incision was made in the distal region of the left cauda epididymis, and the cauda was placed in a Petri dish containing M199 solution (maintained at approximately 37°C) with 1.0% bovine serum albumin (BSA). A small sample of the diluted sperm was loaded into a 100 µm-chambered slide for determination of motility. After completion of sperm motility estimates, the remainder of the diluted sperm and cauda epididymis in M199/BSA solution and the left testis were stored frozen (approximately −70°C) until enumeration of sperm concentration was performed. The left cauda epididymis in M199/BSA solution was thawed and homogenized, and the left testis was thawed and homogenized in 0.9% saline with 0.05% Triton-X 100. Homogenized samples were mixed with a DNA-specific fluorescent dye (IDENT) to allow for sperm identification under fluorescent illumination.

Complete necropsies and microscopic examinations were performed on all 2-year study F_1_ rats and all mice. At the 3-month interim evaluation, complete histopathological examinations were performed on all organs with gross lesions and on all vehicle control and 1,000 mg/L rats and mice. The kidney was identified as a target organ and examined to a no-effect-level. At the 3-month F_1_ rat interim evaluation, the weights of the left and right epididymis, heart, left and right kidneys, liver, lungs, left and right ovaries, left and right testes, and thymus were collected. At the 3-month and 2-year necropsies, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin except for the eyes and right testis (including vaginal tunic and epididymis), which were first fixed in Davidson’s solution and modified Davidson’s solution, respectively. Tissues were processed and trimmed, embedded in paraffin, sectioned at a thickness of 4 to 6 μm, and stained with hematoxylin and eosin (H&E) for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. The uterus/cervix/vagina and ovaries, with the exception of interim evaluations for which the ovaries were removed and weighed, were mounted on cardstock before fixation. Following fixation, the ovaries were removed and embedded whole. The cervix and vagina were separated from the uterus immediately posterior to the uterine body. The uterine horns were bisected at their midpoint, and one transverse section was taken from the midpoint of each horn. Within a single cassette, the cervix and vagina were embedded as one piece, along with the two transverse sections of the uterine horns. The uterine body with attached pieces of the uterine horn and the two free portions of the uterine horn were embedded in a second cassette. Sagittal sections of all tissues within the resulting blocks were processed and examined histologically. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by a board-certified veterinary pathologist (study pathologist), and the pathology data were entered into the NTP Provantis software (Instem, Stone, UK). The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory and storage. An audit of pathology specimens was conducted wherein the wet tissues, blocks, and slides were examined for quality and adherence to the NTP Specifications (published in 2011)^40^ by technical staff, and the wet tissues were examined by a team of pathologists to ensure all tissues were sampled according to NTP Specifications. The slide and tissue counts were also verified. Slide-mounted, H&E-stained slides were evaluated for accuracy and consistency of diagnoses by a team of quality assessment (QA) pathologists independent of the study laboratory. The histotechnique was also evaluated. For the 2-year studies, QA pathologists evaluated slides from all tumors and all potential target organs, which included the kidney of male rats, as well as other slides identified during the pathology data review. For lesions in which there was a discrepancy of diagnosis, slide scans (Hamamatsu S360 whole slide scanner; Hamamatsu Photonics K. K., Hamamatsu-city, Japan) were reviewed by the study pathologist and QA pathologists (with the Division of Translational Toxicology [DTT] pathologist present) to reconcile differences, and the diagnoses were revised as appropriate.

Subsequently, a secondary reviewing pathologist reviewed the lung, liver, spleen, skin (with mammary gland), and bone marrow to confirm the diagnoses of proliferative endothelial lesions (i.e., endothelial hyperplasia, hemangioma, and hemangiosarcoma) in mice. A pathology working group (PWG) was conducted by the secondary reviewing pathologist, DTT pathologist, and other pathologists experienced in rodent toxicological pathology. When the PWG consensus diagnosis differed from that of the laboratory pathologist, the diagnosis was changed. The study pathologist and QA pathologist read the slides in an informed manner (with knowledge of the animal numbers and which exposure groups the animals were from), but the PWG members reviewed the slides in a blinded fashion (with no knowledge of exposure groups). The rationale for this is presented in Sills et al.^41^ Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman,^42^ Boorman et al.,^43^ and Sills et al.^41^ For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of Brix et al.^44^

## Statistical Methods

For all analyses, p values ≤0.05 were considered statistically significant, and p values ≤0.01 were also noted. Statistical significance is one component of the “weight of evidence” approach to evaluate carcinogenicity (described in the Explanation of Levels of Evidence of Carcinogenic Activity section).

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^45^ and is presented graphically. Animals surviving to the end of the observation period are treated as censored observations, as are animals dying from unnatural causes within the observation period. Animals dying from natural causes are included in analyses and are treated as uncensored observations. For the 2-year mouse study, exposure concentration-related trends are identified with Tarone’s life-table test,^46^ and pairwise exposure concentration-related effects are assessed using Cox’s method.^47^ For the rat perinatal study, exposure concentration-related trends and pairwise exposure concentration-related effects on survival are assessed using a Cox proportional hazards model^47^ with a random litter effect. All reported p values for the survival analyses are two-sided. In this study, animals that reached or exceeded the age of the youngest animal euthanized at study termination were considered to have survived to study termination.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented as the numbers of animals bearing such lesions at a specific anatomic site. For calculation of incidence rates, the denominator for most neoplasms and all nonneoplastic lesions is the number of animals for which the site was examined microscopically. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominator consists of the number of animals on which a necropsy was performed. Additional study data also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (derived from the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal euthanasia.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidence

Statistical analyses of neoplasm and nonneoplastic lesion incidence considered two features of the data. Some animals did not survive the entire 2 years of the study, so survival differences between groups had to be considered. In addition, up to two animals per sex were randomly selected from each litter to participate in the study. The statistical analysis of lesion incidence used the Poly-3 test to account for survival differences, with a Rao-Scott adjustment for litter effects, as described below.

The Poly-k test^48-50^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to account for survival differences. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is 1 if the animal had a lesion at that site or if it survived until terminal euthanasia; if the animal died before terminal euthanasia and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only on the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^48^ Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^48^ after an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control Fischer 344 rats and B6C3F1 mice.^51^ Bailer and Portier^48^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range of 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^52^ Poly-3 tests used the continuity correction described by Nam.^53^

Littermates tend to be more like each other than like fetuses/pups in other litters. Failure to account for correlation within litters leads to underestimates of variance in statistical tests, resulting in higher probabilities of Type I errors (“false positives”). Because up to two pups/sex/litter were present in the rat perinatal and 2-year study, the Poly-3 test was modified to accommodate litter effects using the Rao-Scott approach.^54^ The Rao-Scott approach accounts for litter effects by estimating the ratio of the variance in the presence of litter effects to the variance in the absence of litter effects. This ratio is then used to adjust the sample size downward to yield the estimated variance in the presence of litter effects. The Rao-Scott approach was implemented in the Poly-3 test as recommended by Fung et al.^55^ formula ₸_RS2_.

Tests of significance included pairwise comparisons of each exposed group with control groups and a test for an overall exposure concentration-related trend. Continuity-corrected Rao-Scott-adjusted Poly-3 tests were used in the analysis of lesion incidence and reported p values are one-sided. For neoplasms and nonneoplastic lesions observed without litter structure (as in the 2-year mouse study), Poly-3 tests that included the continuity correction, but without adjustment for potential litter effects, were used for trend and pairwise comparisons to the control group. At the interim evaluation, neither a Poly-3 adjustment nor a Rao-Scott adjustment was needed because there were no long-term exposures and no littermates; the Cochran-Armitage trend tests and Fisher’s exact pairwise tests were used.

To evaluate incidence rates by litter in the rat perinatal and 2-year study, the proportions of litters affected by each lesion type were tested among groups. Cochran-Armitage trend tests and Fisher’s exact test^56^ were used to test the litter incidences for trends and pairwise differences from the control group, respectively.

### Analysis of Continuous Variables

Before statistical analysis, outliers identified by the Dixon and Massey test^57^ for small samples (n < 20) and Tukey’s outer fences method^58^ for large samples (n ≥ 20) were examined by DTT personnel, and biologically implausible values (likely due to experimental error) were eliminated from the analysis. Organ and body weight measurements, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^59^ and Williams.^60,61^ Dam gestational and lactational feed consumption, hematology and clinical chemistry data, litter sizes, pup survival, implantations, number of resorptions, and proportions of male pups per litter for all studies were analyzed using the nonparametric multiple comparison methods of Shirley^62^ [as modified by Williams^63^] and Dunn^64^ given that these endpoints typically have skewed distributions. For all quantitative endpoints unaffected by litter structure, the Jonckheere test^65^ was used to assess the significance of the exposure concentration-related trends and to determine at the 0.01 level of significance whether a trend-sensitive test (the Williams or Shirley test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic exposure concentration-related trend (the Dunnett or Dunn test). For plasma concentration data, when individual concentration values were provided as “below limit of detection,” one-half the LOD was used as a substitute value. However, if 80% or more of the values in the control group were below the LOD, the mean was reported as “BD” to indicate the values were “below detection” and no statistical analysis was performed on the endpoint.

Dam body weights during gestation and lactation were analyzed with the parametric multiple comparison procedures of Dunnett^59^ or Williams,^60,61^ depending on whether the Jonckheere test indicated the use of a trend-sensitive test. P values for these analyses are two-sided. Postweaning body weights were measured on two pups/sex/litter in the 2-year study; more than two pups/sex/litter were possible in preweaning body weight measurements. The analysis of these postweaning weights along with the analysis of pup body weights and pup body weights adjusted for litter size (described below), accounted for litter effects using a mixed model with litter as a random effect. AGD was adjusted for the body weight of the pup taken on the day of AGD measurement. The adjusted AGDs were analyzed as normal variates with litter effects using a linear mixed model. To adjust for multiple comparisons, a Dunnett-Hsu adjustment was used.^66^

### Analysis of Gestational and Fertility Indices

Cochran-Armitage trend tests were used to test the significance of trends in gestational and fertility indices across exposure groups. Fisher’s exact test was used to conduct pairwise comparisons of each exposed group with the control group. P values for these analyses are two-sided.

### Body Weight Adjustments

Preweaning pup body weights were adjusted for live litter size as follows: A linear model was fit to body weights as a function of exposure and litter size. The estimated coefficient of litter size was then used to adjust each pup body weight based on the difference between its litter size and the mean litter size. Prestandardization PND 4 body weights were adjusted for PND 1 litter size, and body weights measured between PND 4 poststandardization and PND 21 were adjusted for PND 4 poststandardization litter size. After adjustment, body weights were analyzed with a linear mixed model with a random litter effect.

### Analysis of Time-to-event Data

Time-to-event endpoints, such as day of attainment of BPS and VO, have several features that require careful model selection: non-normality of distributions, litter-based correlation, and censored values when attainment was not observed before the end of the observation period. Further, growth retardation, reflected in the weaning weight, is an important covariate in the case of BPS and VO given the relationship between normal day of expected attainment and body weight.

When attainment times were approximately normally distributed and attainment was observed for all or most animals, two approaches for modeling discrete developmental endpoints were taken. First, a mixed model was fit to attainment day as a function of exposure concentration with a random litter effect. A second mixed model was fit to attainment day as a function of exposure concentration and weaning weight with a random litter effect. Dunnett-Hsu adjustments were used to account for multiple comparisons.^66^

To calculate mean attainment values adjusted for weaning weight, a linear model was fit to attainment day as a function of exposure concentration and weaning weight. The estimated coefficient of weaning weight was then used to adjust each attainment day based on the difference between the measured weaning weight and the mean weaning weight.

### Analysis of Vaginal Cytology Data

Vaginal cytology data consist of daily observations of estrous cycle stages over a 16-day period. Differences from the control group for cycle length and number of cycles were analyzed using a Dunn’s test or a Shirley’s test as determined by the results of a Jonckheere trend test To identify disruptions in estrous cyclicity, a continuous-time Markov chain model (multi-state model) was fit using a maximum likelihood approach, producing estimates of stage lengths for each exposure concentration group. Confidence intervals for these estimates were derived from bootstrap sampling of the individual animal cycle sequences. Stage lengths that were significantly different from the control group were identified using permutation testing with a Hommel adjustment.

### Historical Control Data

The concurrent control group is the most valid comparison to the exposed groups and is the only control group analyzed statistically in NTP bioassays. Historical control data are often helpful in interpreting potential exposure-related effects, however, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control data must be generally similar. Significant factors affecting the background incidence of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period^67-69^ including the concurrent control for comparison across multiple technical reports. In general, the historical control data for a given study includes studies using the same route of administration, and the overall incidence of neoplasms in controls for all routes of administration are included for comparison, including the current study. However, there is only one other drinking water study in the database; therefore, only the overall incidence for all routes was included.

## Quality Assurance Methods

The 2-year studies were conducted in compliance with U.S. Food and Drug Administration Good Laboratory Practice Regulations.^70^ In addition, the 2-year study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by DTT staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of sulfolane was assessed by testing whether the chemical increases the frequency of micronucleated erythrocytes in rat and mouse peripheral blood or increases DNA damage in cells from the peripheral blood of rats and mice. The protocol for these studies and the results are given in Appendix E.

The genetic toxicity studies have evolved from an earlier effort to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals that was based on numerous considerations, including the relationship between the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were developed originally to clarify proposed mechanisms of chemical-induced DNA damage, given the relationship between electrophilicity and mutagenicity,^71^ and the somatic mutation theory of cancer.^72,73^ Not all cancers, however, arise through genotoxic mechanisms.

### Peripheral Blood Micronucleus Test

Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^74,75^ Acute in vivo bone marrow chromosome aberration and micronucleus tests appear to be less predictive of carcinogenicity than the Salmonella test.^76,77^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^78^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, determination of in vivo genetic effects is important to overall understanding of risks associated with exposure to a particular chemical.