# Introduction

Figure 1

Sulfolane (CASRN 126-33-0; DTXSID3027037; Chemical Formula: C_4_H_8_SO_2_; Molecular Weight: 120.17 g/mol)

Synonyms: 2,3,4,5-tetrahydrothiophene-1,1-dioxide, tetramethylene sulfone, tetrahydrothiophene-1,1-dioxide.

## Chemical and Physical Properties

Sulfolane is an organosulfur compound containing a sulfonyl group with a sulfur atom double-bonded to two oxygen atoms. The double bond is highly polar, whereas the carbon ring has high nonpolar stability. Sulfolane is a clear, colorless gel at ambient temperature (approximately 25°C) with a melting point in the range of 27.4°C to 27.8°C and a density of 1.261 g/cm^3^, liquid.^6^ Sulfolane is miscible in water, acetone, glycerol, and many oils. It is chemically stable in the presence of many chemical substances except sulfur and aluminum chloride.^7^ Sulfolane has a low vapor pressure (0.0062 mm Hg at 27.6°C).^6^

## Production, Use, and Human Exposure

Sulfolane production occurs when sulfur dioxide and butadiene react together, forming sulfolene; sulfolene is then hydrogenated to form sulfolane.

Sulfolane is commonly used as an industrial solvent in liquid-liquid and liquid-vapor extractions, such as in the extraction of benzene, toluene, and xylene from mixtures with aliphatic hydrocarbons (e.g., in petroleum refining) and in the extraction of acidic components (e.g., hydrogen sulfide, carbon dioxide, carbonyl sulfide, carbon dioxide, mercaptans) from sour gas streams.^8-10^ It is also used in textile refinishing, in the fractionalization of wood tars, as a component of hydraulic fluid, and as a curing agent in epoxy resins.^10^ It is estimated that approximately 150 extraction units utilizing sulfolane are in use around the world, and sulfolane is considered a high production volume chemical in the United States, with an annual production of 10–50 million pounds.^11^

Release of sulfolane into the environment through various waste streams near refineries results in groundwater contamination. It is presumed that sulfolane does not break down easily in groundwater, likely because of low oxygen and nutrient levels, and while it does not accumulate in the aquatic food chain, it is taken up by plants.^12,13^ In North Pole, Alaska, contamination of groundwater from a nearby petroleum refinery led to detection of sulfolane in nearly 300 drinking water wells in the area since 2009, with measurements in 2015 ranging from 4 to 7 ppb in older supply wells^14^ and several measurements within 100–400 ppb in previous years.^15,16^ Sulfolane has been detected at additional sites in Canada and the United States near natural gas or petroleum refineries.^17-20^

Human exposure to sulfolane occurs through occupational (inhalation and/or dermal) and environmental (drinking water) sources; however, no exposure data are available.

## Regulatory Status

Currently, no federal regulatory limits exist for sulfolane levels in drinking water. The Agency for Toxic Substances and Disease Registry’s (ATSDR’s) recommended public health action levels in drinking water are based on the Zhu research group identifying an oral no-observed-adverse-effect level (NOAEL) for guinea pigs of 0.25 mg sulfolane/kg body weight/day (mg/kg/day).^21^ Because of limited available research, ATSDR applied an uncertainty factor of 100 to the NOAEL of 0.25 mg/kg/day, resulting in a health guidance value dose of 0.0025 mg/kg/day (2.5 μg/kg/day). On the basis of average water intake, the public health action levels in drinking water for sulfolane are 20 ppb (infants), 32 ppb (children), and 70 ppb (adults).^22^ The U.S. Environmental Protection Agency (EPA) Provisional Peer-reviewed Toxicity Values for subchronic and chronic sulfolane exposure are 10 μg/kg/day and 1 μg/kg/day, respectively, and are based on decreased white blood cell (WBC) counts in female CD rats after a 90-day drinking water exposure.^23^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

As part of the National Toxicology Program (NTP) research program on sulfolane, absorption, distribution, metabolism, and excretion studies, as well as toxicokinetic (TK) studies, were conducted following a single gavage administration or dermal application in male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and B6C3F1/N mice.^2,3^ Sulfolane was well absorbed following administration of 30, 100, or 300 mg/kg [2,5-^14^C]sulfolane in rats and mice and was excreted extensively in urine (rats, approximately 91%–93%; mice, approximately 64%–86%) with low tissue retention (<2%) at 48 hours following oral administration.^2^ Following dermal application of 100 mg/kg [2,5-^14^C]sulfolane to a covered application site, the absorption of sulfolane was lower in male and female rats (approximately 16%–19%) compared to that in male and female mice (approximately 70%–80%).^2^ There were no route, species, or sex differences in urinary radiochemical profiles, with sulfolane and 3-hydroxysulfolane analytes found to be the main analytes in urine.^2^ Other investigators have also reported 3-hydroxysulfolane as the primary metabolite of sulfolane in rats, mice, and rabbits.^24^ Following intraperitoneal (IP) injection of 100 mg of [^35^S]sulfolane/kg, 85% of the radioactivity excreted in the urine during the first 24 hours was associated with the metabolite 3-hydroxysulfolane.^24^

In studies investigating the TK behavior of sulfolane in male and female rats and mice, absorption of sulfolane was rapid following a single gavage administration of 10, 30, or 100 mg/kg of sulfolane, with the maximum plasma concentration (C_max_) reached at 1.47 hours in rats and at 0.55 hours in mice.^3^ In rats of both sexes, C_max_ increased proportionally with the dose, whereas the increase in C_max_ was greater than proportional in mice. The plasma elimination half-life increased with dose in rats (1.99–6.33 hours) and mice (0.299–1.25 hours), with shorter half-lives observed in mice compared with rats. Estimated oral bioavailability was higher in rats (81%–83%) than in mice (59%–63%) at 10 mg/kg; values were >100% at 30 and 100 mg/kg in both species and sexes, suggesting that saturation of the metabolism and clearance pathways of sulfolane may begin at doses of approximately 30 mg/kg.^2^

### Humans

The literature contains no studies on the absorption, metabolism, distribution, or excretion of sulfolane in humans.

## Toxicity

### Experimental Animals

#### General Toxicity

In subchronic inhalation studies of aerosolized sulfolane (3% water) conducted in rats, guinea pigs, dogs, and squirrel monkeys, overt toxicity was observed in squirrel monkeys and dogs within the first 7 days of exposure to 200 mg/m^3^ sulfolane. Chronic lung inflammation was observed in all species following 27 days of exposure (8 hours/day, 5 days/week) to 495 mg/m^3^ sulfolane.^25^ At 60 days, the only remaining male dog had grossly elevated plasma aspartate aminotransferase, alanine aminotransferase, and lactate dehydrogenase activities. In guinea pigs, chronic pleuritis was noted in the lungs after 30 days of exposure to 200 mg/m^3^, and fatty vacuolization was observed in the liver of the 30-, 60-, and 90-day exposed groups. No signs of toxicity or effects on body weight, hematology, or pathology were observed following continuous exposure (85–110 days) to 2.8–159 mg/m^3^ sulfolane in rats, guinea pigs, monkeys, or dogs.^25^

In a 28-day study, male and female rats dosed with 700 mg/kg/day sulfolane via gavage experienced significantly decreased body weights and feed consumption, although the female rats recovered after the second week of exposure. In males, a higher incidence of hyaline droplet accumulation was observed in the kidneys. A significant decrease in erythrocyte count was noted in female rats after a 2-week recovery period, and significant decreases in spleen weights were also noted at 28 days and after a 2-week recovery period.^26,27^ An NTP 28-day toxicity study compared the effects of sulfolane in three species (rats, mice, and guinea pigs) to determine species sensitivity.^4^ Following gavage administration of 800 mg/kg/day sulfolane, male and female B6C3F1/N mice and Hartley guinea pigs were removed from the study because of overt toxicity, and a noted reduction in weight was observed in male and female Sprague Dawley rats.^4^ Additional findings following 28 days of exposure included nonneoplastic lesions in the kidney (male rats), forestomach and glandular stomach (male mice), esophagus (male and female guinea pigs), and nose (male guinea pigs), including hyaline droplet accumulation in the proximal tubules of the kidney (male rats).^4^

In a 90-day drinking water study of sulfolane (0, 25, 100, 400, or 1,600 mg/L) by Huntingdon Life Sciences (2001), a NOAEL of 25 mg/L (2.9 mg/kg/day) and a lowest-observed-adverse-effect level (LOAEL) of 100 mg/L (10.6 mg/kg/day) were reported for female CD rats and were based on significantly decreased WBC, lymphocytes, monocytes, and large unstained cells.^28^ Although few details are provided, a 90-day gavage study (0, 55.6, 167, and 500 mg/kg/day) in rats and guinea pigs reported clinical chemistry changes in addition to significantly decreased WBC in guinea pigs.^21^ In a second study in guinea pigs orally exposed for 6 months (0, 0.25, 2.5, 25, or 250 mg/kg/day), clinical pathology and bone marrow cell changes along with spleen white pulp shrinkage were observed at the 3-month interim, and lesions in the liver (fatty deposits) and spleen (white pulp shrinkage) were reported after 6 months of exposure.^21^

#### Neurotoxicity

Acute metabolic and neurotoxic effects have been reported for sulfolane, including changes in thermoregulation, motor activity, and brain-wave patterns in male Long Evans hooded rats.^29,30^ Following acute IP injection, dose-related inhibition of metabolic rate and hypothermia were first observed 60 minutes postinjection and lasted at least 2.5 hours in Sprague Dawley rats.^31^ In male CD-1 mice, IP injection of sulfolane at ≥400 mg/kg reduced the metabolic rate and body temperatures and induced behavioral changes including preference of ambient temperatures.^32^ Sulfolane has been reported as a convulsant in rats, mice, dogs, and squirrel monkeys.^8,9^ In a study exploring the median lethal dose (LD_50_) via different routes of exposure (i.e., oral and IP) in rats, mice, guinea pigs, and rabbits, no significant species differences in the LD_50_ of sulfolane were observed, and death was preceded by signs of central nervous system (CNS) stimulation, such as hyperactivity and convulsions, across species.^8^ Similar toxic signs of CNS stimulation in mice and rats were observed across different routes of exposure (i.e., intravenous and IP) including hunched, retreating posture with front limbs braced wide, erect tail, hyperactivity, increased responsiveness to auditory stimulation, and rapid respiration. At lethal doses, all species on study had clonic-tonic convulsions.^8^

#### Reproductive and Developmental Toxicity

A gavage reproductive/developmental toxicity screening test (OECD TG 421) was conducted at doses of 0, 60, 200, and 700 mg/kg/day.^26,33^ Male Sprague Dawley rats were dosed for 49 days starting 14 days prior to mating, and female rats were dosed for 41–50 days (starting 14 days prior to mating to day 3 of lactation). There was some mortality and significant decreases in body weight gain and feed consumption at 700 mg/kg/day along with disrupted estrous cyclicity. Four dams experienced whole litter loss at 700 mg/kg/day. Litter size, survival, and pup weight were significantly decreased postparturition. Litter size at birth and the number of pups and pup weight on days 0 and 4 of lactation were lower in the 200 mg/kg/day group. The parental NOAEL was 200 mg/kg/day, and the NOAEL for offspring was 60 mg/kg/day. In the above study, there were no dose-related findings in the external appearance, general conditions, and necropsy findings of the offspring. However, in another study, increased fetal resorptions and fetal skeletal anomalies were observed in Chinese Kunming mice following maternal oral exposure to 840 mg/kg/day.^21^

#### Immunotoxicity

In a comprehensive NTP immunotoxicology study, the potential effects of sulfolane on gross pathology, enhanced immunopathology, hematology, antibody response to sheep red blood cells, antibody response to keyhole limpet hemocyanin, T-cell proliferation, natural killer (NK) cell activity, immunophenotyping of the spleen, and cytotoxic T-lymphocyte response to influenza infection were examined.^5^ In this study, adult female B6C3F1/N mice were dosed with sulfolane via gavage (0, 1, 10, 30, 100, or 300 mg/kg/day) for 90 days, and time-mated female Sprague Dawley rats were exposed to sulfolane in drinking water (0, 30, 100, 300, or 1,000 mg/L) from gestational day 6 through approximately 13 weeks of age. In mice, no clinical indications of toxicity or effects on body weight were observed following sulfolane exposure, and minimal immunotoxic effects, including decreased splenic NK cell number at ≥100 mg/kg/day (ex vivo NK cell activity was not affected) and decreased number of large unstained cells at doses ≥30 mg/kg/day, were noted. Similarly, limited findings were observed following perinatal exposure in rats. No clinical indications of toxicity related to sulfolane were noted, and a slight decrease in body weight was observed in male and female F_1_ rats exposed to 1,000 mg/L (approximately 5% and 7%–10%, respectively). Sulfolane exposure had no significant immunotoxic effects on F_1_ males. In female F_1_ rats immunized with sheep red blood cells (SRBC), spleen cellularity was increased 14%–31% at concentrations of ≥100 mg/L sulfolane, and NK cell activity decreased in a concentration-dependent manner in cells from the sulfolane-exposed female F_1_ rats.^5^

### Humans

The literature contains no studies on the possible health effects following sulfolane exposure in humans.

## Carcinogenicity

### Experimental Animals

Aside from the previously mentioned 6-month study in guinea pigs,^21^ there are no chronic or carcinogenicity studies of sulfolane in animal models. Structurally related 3-sulfolene was previously evaluated for carcinogenic activity in male and female Osborne-Mendel rats and B6C3F1 mice via gavage (corn oil vehicle) by the National Cancer Institute.^34^ There was no evidence of carcinogenic activity in both rats and mice; however, exposure-related significant decreases in survival were observed, resulting in dose adjustments throughout the study.

### Humans

The literature contains no studies on the carcinogenicity of sulfolane in humans.

## Genetic Toxicity

In 28-day gavage studies previously conducted as part of the NTP sulfolane research program, peripheral blood samples were obtained from male and female Sprague Dawley rats and B6C3F1/N mice and analyzed for the frequency of micronucleated reticulocytes and erythrocytes.^4^ In male and female rats, the reticulocyte population (polychromatic erythrocytes, or PCEs), which is the only red blood cell population that can be accurately assessed for micronucleus frequency in peripheral blood of rats because of efficient splenic scavenging of damaged erythrocytes, did not show an increase in micronuclei after 28 days of exposure to sulfolane via gavage (0, 1, 10, 30, 100, 300, or 800 mg/kg/day). Significant changes in the percentage of reticulocytes were observed in male and female rats; however, these changes were within the historical control 95% confidence interval. There were no increases in micronucleated reticulocytes or micronucleated erythrocytes in male and female mice after 28 days of exposure to sulfolane via gavage (0, 1, 10, 30, 100, or 300 mg/kg/day).

A few additional reports of the genetic toxicity of sulfolane are also available in the peer-reviewed literature; however, these reports lacked primary data and were inadequate for review.

## Study Rationale

Sulfolane was nominated to NTP by the Alaska Department of Environmental Conservation with support from various entities in Alaska, as well as by ATSDR. The potential for human exposure to sulfolane through groundwater in North Pole, Alaska, and near other natural gas or petroleum refining sites has raised public health concerns for residents. Because long-term exposure to sulfolane has likely occurred and information on potential toxicity following long-term exposure is lacking, 2-year drinking water studies were conducted in rats and mice to evaluate the potential chronic toxicity and carcinogenic activity of sulfolane. Because of the likelihood of early life exposure to sulfolane in these communities, gestation and early postnatal exposure was included in the rat study to evaluate for potential effects of lifetime exposure.